# APPENDIX G CHEMICAL CHARACTERIZATION AND DOSE FORMULATION STUDIES

## Procurement and Characterization

### Sodium Bromate

Sodium bromate was obtained from Fisher Scientific (Fairlawn, NJ) in one lot (946272A) that was used in the 26- and 39-week dermal studies and in the 27- and 43-week drinking water studies. Identity and purity analyses were conducted by the analytical chemistry laboratories, Research Triangle Institute (RTI) (Research Triangle Park, NC) and Battelle Memorial Institute (Columbus, OH), and by the study laboratory, Battelle Columbus Operations (Columbus, OH). Reports on analyses performed in support of the sodium bromate studies are on file at the National Institute of Environmental Health Sciences.

Lot 946272A, a white crystalline powder, was identified as sodium bromate by the analytical chemistry laboratories and by the study laboratory using infrared spectroscopy (IR), by Galbraith Laboratories, Inc. (Knoxville, TN), using elemental analysis, and by Battelle Memorial Institute using inductively coupled plasma emission (ICP) spectrometry for elemental sodium content. All IR spectra were consistent with the structure and with a literature spectrum of sodium bromate. An IR spectrum is presented in Figure G1. Elemental analyses for bromine and sodium were in agreement with the theoretical values for sodium bromate. ICP spectrometry indicated that the sodium content was 93.5% of theoretical.

The purity of lot 946272A was determined by the analytical chemistry laboratories and by the study laboratory using ion chromatography (IC) and by Battelle Memorial Institute using iodometric titration of bromate ions. The IC system was operated in anion mode to measure the bromate anion and utilized a dual pump ion chromatograph, an IonPac^®^ AS12A column (200 mm × 4 mm), a CDM-1 suppressed conductivity detector from Dionex Corp. (Sunnyvale, CA), and an isocratic mobile phase of 2.7 mM sodium carbonate/0.3 mM sodium bicarbonate at a flow rate of 1.5 mL/minute. Iodometric titration utilized certified 0.1 N sodium thiosulfate solution and a starch indicator to measure the iodine produced from the oxidation of iodide ion by bromate.

For lot 946272A, IC indicated one major peak and no impurities with relative areas greater than 0.1%, with purities of 101.2% relative to a frozen reference standard and 97% based on bromate anion recovery relative to a reference sample of 99% purity obtained from Aldrich Chemical Co. (Milwaukee, WI). Iodometric titration indicated a purity of approximately 99%. The overall purity of lot 946272A was determined to be 99% or greater.

To ensure stability, the bulk chemical was stored at room temperature, protected from light. Stability was monitored during the 26-, 27-, 39-, and 43-week studies using IC by a system similar to that described for purity analysis. No degradation of the bulk chemical was detected.

### 12-O-Tetradecanoylphorbol-13-acetate

12-O-tetradecanoylphorbol-13-acetate (TPA) was obtained from Sigma-Aldrich Chemical Company (St. Louis, MO) in one lot (48H1178) that was used in the 26- week and 27-week studies in Tg.AC hemizygous mice. Lot 48H1178, a white crystalline powder, was identified as TPA by RTI using IR and proton nuclear magnetic resonance (NMR) spectrometry. All spectra were consistent with the structure of TPA.

The purity of lot 48H1178 was determined by RTI using high performance liquid chromatography (HPLC). HPLC analysis was performed with a Dupont Zorbax Rx C8 column (25 cm × 4.6 mm; Agilent Technologies, Palo Alto, CA), photodiode array detection monitored at 232 nm, and an isocratic mobile phase of water:acetonitrile (10:90) with a flow rate of 1.0 mL/minute. Analysis indicated one major peak and one impurity peak with an area equal to approximately 0.11% of the total integrated peak area. The overall purity of lot 48H1178 was determined to be greater than 99%.

### Ethanol

USP-grade 95% ethanol was obtained from Spectrum Chemicals and Laboratory Products (Gardena, CA) in one lot (NK0283) that was used in the 26- and 39-week dermal studies. Lot NK0283, a clear liquid, was identified as ethanol by the study laboratory using IR; the IR spectrum was consistent with a literature spectrum (Aldrich, 1985) of ethanol.

The purity of lot NK0283 was determined by the study laboratory using gas chromatography (GC). The analytical system used a Fisons gas chromatograph (Carlo Erba/Fisons, Ltd, Valencia, CA) with a DB-Wax column (30 m × 0.53 mm, 1.0-µm film thickness; Agilent Technologies, Palo Alto, CA), a flame ionization detector, helium carrier gas flowing at approximately 10 mL/minute, and an oven temperature program of 80° C for 5 minutes, then 10° C/minute to 220° C, and held for 3 minutes. Analysis indicated one major peak and no impurities with areas greater than or equal to 0.1% of the major peak. The overall purity of lot NK0283 was determined to be greater than 99%.

The purity of the bulk chemical was periodically monitored by the study laboratory during the studies using the GC system described above. No degradation of the ethanol was detected.

## Preparation and Analysis of Dose Formulations

### Dermal Studies

The dose formulations were prepared every 4 to 5 weeks by mixing sodium bromate and 40% USP-grade 95% ethanol/60% deionized water to give the required concentrations (Table G1). The dose formulations of sodium bromate were stored at room temperature in clear glass bottles for up to 35 days. A positive control dose formulation of TPA was prepared twice during the studies by adding the appropriate amount of TPA to acetone; the formulations were stored at approximately 5° C in amber glass bottles for up to 6 months.

Stability studies of a 5.67 mg/mL dose formulation were conducted by RTI using IC by a system similar to that described for purity determination. Stability was confirmed for at least 35 days for dose formulations stored in 100 mL glass bottles at temperatures up to ambient, for at least 3 hours for dose formulations stored in capped, partially filled clear glass scintillation vials, and for at least 24 hours for dose formulations stored exposed to light and air at 25° C to 30° C followed by resolubilization in 40% USP-grade 95% ethanol/60% deionized water. Stability studies of a positive control dose formulation of TPA were conducted by RTI using HPLC by a system similar to that described for purity determination. Stability was confirmed for at least 6 months for formulations stored in amber glass bottles at approximately 5° C.

Periodic analyses of the dose formulations of sodium bromate were conducted by the study laboratory using IC by a system similar to that described for purity determination. During the 26- and 39-week studies, dose formulations were analyzed four times; all 12 of the dose formulations for Tg.AC hemizygous mice were within 10% of the target concentrations (Table G2). Animal room samples of these dose formulations were also analyzed; four of six animal room samples were within 10% of the target concentrations.

### Drinking Water Studies

The dose formulations were prepared every 2 to 5 weeks by adding a specified amount of sodium bromate to tap water in a calibrated NALGENE^®^ tank and stirring with an overhead drum stirrer until dissolved (Table G1). The dose formulations of sodium bromate were stored at room temperature for up to 35 days in the NALGENE^®^ tanks in which they were mixed. A positive control dose formulation of TPA was prepared and stored as described for the dermal studies.

Stability studies of a 5.67 mg/mL dose formulation were conducted by RTI using IC by a system similar to that described for purity determination. Stability was confirmed for at least 35 days for dose formulations stored in 100 mL glass bottles at temperatures up to ambient, and for at least 7 days in partially filled 500 mL clear glass drinking bottles.

Periodic analyses of the dose formulations of sodium bromate were conducted by the study laboratory using an IC system similar to that described for analyses of the dermal formulations of the chemical except that a Dionex IonPac^®^ AS9SC column (200 mm × 4 mm) was used and the isocratic mobile phase was 5.4 mM sodium carbonate/0.6 mM sodium bicarbonate. During the 27- and 43-week studies, these dose formulations were analyzed four times; all 13 of the dose formulations for Tg.AC hemizygous and p53 haploinsufficient mice were within 10% of the target concentrations (Table G3). Animal room samples of these dose formulations were also analyzed; all 12 animal room samples (six for Tg.AC hemizygous mice and six for p53 haploinsufficient mice) were within 10% of the target concentrations. No sodium bromate was found in control formulations above a method detection limit of 0.45 mg/L.

FIGURE G1 Infrared Absorption Spectrum of Sodium Bromate

TABLE G1 Preparation and Storage of Dose Formulations in the Dermal and Drinking Water Studies of Sodium Bromate

Dermal Studies | Drinking Water Studies
Preparation
Sodium bromate: A specified amount of sodium bromate was added to 150 mL of deionized water in a 250 mL volumetric flask. The flask was sealed, shaken, and sonicated until sodium bromate was dissolved. The solution was diluted to volume with USP-grade 95% ethanol, sealed, shaken, and stirred with a stir bar for approximately 30 minutes and inverted at least 10 times. Dose formulations were prepared every 4 to 5 weeks. | Sodium bromate: A specified amount of sodium bromate was added to 48 or 120 L of tap water in a calibrated NALGENE^®^ tank and stirred with an overhead drum stirrer for 15 minutes or until the sodium bromate dissolved. Dose formulations were prepared every 2 to 5 weeks.
TPA: A 12.5 μg/mL formulation was prepared by diluting the appropriate amount of TPA in acetone. Formulations were prepared twice during the study. | TPA: A 12.5 μg/mL formulation was prepared by diluting the appropriate amount of TPA in acetone. Formulations were prepared twice during the studies.
Chemical Lot Number
Sodium bromate: 946272A | Sodium bromate: 946272A
TPA: 48H1178 | TPA: 48H1178
Maximum Storage Time
Sodium bromate: 35 days | Sodium bromate: 35 days
TPA: 6 months | TPA: 6 months
Storage Conditions
Sodium bromate: Formulations were transferred to 250-mL clear glass bottles, sealed with Teflon^®^-lined lids, and stored at room temperature. | Sodium bromate: Formulations remained in the NALGENE^®^ containers in which they were prepared; the lids were sealed with Parafilm or tape and the containers were stored at room temperature.
TPA: Stored in amber glass bottles sealed with Teflon^®^-lined lids and refrigerated at approximately 5° C. | TPA: Stored in amber glass bottles sealed with Teflon^®^-lined lids and refrigerated at approximately 5° C.
Study Laboratory
Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH)

TABLE G2 Results of Analyses of Dose Formulations Administered to Tg.AC Hemizygous Mice in the 26- and 39-Week Dermal Studies of Sodium Bromate

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
October 18, 1999 | October 19, 1999 | 19.4 | 19.54 | +1
October 18, 1999 | October 19, 1999 | 38.8 | 40.06 | +3
October 18, 1999 | October 19, 1999 | 77.6 | 75.10 | −3
October 18, 1999 | November 29–30, 1999^b^ | 19.4 | 22.15 | +14
October 18, 1999 | November 29–30, 1999^b^ | 38.8 | 46.09 | +19
October 18, 1999 | November 29–30, 1999^b^ | 77.6 | 72.14 | −7
January 10, 2000 | January 11, 2000 | 19.4 | 19.34 | 0
January 10, 2000 | January 11, 2000 | 38.8 | 39.56 | +2
January 10, 2000 | January 11, 2000 | 77.6 | 78.38 | +1
April 5, 2000 | April 6–7, 2000 | 19.4 | 18.74 | −3
April 5, 2000 | April 6–7, 2000 | 38.8 | 40.00 | +3
April 5, 2000 | April 6–7, 2000 | 77.6 | 71.22 | −8
June 26, 2000 | June 28, 2000 | 19.4 | 20.11 | +4
June 26, 2000 | June 28, 2000 | 38.8 | 39.52 | +2
June 26, 2000 | June 28, 2000 | 77.6 | 73.01 | −6
June 26, 2000 | August 2, 2000^b^ | 19.4 | 19.91 | +3
June 26, 2000 | August 2, 2000^b^ | 38.8 | 41.03 | +6
June 26, 2000 | August 2, 2000^b^ | 77.6 | 81.48 | +5

a Results of duplicate analyses. Dosing volume=3.3 mL/kg; 19.4 mg/mL=64 mg/kg, 38.8 mg/mL=128 mg/kg, 77.6 mg/mL=256 mg/kg.

b Animal room samples

TABLE G3 Results of Analyses of Dose Formulations Administered to Tg.AC Hemizygous Mice and p53 Haploinsufficient Mice in the 27- and 43-Week Drinking Water Studies of Sodium Bromate

Date Prepared | Date Analyzed | Target Concentration (mg/L) | Determined Concentration^a^ (mg/L) | Difference from Target (%)
Tg.AC Hemizygous Mice and p53 Haploinsufficient Mice
September 13, 1999 | September 16, 1999 | 80 | 75.08 | −6
September 13, 1999 | September 16, 1999 | 400 | 397.3 | −1
September 13, 1999 | September 16, 1999 | 800 | 807.2 | +1
December 7, 1999 | December 8, 1999 | 80 | 77.81 | −3
December 7, 1999 | December 8, 1999 | 400 | 403.2 | +1
December 7, 1999 | December 8, 1999 | 800 | 821.2 | +3
December 7, 1999 | December 8, 1999 | 800 | 816.1 | +2
February 29, 2000 | February 29, 2000 | 80 | 77.40 | −3
February 29, 2000 | February 29, 2000 | 400 | 408.9 | +2
February 29, 2000 | February 29, 2000 | 800 | 816.3 | +2
May 19, 2000 | May 24, 2000 | 80 | 78.29 | −2
May 19, 2000 | May 24, 2000 | 400 | 412.5 | +3
May 19, 2000 | May 24, 2000 | 800 | 825.8 | +3
Animal Room Samples
Tg.AC Hemizygous Mice
September 13, 1999 | October 19, 2000 | 80 | 73.51 | −8
September 13, 1999 | October 19, 2000 | 400 | 397.2 | −1
September 13, 1999 | October 19, 2000 | 800 | 797.4 | 0
May 19, 2000 | June 28–29, 2000 | 80 | 76.69 | −4
May 19, 2000 | June 28–29, 2000 | 400 | 413.7 | +3
May 19, 2000 | June 28–29, 2000 | 800 | 810.1 | +1
p53 Haploinsufficient Mice
September 13, 1999 | October 19, 1999 | 80 | 74.34 | −7
September 13, 1999 | October 19, 1999 | 400 | 397.4 | −1
September 13, 1999 | October 19, 1999 | 800 | 793.7 | −1
May 19, 2000 | June 28–29, 2000 | 80 | 76.21 | −5
May 19, 2000 | June 28–29, 2000 | 400 | 406.1 | +2
May 19, 2000 | June 28–29, 2000 | 800 | 806.2 | +1

a Results of duplicate analyses