# APPENDIX F ORGAN WEIGHTS AND ORGAN-WEIGHT-TO-BODY-WEIGHT RATIOS

TABLE F1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Sodium Bromate^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Male
n | 12 | 11 | 13 | 14
Necropsy body wt | 35.0 ± 1.9 | 35.8 ± 1.1 | 34.4 ± 1.1 | 32.1 ± 0.6
Heart
Absolute | 0.180 ± 0.007 | 0.171 ± 0.003 | 0.178 ± 0.004 | 0.168 ± 0.006
Relative | 5.198 ± 0.109 | 4.829 ± 0.129 | 5.240 ± 0.187 | 5.272 ± 0.132
R. Kidney
Absolute | 0.314 ± 0.011 | 0.337 ± 0.010 | 0.333 ± 0.010 | 0.352 ± 0.013
Relative | 9.104 ± 0.315 | 9.532 ± 0.410 | 9.770 ± 0.344 | 11.006 ± 0.305^**^
Liver
Absolute | 1.656 ± 0.093 | 1.663 ± 0.043 | 1.669 ± 0.051 | 1.702 ± 0.048
Relative | 47.362 ± 1.041 | 46.675 ± 0.877 | 48.668 ± 0.958 | 53.359 ± 0.954^**^
Lung
Absolute | 0.271 ± 0.015 | 0.302 ± 0.013 | 0.270 ± 0.017 | 0.251 ± 0.010
Relative | 7.924 ± 0.504 | 8.468 ± 0.312 | 7.918 ± 0.505 | 7.900 ± 0.359
R. Testis
Absolute | 0.088 ± 0.002 | 0.086 ± 0.002 | 0.081 ± 0.003 | 0.082 ± 0.002
Relative | 2.571 ± 0.112 | 2.409 ± 0.075 | 2.380 ± 0.102 | 2.600 ± 0.086
Thymus
Absolute | 0.031 ± 0.002 | 0.036 ± 0.004 | 0.029 ± 0.003 | 0.024 ± 0.002
Relative | 0.882 ± 0.035 | 0.998 ± 0.084 | 0.852 ± 0.061 | 0.768 ± 0.062
Female
n | 11 | 10 | 11 | 1
Necropsy body wt | 28.5 ± 1.6 | 28.6 ± 1.4 | 27.8 ± 0.8 | 28.5 ± 1.1
Heart
Absolute | 0.151 ± 0.005 | 0.143 ± 0.005 | 0.136 ± 0.003^*^ | 0.137 ± 0.004
Relative | 5.378 ± 0.175 | 5.046 ± 0.119 | 4.906 ± 0.133 | 4.857 ± 0.205
R. Kidney
Absolute | 0.211 ± 0.008 | 0.214 ± 0.008 | 0.207 ± 0.005 | 0.214 ± 0.006
Relative | 7.487 ± 0.141 | 7.527 ± 0.222 | 7.461 ± 0.191 | 7.556 ± 0.179
Liver
Absolute | 1.468 ± 0.082 | 1.447 ± 0.067 | 1.441 ± 0.039 | 1.445 ± 0.039
Relative | 51.575 ± 0.821 | 50.654 ± 0.670 | 51.897 ± 1.098 | 50.989 ± 1.135
Lung
Absolute | 0.259 ± 0.013 | 0.266 ± 0.014 | 0.271 ± 0.015 | 0.231 ± 0.004
Relative | 9.202 ± 0.405 | 9.321 ± 0.327 | 9.860 ± 0.682 | 8.196 ± 0.245
Thymus
Absolute | 0.035 ± 0.003 | 0.037 ± 0.003 | 0.029 ± 0.002 | 0.035 ± 0.002
Relative | 1.219 ± 0.054 | 1.292 ± 0.081 | 1.043 ± 0.070 | 1.210 ± 0.066

* Significantly different (P≤0.05) from the vehicle control group by Dunnett’s or Williams’ test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

TABLE F2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Sodium Bromate^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Male
n | 8 | 8 | 8 | 8
Necropsy body wt | 35.7 ± 2.0 | 35.3 ± 1.2 | 34.7 ± 1.1 | 32.3 ± 1.8
Heart
Absolute | 0.203 ± 0.009 | 0.191 ± 0.005 | 0.190 ± 0.006 | 0.176 ± 0.005^**^
Relative | 5.718 ± 0.196 | 5.452 ± 0.188 | 5.479 ± 0.182 | 5.528 ± 0.210
R. Kidney
Absolute | 0.346 ± 0.019 | 0.376 ± 0.010 | 0.391 ± 0.014 | 0.361 ± 0.022
Relative | 9.727 ± 0.364 | 10.697 ± 0.284^*^ | 11.264 ± 0.200^**^ | 11.176 ± 0.288^**^
Liver
Absolute | 1.871 ± 0.128 | 1.968 ± 0.062 | 2.040 ± 0.046 | 1.673 ± 0.106
Relative | 52.270 ± 1.637 | 55.959 ± 1.778 | 58.986 ± 1.307^*^ | 51.791 ± 1.794
Lung
Absolute | 0.246 ± 0.014 | 0.235 ± 0.011 | 0.259 ± 0.018 | 0.243 ± 0.015
Relative | 7.078 ± 0.623 | 6.687 ± 0.352 | 7.504 ± 0.551 | 7.590 ± 0.405
R. Testis
Absolute | 0.086 ± 0.004 | 0.079 ± 0.004 | 0.084 ± 0.007 | 0.065 ± 0.006^*^
Relative | 2.430 ± 0.144 | 2.281 ± 0.175 | 2.435 ± 0.210 | 2.020 ± 0.167
Thymus
Absolute | 0.024 ± 0.004 | 0.026 ± 0.003 | 0.022 ± 0.003 | 0.025 ± 0.002
Relative | 0.646 ± 0.086 | 0.737 ± 0.069 | 0.645 ± 0.099 | 0.766 ± 0.055
Female
n | 7 | 7 | 8 | 8
Necropsy body wt | 33.2 ± 2.2 | 28.5 ± 0.9 | 28.5 ± 2.0 | 29.4 ± 1.1
Heart
Absolute | 0.158 ± 0.008 | 0.153 ± 0.009 | 0.142 ± 0.006 | 0.147 ± 0.005
Relative | 4.800 ± 0.209 | 5.372 ± 0.244 | 5.056 ± 0.168 | 5.036 ± 0.197
R. Kidney
Absolute | 0.260 ± 0.008 | 0.233 ± 0.009 | 0.233 ± 0.009 | 0.231 ± 0.006^*^
Relative | 7.944 ± 0.423 | 8.177 ± 0.186 | 8.340 ± 0.330 | 7.862 ± 0.134
Liver
Absolute | 1.725 ± 0.095 | 1.551 ± 0.065 | 1.611 ± 0.118 | 1.692 ± 0.094
Relative | 52.362 ± 2.232 | 54.449 ± 1.879 | 56.697 ± 2.239 | 57.274 ± 1.488
Lung
Absolute | 0.223 ± 0.013 | 0.252 ± 0.019 | 0.221 ± 0.011 | 0.230 ± 0.010
Relative | 6.747 ± 0.276 | 8.911 ± 0.770^*^ | 8.003 ± 0.657 | 7.907 ± 0.504
Thymus
Absolute | 0.028 ± 0.003 | 0.031 ± 0.003 | 0.028 ± 0.004 | 0.029 ± 0.003
Relative | 0.843 ± 0.065 | 1.091 ± 0.077 | 0.972 ± 0.140 | 0.970 ± 0.058

* Significantly different (P≤0.05) from the vehicle control group by Dunnett’s or Williams’ test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

TABLE F3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Tg.AC Hemizygous Mice in the 27-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Male
n | 13 | 13 | 14 | 14
Necropsy body wt | 37.7 ± 1.5 | 38.9 ± 0.8 | 34.8 ± 1.5 | 32.4 ± 0.8^**^
Heart
Absolute | 0.180 ± 0.005 | 0.180 ± 0.003 | 0.168 ± 0.005 | 0.157 ± 0.004^**^
Relative | 4.825 ± 0.118 | 4.638 ± 0.069 | 4.879 ± 0.148 | 4.875 ± 0.118
R. Kidney
Absolute | 0.317 ± 0.009 | 0.341 ± 0.007 | 0.333 ± 0.015 | 0.323 ± 0.008
Relative | 8.482 ± 0.194 | 8.779 ± 0.166 | 9.559 ± 0.140^**^ | 9.998 ± 0.209^**^
Liver
Absolute | 1.812 ± 0.067 | 1.887 ± 0.045 | 1.794 ± 0.090 | 1.711 ± 0.029
Relative | 48.186 ± 0.749 | 48.455 ± 0.432 | 51.393 ± 1.015^*^ | 53.061 ± 0.990^**^
Lung
Absolute | 0.228 ± 0.008 | 0.230 ± 0.011 | 0.243 ± 0.008 | 0.234 ± 0.006
Relative | 6.125 ± 0.246 | 5.936 ± 0.306 | 7.177 ± 0.432^*^ | 7.306 ± 0.272^*^
R. Testis
Absolute | 0.085 ± 0.002 | 0.088 ± 0.002 | 0.086 ± 0.003 | 0.079 ± 0.003
Relative | 2.307 ± 0.094 | 2.274 ± 0.050 | 2.548 ± 0.140 | 2.464 ± 0.116
Thymus
Absolute | 0.042 ± 0.004 | 0.048 ± 0.004 | 0.035 ± 0.003 | 0.034 ± 0.004
Relative | 1.101 ± 0.081 | 1.205 ± 0.091 | 0.982 ± 0.082 | 1.028 ± 0.090
Female
n | 10 | 9 | 10 | 12
Necropsy body wt | 32.4 ± 1.8 | 31.3 ± 1.5 | 33.1 ± 1.4 | 27.0 ± 1.1^*^
Heart
Absolute | 0.160 ± 0.007 | 0.151 ± 0.005 | 0.150 ± 0.004 | 0.119 ± 0.006^**^
Relative | 5.012 ± 0.251 | 4.876 ± 0.123 | 4.590 ± 0.203 | 4.389 ± 0.182
R. Kidney
Absolute | 0.226 ± 0.005 | 0.221 ± 0.007 | 0.215 ± 0.006 | 0.203 ± 0.008^*^
Relative | 7.090 ± 0.318 | 7.179 ± 0.343 | 6.597 ± 0.289 | 7.560 ± 0.276
Liver
Absolute | 1.672 ± 0.038 | 1.574 ± 0.035 | 1.641 ± 0.053 | 1.638 ± 0.067
Relative | 52.309 ± 1.678 | 50.952 ± 1.738 | 50.135 ± 1.911 | 61.646 ± 3.457^*^
Lung
Absolute | 0.296 ± 0.009 | 0.308 ± 0.018 | 0.277 ± 0.014 | 0.263 ± 0.010
Relative | 9.307 ± 0.452 | 9.890 ± 0.405 | 8.595 ± 0.690 | 9.775 ± 0.252
Thymus
Absolute | 0.042 ± 0.004 | 0.040 ± 0.006 | 0.040 ± 0.003 | 0.032 ± 0.002
Relative | 1.303 ± 0.142 | 1.245 ± 0.139 | 1.209 ± 0.068 | 1.175 ± 0.065

* Significantly different (P≤0.05) from the control group by Dunnett’s or Williams’ test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

TABLE F4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Tg.AC Hemizygous Mice in the 43-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Male
n | 6 | 7 | 6 | 4
Necropsy body wt | 41.7 ± 2.3 | 41.7 ± 1.2 | 40.9 ± 2.2 | 28.4 ± 0.5^**^
Heart
Absolute | 0.200 ± 0.012 | 0.191 ± 0.006 | 0.193 ± 0.009 | 0.139 ± 0.012^**^
Relative | 4.822 ± 0.212 | 4.583 ± 0.088 | 4.738 ± 0.219 | 4.882 ± 0.355
R. Kidney
Absolute | 0.346 ± 0.014 | 0.366 ± 0.012 | 0.351 ± 0.016 | 0.267 ± 0.007^**^
Relative | 8.399 ± 0.507 | 8.814 ± 0.326 | 8.622 ± 0.250 | 9.406 ± 0.279
Liver
Absolute | 2.093 ± 0.127 | 2.127 ± 0.071 | 2.168 ± 0.119 | 1.751 ± 0.098
Relative | 50.149 ± 0.575 | 50.997 ± 0.699 | 53.035 ± 0.952 | 61.739 ± 3.539^**^
Lung
Absolute | 0.316 ± 0.029 | 0.246 ± 0.012^*^ | 0.254 ± 0.015 | 0.230 ± 0.015^*^
Relative | 7.651 ± 0.643 | 5.922 ± 0.296^*^ | 6.287 ± 0.483 | 8.079 ± 0.448
R. Testis
Absolute | 0.092 ± 0.003 | 0.091 ± 0.003 | 0.081 ± 0.006 | 0.053 ± 0.007^**^
Relative | 2.271 ± 0.205 | 2.194 ± 0.078 | 1.993 ± 0.164 | 1.869 ± 0.243
Thymus
Absolute | 0.035 ± 0.008 | 0.040 ± 0.002 | 0.033 ± 0.005 | 0.020 ± 0.002
Relative | 0.812 ± 0.165 | 0.961 ± 0.060 | 0.795 ± 0.106 | 0.696 ± 0.070
Female
n | 7 | 5 | 4 | 2
Necropsy body wt | 32.8 ± 2.6 | 31.2 ± 1.3 | 34.9 ± 2.4 | 22.6 ± 0.1
Heart
Absolute | 0.177 ± 0.014 | 0.145 ± 0.012 | 0.172 ± 0.011 | 0.096 ± 0.003^*^
Relative | 5.484 ± 0.425 | 4.635 ± 0.285 | 4.930 ± 0.059 | 4.235 ± 0.120
R. Kidney
Absolute | 0.243 ± 0.010 | 0.246 ± 0.010 | 0.248 ± 0.011 | 0.171 ± 0.006^**^
Relative | 7.562 ± 0.364 | 7.933 ± 0.411 | 7.151 ± 0.312 | 7.583 ± 0.249
Liver
Absolute | 1.787 ± 0.100 | 2.635 ± 0.875 | 1.996 ± 0.193 | 1.597 ± 0.036
Relative | 55.168 ± 2.344 | 83.674 ± 26.769 | 57.328 ± 4.792 | 70.795 ± 1.417
Lung
Absolute | 0.285 ± 0.030 | 0.247 ± 0.029 | 0.242 ± 0.005 | 0.193 ± 0.019
Relative | 8.864 ± 1.055 | 7.907 ± 0.886 | 7.022 ± 0.436 | 8.538 ± 0.839
Thymus
Absolute | 0.031 ± 0.003 | 0.030 ± 0.006 | 0.026 ± 0.004 | 0.022 ± 0.007
Relative | 0.945 ± 0.037 | 0.933 ± 0.174 | 0.736 ± 0.128 | 0.953 ± 0.286

* Significantly different (P≤0.05) from the control group by Dunnett’s or Williams’ test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

TABLE F5 Organ Weights and Organ-Weight-to-Body-Weight Ratios for p53 Haploinsufficient Mice in the 27-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Male
n | 14 | 14 | 14 | 14
Necropsy body wt | 47.7 ± 1.5 | 49.0 ± 0.9 | 47.8 ± 1.1 | 46.8 ± 1.1
Heart
Absolute | 0.206 ± 0.009 | 0.225 ± 0.007 | 0.213 ± 0.006 | 0.219 ± 0.007
Relative | 4.319 ± 0.124 | 4.593 ± 0.133 | 4.469 ± 0.111 | 4.694 ± 0.168
R. Kidney
Absolute | 0.279 ± 0.011 | 0.290 ± 0.011 | 0.291 ± 0.008 | 0.286 ± 0.010
Relative | 5.891 ± 0.250 | 5.906 ± 0.149 | 6.104 ± 0.166 | 6.092 ± 0.151
Liver
Absolute | 2.874 ± 0.212 | 3.022 ± 0.152 | 2.724 ± 0.154 | 2.555 ± 0.161
Relative | 59.352 ± 3.046 | 61.257 ± 2.287 | 56.591 ± 2.149 | 53.972 ± 2.262
Lung
Absolute | 0.268 ± 0.016 | 0.268 ± 0.012 | 0.277 ± 0.015 | 0.289 ± 0.018
Relative | 5.705 ± 0.404 | 5.489 ± 0.239 | 5.817 ± 0.309 | 6.246 ± 0.449
R. Testis
Absolute | 0.109 ± 0.003 | 0.111 ± 0.002 | 0.110 ± 0.002 | 0.111 ± 0.002
Relative | 2.317 ± 0.074 | 2.279 ± 0.038 | 2.303 ± 0.044 | 2.374 ± 0.061
Thymus
Absolute | 0.064 ± 0.004 | 0.065 ± 0.004 | 0.072 ± 0.004 | 0.064 ± 0.003
Relative | 1.340 ± 0.056 | 1.317 ± 0.069 | 1.527 ± 0.088 | 1.374 ± 0.060
Female
n | 14 | 15 | 15 | 14
Necropsy body wt | 36.0 ± 2.1 | 35.8 ± 1.7 | 33.7 ± 2.2 | 31.6 ± 1.4
Heart
Absolute | 0.160 ± 0.005 | 0.161 ± 0.004 | 0.161 ± 0.005 | 0.156 ± 0.004
Relative | 4.580 ± 0.225 | 4.591 ± 0.157 | 4.991 ± 0.296 | 4.999 ± 0.179
R. Kidney
Absolute | 0.194 ± 0.004 | 0.196 ± 0.006 | 0.204 ± 0.006 | 0.198 ± 0.005
Relative | 5.592 ± 0.309 | 5.563 ± 0.146 | 6.265 ± 0.269 | 6.348 ± 0.245
Liver
Absolute | 1.640 ± 0.074 | 1.594 ± 0.048 | 1.500 ± 0.068 | 1.498 ± 0.052
Relative | 46.062 ± 1.210 | 45.106 ± 1.012 | 45.241 ± 1.016 | 47.663 ± 0.903
Lung
Absolute | 0.270 ± 0.016 | 0.272 ± 0.016 | 0.271 ± 0.013 | 0.284 ± 0.012
Relative | 7.741 ± 0.567 | 7.848 ± 0.589 | 8.220 ± 0.332 | 9.118 ± 0.454
Thymus
Absolute | 0.056 ± 0.003 | 0.058 ± 0.003 | 0.061 ± 0.003 | 0.059 ± 0.003
Relative | 1.615 ± 0.097 | 1.672 ± 0.109 | 1.888 ± 0.104 | 1.881 ± 0.079

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

TABLE F6 Organ Weights and Organ-Weight-to-Body-Weight Ratios for p53 Haploinsufficient Mice in the 43-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Male
n | 9 | 8 | 8 | 9
Necropsy body wt | 50.7 ± 1.4 | 52.7 ± 1.2 | 51.0 ± 1.5 | 51.8 ± 1.4
Heart
Absolute | 0.249 ± 0.009 | 0.253 ± 0.009 | 0.285 ± 0.009^*^ | 0.237 ± 0.013
Relative | 4.939 ± 0.210 | 4.802 ± 0.143 | 5.633 ± 0.264 | 4.575 ± 0.228
R. Kidney
Absolute | 0.328 ± 0.017 | 0.312 ± 0.013 | 0.367 ± 0.022 | 0.327 ± 0.018
Relative | 6.461 ± 0.249 | 5.933 ± 0.235 | 7.173 ± 0.307 | 6.330 ± 0.359
Liver
Absolute | 3.353 ± 0.196 | 3.567 ± 0.163 | 3.240 ± 0.242 | 3.265 ± 0.222
Relative | 65.694 ± 2.560 | 67.629 ± 2.237 | 62.981 ± 3.408 | 62.754 ± 3.526
Lung
Absolute | 0.253 ± 0.022 | 0.256 ± 0.017 | 0.276 ± 0.018 | 0.233 ± 0.006
Relative | 4.981 ± 0.390 | 4.871 ± 0.334 | 5.377 ± 0.265 | 4.520 ± 0.149
R. Testis
Absolute | 0.106 ± 0.009 | 0.109 ± 0.005 | 0.117 ± 0.005 | 0.111 ± 0.004
Relative | 2.103 ± 0.182 | 2.071 ± 0.070 | 2.302 ± 0.107 | 2.140 ± 0.085
Thymus
Absolute | 0.046 ± 0.006 | 0.041 ± 0.003 | 0.040 ± 0.002 | 0.046 ± 0.004
Relative | 0.895 ± 0.097 | 0.776 ± 0.047 | 0.786 ± 0.047 | 0.880 ± 0.063
Female
n | 9 | 9 | 10 | 10
Necropsy body wt | 47.7 ± 2.8 | 45.7 ± 2.4 | 38.3 ± 2.7^*^ | 42.9 ± 2.1
Heart
Absolute | 0.191 ± 0.008 | 0.188 ± 0.008 | 0.203 ± 0.010 | 0.186 ± 0.008
Relative | 4.069 ± 0.189 | 4.211 ± 0.318 | 5.408 ± 0.254^**^ | 4.371 ± 0.159
R. Kidney
Absolute | 0.233 ± 0.005 | 0.234 ± 0.005 | 0.229 ± 0.008 | 0.225 ± 0.008
Relative | 5.015 ± 0.289 | 5.247 ± 0.332 | 6.207 ± 0.421^*^ | 5.301 ± 0.197
Liver
Absolute | 1.955 ± 0.073 | 1.840 ± 0.084 | 1.967 ± 0.163 | 1.895 ± 0.067
Relative | 41.507 ± 1.282 | 40.637 ± 1.450 | 54.271 ± 7.518 | 44.651 ± 1.461
Lung
Absolute | 0.240 ± 0.020 | 0.237 ± 0.011 | 0.254 ± 0.021 | 0.271 ± 0.014
Relative | 5.072 ± 0.313 | 5.347 ± 0.442 | 7.108 ± 1.025 | 6.417 ± 0.369
Thymus
Absolute | 0.048 ± 0.008 | 0.040 ± 0.003 | 0.121 ± 0.078 | 0.045 ± 0.004
Relative | 1.032 ± 0.180 | 0.907 ± 0.077 | 4.002 ± 2.890 | 1.045 ± 0.086

* Significantly different (P≤0.05) from the control group by Dunnett’s or Williams’ test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).