# APPENDIX E CLINICAL PATHOLOGY RESULTS

TABLE E1 Hematology Data for Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Sodium Bromate^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Male
n | 12 | 10 | 13 | 12
Hematocrit (%) | 42.9 ± 0.5 | 41.4 ± 0.7 | 41.9 ± 0.7 | 41.0 ± 0.6
Hemoglobin (g/dL) | 13.9 ± 0.2 | 13.2 ± 0.2 | 13.4 ± 0.2 | 13.0 ± 0.2^**^
Erythrocytes (10^6^/μL) | 9.91 ± 0.15 | 9.47 ± 0.17 | 9.65 ± 0.18 | 9.29 ± 0.18^*^
Reticulocytes (10^6^/μL) | 0.15 ± 0.02 | 0.19 ± 0.02 | 0.19 ± 0.01 | 0.22 ± 0.02^*^
Mean cell volume (fL) | 43.3 ± 0.4 | 43.8 ± 0.2 | 43.4 ± 0.3 | 44.2 ± 0.3
Mean cell hemoglobin (pg) | 14.0 ± 0.2 | 14.0 ± 0.1 | 13.9 ± 0.1 | 14.0 ± 0.2
Mean cell hemoglobin concentration (g/dL) | 32.3 ± 0.1 | 32.0 ± 0.1 | 32.1 ± 0.2 | 31.7 ± 0.3^*^
Platelets (10^3^/μL) | 1,038.2 ± 36.8 | 997.5 ± 26.1 | 1,117.9 ± 32.2 | 1,245.3 ± 70.5^*^
Leukocytes (10^3^/μL) | 3.31 ± 0.49 | 2.90 ± 0.41 | 3.91 ± 0.50 | 3.00 ± 0.37
Segmented neutrophils (10^3^/μL) | 1.08 ± 0.27 | 0.45 ± 0.07 | 0.98 ± 0.25 | 0.70 ± 0.17
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 2.13 ± 0.24 | 2.36 ± 0.34 | 2.76 ± 0.30 | 2.18 ± 0.3
Monocytes (10^3^/μL) | 0.05 ± 0.02 | 0.06 ± 0.02 | 0.15 ± 0.04 | 0.10 ± 0.03
Basophils (10^3^/μL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL) | 0.05 ± 0.02 | 0.03 ± 0.01 | 0.02 ± 0.01 | 0.03 ± 0.01
Female
n | 10 | 10 | 11 | 11
Hematocrit (%) | 43.4 ± 0.5 | 42.6 ± 0.5 | 41.0 ± 0.8^*^ | 41.1 ± 0.5^**^
Hemoglobin (g/dL) | 14.3 ± 0.1 | 13.8 ± 0.2 | 13.1 ± 0.3^**^ | 13.1 ± 0.1^**^
Erythrocytes (10^6^/μL) | 9.84 ± 0.19 | 9.55 ± 0.13 | 9.45 ± 0.31 | 9.67 ± 0.25
Reticulocytes (10^6^/μL) | 0.15 ± 0.01 | 0.19 ± 0.01 | 0.21 ± 0.02^*^ | 0.21 ± 0.02^*^
Mean cell volume (fL) | 44.1 ± 0.5 | 44.6 ± 0.2 | 43.6 ± 0.6 | 42.7 ± 0.7
Mean cell hemoglobin (pg) | 14.5 ± 0.2 | 14.5 ± 0.1 | 14.0 ± 0.2^*^ | 13.6 ± 0.2^**^
Mean cell hemoglobin concentration (g/dL) | 32.9 ± 0.1 | 32.5 ± 0.1^**^ | 32.0 ± 0.1^**^ | 31.8 ± 0.2^**^
Platelets (10^3^/μL) | 890.7 ± 38.8 | 918.3 ± 59.0 | 924.1 ± 54.9 | 1,024.6 ± 21.2
Leukocytes (10^3^/μL) | 5.26 ± 0.58 | 5.78 ± 0.47 | 5.01 ± 0.42 | 5.43 ± 0.27
Segmented neutrophils (10^3^/μL) | 1.39 ± 0.28 | 1.01 ± 0.10 | 1.19 ± 0.30 | 1.27 ± 0.18
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 3.68 ± 0.31 | 4.60 ± 0.38 | 3.62 ± 0.34 | 3.96 ± 0.23
Monocytes (10^3^/μL) | 0.12 ± 0.03 | 0.14 ± 0.04 | 0.14 ± 0.03 | 0.15 ± 0.02
Basophils (10^3^/μL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL) | 0.07 ± 0.03 | 0.03 ± 0.02 | 0.06 ± 0.02 | 0.05 ± 0.02

* Significantly different (P≤0.05) from the vehicle control group by Dunn’s or Shirley’s test

** P≤0.01

a Mean ± standard error. Statistical tests were performed on unrounded data.

TABLE E2 Hematology Data for Tg.AC Hemizygous Mice in the 27-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Male
n | 12 | 13 | 13 | 14
Hematocrit (%) | 40.8 ± 0.5 | 41.0 ± 0.4 | 40.1 ± 0.4 | 41.7 ± 0.4
Hemoglobin (g/dL) | 13.3 ± 0.2 | 13.2 ± 0.1 | 12.8 ± 0.2^*^ | 13.0 ± 0.2
Erythrocytes (10^6^/μL) | 9.31 ± 0.15 | 9.40 ± 0.13 | 9.13 ± 0.12 | 9.56 ± 0.08
Reticulocytes (10^6^/μL) | 0.14 ± 0.01 | 0.15 ± 0.01 | 0.19 ± 0.01^**^ | 0.24 ± 0.02^**^
Mean cell volume (fL) | 43.9 ± 0.2 | 43.6 ± 0.3 | 44.0 ± 0.3 | 43.7 ± 0.3
Mean cell hemoglobin (pg) | 14.3 ± 0.1 | 14.1 ± 0.1 | 14.0 ± 0.1^*^ | 13.6 ± 0.1^**^
Mean cell hemoglobin concentration (g/dL) | 32.5 ± 0.1 | 32.3 ± 0.0^*^ | 31.9 ± 0.1^**^ | 31.1 ± 0.2^**^
Platelets (10^3^/μL) | 1,272.7 ± 47.3 | 1,229.4 ± 30.9 | 1,248.5 ± 22.5 | 1,269.4 ± 22.8
Leukocytes (10^3^/μL) | 5.25 ± 0.24 | 4.32 ± 0.34 | 4.51 ± 0.55 | 4.96 ± 0.46
Segmented neutrophils (10^3^/μL) | 1.12 ± 0.17 | 0.75 ± 0.08 | 1.13 ± 0.44 | 1.14 ± 0.45
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 4.08 ± 0.24 | 3.52 ± 0.27 | 3.32 ± 0.19 | 3.74 ± 0.22
Monocytes (10^3^/μL) | 0.02 ± 0.01 | 0.01 ± 0.01 | 0.04 ± 0.02 | 0.06 ± 0.06
Basophils (10^3^/μL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL) | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.02 ± 0.01 | 0.02 ± 0.01
Female
n | 10 | 9 | 9 | 12
Hematocrit (%) | 44.4 ± 0.7 | 44.5 ± 0.7 | 42.4 ± 0.8 | 41.4 ± 0.6^**^
Hemoglobin (g/dL) | 14.4 ± 0.2 | 14.5 ± 0.3 | 13.6 ± 0.3 | 13.0 ± 0.2
Erythrocytes (10^6^/μL) | 10.11 ± 0.18 | 9.96 ± 0.20 | 9.50 ± 0.29^*^ | 9.12 ± 0.21^**^
Reticulocytes (10^6^/μL) | 0.14 ± 0.01 | 0.15 ± 0.02 | 0.17 ± 0.02 | 0.33 ± 0.04^*^
Mean cell volume (fL) | 44.0 ± 0.5 | 44.7 ± 0.5 | 44.8 ± 0.6 | 45.5 ± 0.5
Mean cell hemoglobin (pg) | 14.3 ± 0.2 | 14.6 ± 0.2 | 14.4 ± 0.2 | 14.2 ± 0.2
Mean cell hemoglobin concentration (g/dL) | 32.4 ± 0.2 | 32.6 ± 0.1 | 32.0 ± 0.1 | 31.3 ± 0.1^**^
Platelets (10^3^/μL) | 877.7 ± 26.8 | 933.2 ± 68.9 | 977.6 ± 44.3 | 1,110.3 ± 59.1^**^
Leukocytes (10^3^/μL) | 6.08 ± 0.68 | 5.52 ± 0.34 | 5.16 ± 0.35 | 6.63 ± 0.39
Segmented neutrophils (10^3^/μL) | 1.38 ± 0.51 | 1.01 ± 0.26 | 0.8 ± 0.12 | 1.47 ± 0.33
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 4.58 ± 0.48 | 4.42 ± 0.32 | 4.35 ± 0.29 | 5.04 ± 0.30
Monocytes (10^3^/μL) | 0.04 ± 0.02 | 0.05 ± 0.02 | 0.01 ± 0.01 | 0.09 ± 0.03
Basophils (10^3^/μL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL) | 0.08 ± 0.03 | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.03 ± 0.01

* Significantly different (P≤0.05) from the vehicle control group by Dunn’s or Shirley’s test

** P≤0.01

a Mean ± standard error. Statistical tests were performed on unrounded data.

TABLE E3 Hematology Data for p53 Haploinsufficient Mice in the 27-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Male
n | 14 | 14 | 13 | 14
Hematocrit (%) | 46.7 ± 0.4 | 47.5 ± 0.2 | 46.4 ± 0.6 | 47.5 ± 0.7
Hemoglobin (g/dL) | 15.2 ± 0.1 | 15.4 ± 0.1 | 14.9 ± 0.2 | 15.2 ± 0.2
Erythrocytes (10^6^/μL) | 10.41 ± 0.13 | 10.52 ± 0.08 | 10.33 ± 0.12 | 10.87 ± 0.19^*^
Reticulocytes (10^6^/μL) | 0.15 ± 0.01 | 0.16 ± 0.01 | 0.17 ± 0.02 | 0.20 ± 0.01^*^
Mean cell volume (fL) | 44.9 ± 0.3 | 45.2 ± 0.2 | 44.9 ± 0.2 | 43.8 ± 0.3
Mean cell hemoglobin (pg) | 14.6 ± 0.1 | 14.6 ± 0.1 | 14.4 ± 0.1 | 14.0 ± 0.1^**^
Mean cell hemoglobin concentration (g/dL) | 32.5 ± 0.1 | 32.5 ± 0.1 | 32.1 ± 0.1 | 32.0 ± 0.1^**^
Platelets (10^3^/μL) | 986.0 ± 16.5 | 962.0 ± 19.6 | 974.9 ± 43.0 | 966.4 ± 31.8
Leukocytes (10^3^/μL) | 7.79 ± 0.39 | 7.07 ± 0.25 | 7.18 ± 0.37 | 7.60 ± 0.40
Segmented neutrophils (10^3^/μL) | 1.04 ± 0.15 | 0.88 ± 0.07 | 0.92 ± 0.06 | 0.88 ± 0.09
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 6.67 ± 0.30 | 6.12 ± 0.27 | 6.15 ± 0.40 | 6.62 ± 0.35
Monocytes (10^3^/μL) | 0.02 ± 0.01 | 0.01 ± 0.01 | 0.04 ± 0.01 | 0.04 ± 0.01
Basophils (10^3^/μL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL) | 0.06 ± 0.02 | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.06 ± 0.01
Female
n | 14 | 15 | 15 | 14
Hematocrit (%) | 46.1 ± 0.4 | 47.2 ± 0.4 | 48.0 ± 0.6^*^ | 47.0 ± 0.4
Hemoglobin (g/dL) | 14.8 ± 0.1 | 15.2 ± 0.1 | 15.3 ± 0.2^*^ | 15.0 ± 0.2
Erythrocytes (10^6^/μL) | 10.25 ± 0.09 | 10.49 ± 0.08 | 10.76 ± 0.13^**^ | 10.72 ± 0.09^**^
Reticulocytes (10^6^/μL) | 0.20 ± 0.01 | 0.18 ± 0.01 | 0.17 ± 0.01 | 0.20 ± 0.01
Mean cell volume (fL) | 45.0 ± 0.2 | 44.9 ± 0.1 | 44.7 ± 0.2 | 43.9 ± 0.2^**^
Mean cell hemoglobin (pg) | 14.4 ± 0.1 | 14.5 ± 0.1 | 14.3 ± 0.0 | 14.0 ± 0.1^**^
Mean cell hemoglobin concentration (g/dL) | 32.0 ± 0.1 | 32.3 ± 0.1 | 32.0 ± 0.1 | 31.8 ± 0.1
Platelets (10^3^/μL) | 908.6 ± 17.9 | 883.1 ± 24.8 | 901.8 ± 55.4 | 948.6 ± 57.6
Leukocytes (10^3^/μL) | 4.07 ± 0.28 | 4.41 ± 0.34 | 4.04 ± 0.26 | 4.06 ± 0.32
Segmented neutrophils (10^3^/μL) | 0.36 ± 0.03 | 0.45 ± 0.06 | 0.35 ± 0.03 | 0.32 ± 0.04
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 3.68 ± 0.28 | 3.92 ± 0.30 | 3.64 ± 0.25 | 3.72 ± 0.3
Monocytes (10^3^/μL) | 0.02 ± 0.01 | 0.01 ± 0.01 | 0.02 ± 0.01 | 0.01 ± 0.0
Basophils (10^3^/μL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL) | 0.02 ± 0.01 | 0.04 ± 0.02 | 0.04 ± 0.01 | 0.02 ± 0.01

* Significantly different (P≤0.05) from the vehicle control group by Dunn’s or Shirley’s test

** P≤0.01

a Statistical tests were performed on unrounded data.