# APPENDIX D GENETIC TOXICOLOGY

TABLE D1 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Tg.AC Hemizygous Mice Following Dermal Administration of Sodium Bromate for 26 Weeks^a^

| Concentration (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)
Male
Ethanol/water^d^ | | 12 | 0.92 ± 0.16 | | 3.000 ± 0.25
Sodium bromate | 64 | 11 | 2.14 ± 0.20 | 0.0004 | 3.727 ± 0.24
Sodium bromate | 128 | 13 | 4.42 ± 0.39 | 0.0000 | 4.692 ± 0.26
Sodium bromate | 256 | 15 | 5.20 ± 0.42 | 0.0000 | 5.000 ± 0.43
| | | P=0.000^e^ | | P<0.001^f^
Female
Ethanol/water | | 10 | 1.45 ± 0.31 | | 3.900 ± 0.23
Sodium bromate | 64 | 10 | 2.60 ± 0.31 | 0.0053 | 4.200 ± 0.29
Sodium bromate | 128 | 11 | 3.00 ± 0.44 | 0.0004 | 4.818 ± 0.42
Sodium bromate | 256 | 11 | 4.09 ± 0.46 | 0.0000 | 5.000 ± 0.43
| | | P=0.000 | | P=0.126

a Study was performed at SITEK Research Laboratories, Inc. The detailed protocol is presented by MacGregor et al. (1990). NCE=normochromatic erythrocyte; PCE=polychromatic erythrocyte

b Mean ± standard error

c Pairwise comparison with the vehicle control, significant at P≤0.008 (ILS, 1990)

d Vehicle control (40% USP-grade 95% ethanol/60% water)

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)

f Significance of percent PCEs tested by ANOVA using individual animal data

TABLE D2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Tg.AC Hemizygous Mice Following Administration of Sodium Bromate in Drinking Water for 27 Weeks^a^

| Concentration (mg/L) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)
Male
Tap water^d^ | | 13 | 1.42 ± 0.18 | | 3.231 ± 0.17
Sodium bromate | 80 | 13 | 1.58 ± 0.26 | 0.3252 | 3.538 ± 0.24
Sodium bromate | 400 | 14 | 1.96 ± 0.26 | 0.0638 | 3.929 ± 0.22
Sodium bromate | 800 | 14 | 5.25 ± 0.73 | 0.0000 | 5.357 ± 0.45
| | | P=0.000^e^ | | P<0.001^f^
Female
Tap water | | 10 | 1.25 ± 0.40 | | 3.800 ± 0.20
Sodium bromate | 80 | 9 | 1.61 ± 0.23 | 0.1754 | 4.444 ± 0.24
Sodium bromate | 400 | 10 | 3.30 ± 0.35 | 0.0000 | 5.200 ± 0.44
Sodium bromate | 800 | 12 | 7.75 ± 1.35 | 0.0000 | 7.833 ± 0.67
| | | P=0.000 | | P<0.001

a Study was performed at SITEK Research Laboratories, Inc. The detailed protocol is presented by MacGregor et al. (1990). NCE=normochromatic erythrocyte; PCE=polychromatic erythrocyte

b Mean ± standard error

c Pairwise comparison with the untreated control, significant at P≤0.008 (ILS, 1990)

d Untreated control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)

f Significance of percent PCEs tested by ANOVA using individual animal data

TABLE D3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of p53 Haploinsufficient Mice Following Administration of Sodium Bromate in Drinking Water for 27 Weeks^a^

| Concentration (mg/L) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)
Male
Tap water^d^ | | 14 | 1.54 ± 0.24 | | 3.357 ± 0.20
Sodium bromate | 80 | 14 | 1.79 ± 0.31 | 0.2338 | 3.143 ± 0.21
Sodium bromate | 400 | 14 | 2.29 ± 0.41 | 0.0211 | 3.571 ± 0.42
Sodium bromate | 800 | 14 | 3.86 ± 0.25 | 0.0000 | 4.000 ± 0.36
| | | P=0.000^e^ | | P=0.246^f^
Female
Tap water | | 14 | 1.18 ± 0.18 | | 3.071 ± 0.16
Sodium bromate | 80 | 15 | 1.47 ± 0.23 | 0.1705 | 3.133 ± 0.22
Sodium bromate | 400 | 15 | 1.97 ± 0.22 | 0.0086 | 3.400 ± 0.13
Sodium bromate | 800 | 14 | 3.57 ± 0.25 | 0.0000 | 3.357 ± 0.17
| | | P=0.000 | | P=0.628

a Study was performed at SITEK Research Laboratories, Inc. The detailed protocol is presented by MacGregor et al. (1990). NCE=normochromatic erythrocyte; PCE=polychromatic erythrocyte

b Mean ± standard error

c Pairwise comparison with the untreated control, significant at P≤0.008 (ILS, 1990)

d Untreated control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)

f Significance of percent PCEs tested by ANOVA using individual animal data