# APPENDIX C SUMMARY OF LESIONS IN p53 HAPLOINSUFFICIENT MICE IN THE DRINKING WATER STUDIES OF SODIUM BROMATE

TABLE C1 Summary of the Incidence of Neoplasms in Male p53 Haploinsufficient Mice in the 27-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | | 1 | 1
Natural deaths | 1 | | | 1
Survivors
Terminal sacrifice | 14 | 14 | 14 | 14
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Intestine large, cecum | (15) | (15) | (15) | (15)
Polyp adenomatous | | | 1 (7%)
Intestine small, jejunum | (15) | (15) | (15) | (15)
Carcinoma | | | | 1 (7%)
Liver | (15) | (15) | (15) | (15)
Mesentery | (1) | (1)
Salivary glands | | (1)
Endocrine System
Adrenal cortex | (14) | (15) | (15) | (15)
Adrenal medulla | (14) | (15) | (15) | (15)
Pituitary gland | (15) | (15) | (15) | (15)
Thyroid gland | (15) | (15) | (15) | (15)
Hematopoietic System
Lymph node | (1)
Lymph node, mandibular | (15) | (15) | (15) | (15)
Lymph node, mesenteric | (15) | (15) | (15) | (15)
Spleen | (15) | (15) | (15) | (15)
Thymus | (14) | (15) | (15) | (15)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Trachea | | (1)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15)
Lymphoma malignant | 1 (7%) | 1 (7%) | 1 (7%) | 1 (7%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Genital System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 1 | 1 | 2 | 2
Total primary neoplasms | 1 | 1 | 2 | 2
Total animals with benign neoplasms | | | 1
Total benign neoplasms | | | 1
Total animals with malignant neoplasms | 1 | 1 | 1 | 2
Total malignant neoplasms | 1 | 1 | 1 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE C2 Summary of the Incidence of Nonneoplastic Lesions in Male p53 Haploinsufficient Mice in the 27-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | | 1 | 1
Natural deaths | 1 | | | 1
Survivors
Terminal sacrifice | 14 | 14 | 14 | 14
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | 1 (7%)
Inflammation, chronic active | 12 (80%) | 12 (80%) | 10 (67%) | 14 (93%)
Hepatocyte, fatty change | 10 (67%) | 13 (87%) | 10 (67%) | 8 (53%)
Hepatocyte, vacuolization cytoplasmic | 13 (87%) | 14 (93%) | 12 (80%) | 14 (93%)
Stomach, forestomach | (15) | (15) | (15) | (14)
Epithelium, hyperplasia | 3 (20%) | 3 (20%) | 1 (7%) | 3 (21%)
Endocrine System
Adrenal cortex | (14) | (15) | (15) | (15)
Accessory adrenal cortical nodule | | 1 (7%)
Hypertrophy | 1 (7%) | | 2 (13%)
Subcapsular, hyperplasia | 1 (7%) | 2 (13%) | 2 (13%) | 3 (20%)
Pituitary gland | (15) | (15) | (15) | (15)
Pars distalis, cyst | 4 (27%) | 1 (7%) | 3 (20%) | 3 (20%)
Pars distalis, hyperplasia | 2 (13%)
Thyroid gland | (15) | (15) | (15) | (15)
Ectopic thymus | | | 1 (7%) | 1 (7%)
Infiltration cellular, lymphocyte | 1 (7%) | 1 (7%) | 1 (7%)
Genital System
Epididymis | (15) | (15) | (15) | (15)
Degeneration | 1 (7%)
Granuloma sperm | | | 1 (7%)
Testes | (15) | (15) | (15) | (15)
Cyst | 1 (7%)
Mineralization | 1 (7%)
Germinal epithelium, degeneration | 6 (40%) | 3 (20%) | 3 (20%) | 2 (13%)
Hematopoietic System
Lymph node, mandibular | (15) | (15) | (15) | (15)
Hyperplasia, lymphoid | 1 (7%) | 2 (13%) | 1 (7%)
Spleen | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | 1 (7%) | | 1 (7%)
Thymus | (14) | (15) | (15) | (15)
Cyst | 7 (50%) | 6 (40%) | 2 (13%) | 2 (13%)
Ectopic parathyroid gland | 1 (7%)
Ectopic thyroid | 1 (7%)
Hyperplasia, lymphoid | | | 1 (7%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Inflammation, chronic active | 2 (13%) | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Nephropathy | 5 (33%) | 7 (47%) | 3 (20%) | 3 (20%)
Systems Examined with No Nonneoplastic Lesions Observed
Cardiovascular System
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE C3 Summary of the Incidence of Neoplasms in Female p53 Haploinsufficient Mice in the 27-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Natural deaths | 1 | | | 1
Survivors
Terminal sacrifice | 14 | 15 | 15 | 14
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Hemangiosarcoma, metastatic, mesentery | | | | 1 (7%)
Mesentery | | | | (1)
Hemangiosarcoma | | | | 1 (100%)
Genital System
Uterus | (15) | (15) | (15) | (15)
Polyp stromal | 1 (7%) | 1 (7%) | 1 (7%)
Hematopoietic System
Lymph node, mandibular | (15) | (15) | (15) | (15)
Lymph node, mesenteric | (14) | (12) | (14) | (14)
Spleen | (15) | (15) | (15) | (15)
Thymus | (15) | (15) | (15) | (15)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15)
Lymphoma malignant | 1 (7%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 2 | 1 | 1 | 1
Total primary neoplasms | 2 | 1 | 1 | 1
Total animals with benign neoplasms | 1 | 1 | 1
Total benign neoplasms | 1 | 1 | 1
Total animals with malignant neoplasms | 1 | | | 1
Total malignant neoplasms | 1 | | | 1
Total animals with metastatic neoplasms | | | | 1
Total metastatic neoplasms | | | | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE C4 Summary of the Incidence of Nonneoplastic Lesions in Female p53 Haploinsufficient Mice in the 27-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Natural deaths | 1 | | | 1
Survivors
Terminal sacrifice | 14 | 15 | 15 | 14
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Intestine small, jejunum | (15) | (15) | (15) | (15)
Diverticulum | | | 1 (7%)
Liver | (15) | (15) | (15) | (15)
Angiectasis | | | | 1 (7%)
Hematopoietic cell proliferation | | | | 1 (7%)
Inflammation, chronic active | 14 (93%) | 13 (87%) | 14 (93%) | 14 (93%)
Hepatocyte, fatty change | 1 (7%)
Hepatocyte, vacuolization cytoplasmic | 13 (87%) | 14 (93%) | 12 (80%) | 12 (80%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Inflammation | | | | 1 (7%)
Inflammation, chronic active | 1 (7%)
Epithelium, hyperplasia | 4 (27%) | 1 (7%) | 2 (13%) | 2 (13%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Accessory adrenal cortical nodule | 1 (7%)
Subcapsular, hyperplasia | 13 (87%) | 12 (80%) | 13 (87%) | 14 (93%)
Parathyroid gland | (1) | | (1)
Cyst | 1 (100%) | | 1 (100%)
Pituitary gland | (15) | (15) | (15) | (15)
Pars distalis, cyst | | | | 1 (7%)
Pars distalis, hyperplasia | | | 1 (7%) | 1 (7%)
Thyroid gland | (15) | (15) | (15) | (15)
Ectopic thymus | 1 (7%) | 2 (13%) | 2 (13%)
Infiltration cellular, lymphocyte | | 1 (7%) | 2 (13%)
Follicle, depletion secretory | | | | 2 (13%)
Follicular cell, hypertrophy | | | | 2 (13%)
Genital System
Ovary | (15) | (15) | (15) | (15)
Cyst | 1 (7%) | 1 (7%) | 2 (13%) | 1 (7%)
Uterus | (15) | (15) | (15) | (15)
Inflammation, suppurative | 1 (7%) | | 1 (7%)
Endometrium, hyperplasia, cystic | 11 (73%) | 10 (67%) | 10 (67%) | 10 (67%)
Hematopoietic System
Lymph node, mandibular | (15) | (15) | (15) | (15)
Hyperplasia, lymphoid | | 2 (13%) | 1 (7%) | 1 (7%)
Spleen | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | 1 (7%) | | 2 (13%) | 1 (7%)
Thymus | (15) | (15) | (15) | (15)
Atrophy | | | | 1 (7%)
Cyst | 4 (27%) | 7 (47%) | 12 (80%) | 3 (20%)
Ectopic parathyroid gland | | 2 (13%) | 1 (7%) | 2 (13%)
Ectopic thyroid | | | | 2 (13%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Inflammation, chronic active | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Hydronephrosis | | | | 1 (7%)
Nephropathy | | | 2 (13%) | 2 (13%)
Systems Examined with No Nonneoplastic Lesions Observed
Cardiovascular System
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE C5 Summary of the Incidence of Neoplasms in Male p53 Haploinsufficient Mice in the 43-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 1 | 2
Natural deaths | | | 2 | 1
Survivors
Terminal sacrifice | 9 | 8 | 8 | 9
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Hemangiosarcoma | | 1 (10%)
Hepatocellular adenoma | | | 1 (10%)
Osteosarcoma, metastatic, bone | 1 (10%)
Mesentery | (1)
Fat, osteosarcoma, metastatic, bone | 1 (100%)
Hematopoietic System
Thymus | (10) | (10) | (10) | (10)
Integumentary System
Skin | (1) | (1)
Subcutaneous tissue, osteosarcoma, metastatic, bone | 1 (100%)
Musculoskeletal System
Bone | (1)
Humerus, osteosarcoma | 1 (100%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Osteosarcoma, metastatic, bone | 1 (10%)
Urinary System
Kidney | (10) | (10) | (9) | (10)
Osteosarcoma, metastatic, bone | 1 (10%)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Lymphoma malignant | | 2 (20%) | | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Genital System
Nervous System
Special Senses System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 1 | 3 | 1 | 1
Total primary neoplasms | 1 | 3 | 1 | 1
Total animals with benign neoplasms | | | 1
Total benign neoplasms | | | 1
Total animals with malignant neoplasms | 1 | 3 | | 1
Total malignant neoplasms | 1 | 3 | | 1
Total animals with metastatic neoplasms | 1
Total metastatic neoplasms | 5

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE C6 Summary of the Incidence of Nonneoplastic Lesions in Male p53 Haploinsufficient Mice in the 43-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 1 | 2
Natural deaths | | | 2 | 1
Survivors
Terminal sacrifice | 9 | 8 | 8 | 9
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Infiltration cellular, mononuclear cell | | | | 1 (10%)
Inflammation, chronic active | 9 (90%) | 6 (60%) | 8 (80%) | 9 (90%)
Hepatocyte, fatty change | 7 (70%) | 9 (90%) | 9 (90%) | 6 (60%)
Hepatocyte, necrosis | 1 (10%)
Hepatocyte, vacuolization cytoplasmic | 9 (90%) | 9 (90%) | 10 (100%) | 10 (100%)
Salivary glands | | | | (1)
Duct, hyperplasia | | | | 1 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Inflammation, chronic active | 1 (10%) | 2 (20%)
Epithelium, hyperkeratosis | 1 (10%) | 3 (30%) | 1 (10%)
Epithelium, hyperplasia | 2 (20%) | 4 (40%) | | 3 (30%)
Epithelium, ulcer | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Accessory adrenal cortical nodule | | | 1 (10%) | 1 (10%)
Hyperplasia | | | 1 (10%)
Hypertrophy | 1 (10%) | 1 (10%) | 1 (10%) | 3 (30%)
Inflammation, chronic active | | 1 (10%)
Subcapsular, hyperplasia | 3 (30%) | 3 (30%) | 2 (20%) | 3 (30%)
Pituitary gland | (10) | (9) | (10) | (9)
Pars distalis, cyst | 3 (30%) | 1 (11%) | 3 (30%) | 1 (11%)
Pars distalis, hyperplasia | | | 1 (10%)
Thyroid gland | (10) | (10) | (10) | (9)
Infiltration cellular, lymphocyte | 1 (10%)
Genital System
Epididymis | (10) | (10) | (10) | (10)
Atrophy | 1 (10%)
Degeneration | | 2 (20%)
Infiltration cellular, lymphocyte | | | | 2 (20%)
Inflammation, chronic active | | 2 (20%)
Testes | (10) | (10) | (10) | (10)
Mineralization | | 2 (20%)
Germinal epithelium, degeneration | 2 (20%) | 4 (40%) | 5 (50%) | 1 (10%)
Germinal epithelium, necrosis | 1 (10%)
Hematopoietic System
Lymph node | (1) | | | (1)
Bronchial, hyperplasia | 1 (100%)
Mediastinal, hyperplasia, lymphoid | | | | 1 (100%)
Lymph node, mandibular | (10) | (10) | (10) | (10)
Hyperplasia, lymphoid | 1 (10%) | | 2 (20%) | 1 (10%)
Lymph node, mesenteric | (10) | (10) | (10) | (10)
Hyperplasia, lymphoid | | | 1 (10%) | 2 (20%)
Spleen | (10) | (10) | (9) | (10)
Atrophy | | | 1 (11%)
Hematopoietic cell proliferation | 1 (10%) | 1 (10%)
Thymus | (10) | (10) | (10) | (10)
Atrophy | 1 (10%) | | 1 (10%) | 1 (10%)
Cyst | 5 (50%) | 4 (40%) | 2 (20%) | 7 (70%)
Ectopic parathyroid gland | | | | 1 (10%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Hemorrhage | 1 (10%)
Inflammation, chronic active | | | 1 (10%)
Urinary System
Kidney | (10) | (10) | (9) | (10)
Infarct | 1 (10%)
Mineralization | | | 1 (11%)
Nephropathy | 9 (90%) | 7 (70%) | 7 (78%) | 7 (70%)
Cortex, mineralization | | | 1 (11%)
Papilla, mineralization | | 1 (10%) | | 1 (10%)
Pelvis, dilatation | | | | 1 (10%)
Systems Examined with No Nonneoplastic Lesions Observed
Cardiovascular System
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE C7 Summary of the Incidence of Neoplasms in Female p53 Haploinsufficient Mice in the 43-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | | 1
Natural deaths | 1
Survivors
Terminal sacrifice | 9 | 9 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Pancreas | | (1)
Acinus, carcinoma | | 1 (100%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Adrenal medulla | (10) | (10) | (10) | (10)
Pituitary gland | (10) | (10) | (10) | (10)
Pars distalis, adenoma | | 1 (10%)
Thyroid gland | (10) | (10) | (10) | (10)
Follicular cell, adenoma | | 1 (10%)
Genital System
Ovary | (10) | (10) | (10) | (10)
Cystadenoma | 1 (10%)
Hematopoietic System
Lymph node | (1) | | (1)
Lymph node, mandibular | (10) | (10) | (10) | (10)
Lymph node, mesenteric | (10) | (10) | (10) | (10)
Spleen | (10) | (10) | (10) | (10)
Thymus | (10) | (10) | (10) | (10)
Integumentary System
Skin | | (1) | (1) | (1)
Squamous cell carcinoma | | | 1 (100%)
Subcutaneous tissue, lipoma | | | | 1 (100%)
Respiratory System
Lung | (10) | (10) | (10) | (9)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Lymphoma malignant | 2 (20%) | | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 3 | 3 | 2 | 1
Total primary neoplasms | 3 | 3 | 2 | 1
Total animals with benign neoplasms | 1 | 2 | | 1
Total benign neoplasms | 1 | 2 | | 1
Total animals with malignant neoplasms | 2 | 1 | 2
Total malignant neoplasms | 2 | 1 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE C8 Summary of the Incidence of Nonneoplastic Lesions in Female p53 Haploinsufficient Mice in the 43-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | | 1
Natural deaths | 1
Survivors
Terminal sacrifice | 9 | 9 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Angiectasis | | | | 2 (20%)
Hematopoietic cell proliferation | | 1 (10%)
Inflammation, chronic active | 9 (90%) | 10 (100%) | 8 (80%) | 10 (100%)
Mixed cell focus | | | | 1 (10%)
Hepatocyte, fatty change | 1 (10%) | 1 (10%)
Hepatocyte, vacuolization cytoplasmic | 9 (90%) | 10 (100%) | 8 (80%) | 10 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Inflammation, chronic active | 1 (10%)
Epithelium, hyperkeratosis | 2 (20%) | 1 (10%) | | 1 (10%)
Epithelium, hyperplasia | 2 (20%) | 1 (10%) | | 3 (30%)
Epithelium, ulcer | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Accessory adrenal cortical nodule | 1 (10%) | 1 (10%)
Infiltration cellular, lymphocyte | 1 (10%) | | | 1 (10%)
Subcapsular, hyperplasia | 8 (80%) | 9 (90%) | 10 (100%) | 10 (100%)
Pituitary gland | (10) | (10) | (10) | (10)
Pars distalis, cyst | | | 2 (20%) | 1 (10%)
Pars distalis, hyperplasia | | 1 (10%) | 2 (20%)
Thyroid gland | (10) | (10) | (10) | (10)
Ectopic thymus | 1 (10%)
Infiltration cellular, lymphocyte | 2 (20%) | | 1 (10%) | 1 (10%)
Follicle, cyst | | | | 2 (20%)
Genital System
Ovary | (10) | (10) | (10) | (10)
Atrophy | | | 1 (10%)
Cyst | 3 (30%) | 2 (20%) | 1 (10%) | 2 (20%)
Bilateral, cyst | | 1 (10%)
Uterus | (10) | (10) | (10) | (10)
Inflammation, suppurative | 1 (10%)
Endometrium, hyperplasia, cystic | 9 (90%) | 10 (100%) | 8 (80%) | 8 (80%)
Hematopoietic System
Lymph node, mandibular | (10) | (10) | (10) | (10)
Hyperplasia, lymphoid | 1 (10%) | 1 (10%) | 1 (10%) | 2 (20%)
Lymph node, mesenteric | (10) | (10) | (10) | (10)
Hyperplasia, lymphoid | | | 1 (10%)
Spleen | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | | 1 (10%) | 1 (10%)
Hyperplasia, lymphoid | | | 1 (10%)
Thymus | (10) | (10) | (10) | (10)
Cyst | 2 (20%) | 4 (40%) | 5 (50%) | 3 (30%)
Ectopic parathyroid gland | | | 1 (10%) | 1 (10%)
Ectopic thyroid | | | | 1 (10%)
Integumentary System
Skin | | (1) | (1) | (1)
Hyperkeratosis | | | 1 (100%)
Hyperplasia | | | 1 (100%)
Inflammation, chronic active | | 1 (100%) | 1 (100%)
Ulcer | | | 1 (100%)
Respiratory System
Lung | (10) | (10) | (10) | (9)
Alveolar epithelium, hyperplasia | | | | 1 (11%)
Perivascular, infiltration cellular, lymphocyte | 4 (40%) | 3 (30%) | 4 (40%) | 2 (22%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Mineralization | | 1 (10%) | | 1 (10%)
Nephropathy | 7 (70%) | 7 (70%) | 6 (60%) | 8 (80%)
Papilla, mineralization | | 1 (10%)
Systems Examined with No Nonneoplastic Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion