# APPENDIX B SUMMARY OF LESIONS IN Tg.AC HEMIZYGOUS MICE IN THE DRINKING WATER STUDIES OF SODIUM BROMATE

TABLE B1 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 27-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | | | 1
Natural deaths | 2 | 2 | | 1
Survivors
Terminal sacrifice | 13 | 13 | 14 | 14
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Stomach, forestomach | (15) | (15) | (15) | (15)
Squamous cell papilloma | 3 (20%) | 2 (13%) | 8 (53%) | 3 (20%)
Squamous cell papilloma, multiple | 4 (27%)
Tooth | (3) | (3) | (4) | (1)
Odontogenic tumor | 3 (100%) | 3 (100%) | 4 (100%) | 1 (100%)
Integumentary System
Skin | | (2) | (4) | (3)
Squamous cell papilloma | | 2 (100%) | 3 (75%) | 2 (67%)
Subcutaneous tissue, fibrosarcoma | | | | 1 (33%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Alveolar/bronchiolar adenoma | | | | 2 (13%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^b^ | 8 | 6 | 11 | 7
Total primary neoplasms | 10 | 7 | 15 | 9
Total animals with benign neoplasms | 7 | 4 | 8 | 5
Total benign neoplasms | 7 | 4 | 11 | 7
Total animals with malignant neoplasms | | | | 1
Total malignant neoplasms | | | | 1
Total animals with uncertain neoplasms-benign or malignant | 3 | 3 | 4 | 1
Total uncertain neoplasms | 3 | 3 | 4 | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B2 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 27-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | | | 1
Natural deaths | 2 | 2 | | 1
Survivors
Terminal sacrifice | 13 | 13 | 14 | 14
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Inflammation, chronic active | 9 (60%) | 4 (27%) | 10 (67%) | 7 (47%)
Necrosis | | | | 1 (7%)
Hepatocyte, vacuolization cytoplasmic | 6 (40%) | 4 (27%) | 7 (47%) | 4 (27%)
Mesentery | (1) | | (1)
Fat, fibrosis | 1 (100%)
Fat, inflammation, chronic | | | 1 (100%)
Fat, necrosis | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Epithelium, hyperkeratosis | 1 (7%) | 1 (7%) | 2 (13%)
Epithelium, hyperplasia | 1 (7%) | 1 (7%) | 2 (13%) | 2 (13%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Hypertrophy | 4 (27%) | 6 (40%) | 6 (40%) | 4 (27%)
Subcapsular, hyperplasia | 1 (7%) | 1 (7%) | | 1 (7%)
Parathyroid gland | (1) | | (2)
Cyst | 1 (100%) | | 2 (100%)
Pituitary gland | (15) | (14) | (15) | (15)
Pars distalis, cyst | | | 4 (27%)
Thyroid gland | (15) | (14) | (15) | (15)
Infiltration cellular, lymphocyte | | 1 (7%) | 1 (7%) | 2 (13%)
Follicle, depletion secretory | 4 (27%) | 6 (43%) | 15 (100%) | 15 (100%)
Follicular cell, hypertrophy | 1 (7%) | 2 (14%) | 12 (80%) | 15 (100%)
Genital System
Epididymis | (15) | (15) | (15) | (15)
Degeneration | | | 2 (13%) | 2 (13%)
Preputial gland | (1) | | (1)
Duct, ectasia | 1 (100%) | | 1 (100%)
Testes | (15) | (15) | (15) | (15)
Cyst | | | 3 (20%)
Germinal epithelium, degeneration | 1 (7%) | | 3 (20%) | 2 (13%)
Hematopoietic System
Lymph node | | | | (1)
Mediastinal, necrosis, lymphoid | | | | 1 (100%)
Lymph node, mandibular | (15) | (15) | (15) | (15)
Hyperplasia, lymphoid | 3 (20%) | 1 (7%) | 3 (20%) | 1 (7%)
Necrosis, lymphoid | | | | 1 (7%)
Lymph node, mesenteric | (15) | (15) | (15) | (15)
Necrosis, lymphoid | | | | 1 (7%)
Spleen | (15) | (15) | (15) | (15)
Atrophy | 1 (7%) | 1 (7%) | | 1 (7%)
Hematopoietic cell proliferation | 1 (7%) | | | 3 (20%)
Lymphoid follicle, necrosis, lymphoid | | | | 1 (7%)
Thymus | (15) | (15) | (14) | (15)
Atrophy | 2 (13%) | 1 (7%) | 1 (7%) | 2 (13%)
Cyst | 2 (13%)
Ectopic parathyroid gland | | | | 1 (7%)
Thymocyte, necrosis | | | | 1 (7%)
Integumentary System
Skin | | (2) | (4) | (3)
Epidermis, hyperkeratosis | | | | 1 (33%)
Epidermis, hyperplasia, focal | | | 1 (25%) | 2 (67%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Inflammation, chronic active | | | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Mineralization | 1 (7%)
Nephropathy | 1 (7%) | 7 (47%) | 10 (67%) | 14 (93%)
Renal tubule, degeneration | | | | 10 (67%)
Renal tubule, dilatation | | | 1 (7%)
Renal tubule, hypertrophy | | | | 2 (13%)
Systems Examined with No Nonneoplastic Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE B3 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 27-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | 1
Natural deaths | 3 | 5 | 5 | 3
Survivors
Terminal sacrifice | 10 | 9 | 10 | 12
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Intestine large, rectum | (1)
Anus, squamous cell papilloma | 1 (100%)
Liver | (15) | (15) | (15) | (15)
Salivary glands | (1)
Carcinoma | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Squamous cell papilloma | 5 (33%) | 2 (13%) | | 3 (20%)
Squamous cell papilloma, multiple | 1 (7%) | 1 (7%) | 2 (13%) | 3 (20%)
Tooth | (1) | (3) | (2) | (4)
Odontogenic tumor | 1 (100%) | 2 (67%) | 2 (100%) | 4 (100%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Adrenal medulla | (15) | (15) | (15) | (15)
Pituitary gland | (15) | (15) | (15) | (15)
Genital System
Ovary | (15) | (15) | (14) | (15)
Hematopoietic System
Lymph node | (1) | (1) | (3)
Lymph node, mandibular | (15) | (15) | (15) | (15)
Lymph node, mesenteric | (15) | (15) | (14) | (14)
Spleen | (15) | (15) | (15) | (15)
Thymus | (15) | (15) | (15) | (15)
Integumentary System
Skin | (6) | (5) | (2) | (7)
Squamous cell papilloma | 5 (83%) | 2 (40%) | 1 (50%) | 4 (57%)
Squamous cell papilloma, multiple | 1 (17%) | 1 (20%) | | 1 (14%)
Vulva, squamous cell papilloma | | 1 (20%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Alveolar/bronchiolar adenoma | | | 1 (7%) | 2 (13%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15)
Leukemia erythrocytic | 1 (7%) | 2 (13%) | 3 (20%) | 1 (7%)
Lymphoma malignant | 1 (7%) | 1 (7%) | 1 (7%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 10 | 8 | 7 | 10
Total primary neoplasms | 17 | 12 | 10 | 18
Total animals with benign neoplasms | 9 | 5 | 4 | 9
Total benign neoplasms | 13 | 7 | 4 | 13
Total animals with malignant neoplasms | 3 | 3 | 4 | 1
Total malignant neoplasms | 3 | 3 | 4 | 1
Total animals with uncertain neoplasms-benign or malignant | 1 | 2 | 2 | 4
Total uncertain neoplasms | 1 | 2 | 2 | 4

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B4 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 27-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | 1
Natural deaths | 3 | 5 | 5 | 3
Survivors
Terminal sacrifice | 10 | 9 | 10 | 12
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | 1 (7%) | 1 (7%) | | 1 (7%)
Inflammation, chronic active | 11 (73%) | 9 (60%) | 10 (67%) | 12 (80%)
Necrosis | 1 (7%) | | | 1 (7%)
Hepatocyte, vacuolization cytoplasmic | 5 (33%) | | 5 (33%) | 5 (33%)
Mesentery | (1)
Fat, congestion | 1 (100%)
Fat, hemorrhage | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Epithelium, hyperkeratosis | 4 (27%) | 3 (20%) | 3 (20%) | 7 (47%)
Epithelium, hyperplasia | 5 (33%) | 3 (20%) | 3 (20%) | 8 (53%)
Tooth | (1) | (3) | (2) | (4)
Inflammation, chronic active | | 1 (33%)
Cardiovascular System
Blood vessel | (1)
Inflammation, chronic | 1 (100%)
Necrosis, fibrinoid | 1 (100%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Mineralization | | 1 (7%)
Necrosis | | 1 (7%)
Subcapsular, hyperplasia | 4 (27%) | 6 (40%) | 2 (13%) | 2 (13%)
Pituitary gland | (15) | (15) | (15) | (15)
Pars distalis, cyst | 1 (7%) | | | 2 (13%)
Pars distalis, hypertrophy | | | | 6 (40%)
Thyroid gland | (15) | (13) | (13) | (15)
Infiltration cellular, lymphocyte | | | 5 (38%) | 11 (73%)
Inflammation, chronic active | 1 (7%)
Follicle, depletion secretory | 7 (47%) | 7 (54%) | 11 (85%) | 14 (93%)
Follicular cell, hypertrophy | 2 (13%) | 2 (15%) | 11 (85%) | 13 (87%)
Genital System
Ovary | (15) | (15) | (14) | (15)
Cyst | 1 (7%) | | 1 (7%)
Mineralization | | | 1 (7%)
Pigmentation, hemosiderin | 1 (7%) | | 1 (7%)
Uterus | (15) | (15) | (15) | (15)
Endometrium, hyperplasia, cystic | 4 (27%) | 7 (47%) | 6 (40%) | 3 (20%)
Hematopoietic System
Lymph node, mandibular | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | 1 (7%)
Hyperplasia, lymphoid | | 4 (27%) | 2 (13%) | 5 (33%)
Necrosis, lymphoid | | 1 (7%)
Lymph node, mesenteric | (15) | (15) | (14) | (14)
Hyperplasia, lymphoid | | | 1 (7%)
Necrosis, lymphoid | | | 1 (7%)
Spleen | (15) | (15) | (15) | (15)
Atrophy | 1 (7%) | 1 (7%) | 1 (7%) | 2 (13%)
Hematopoietic cell proliferation | 2 (13%) | 3 (20%) | 1 (7%) | 4 (27%)
Necrosis | | | | 1 (7%)
Thymus | (15) | (15) | (15) | (15)
Atrophy | 3 (20%) | 3 (20%) | 3 (20%) | 4 (27%)
Cyst | | | | 1 (7%)
Thymocyte, necrosis | 2 (13%) | | | 2 (13%)
Integumentary System
Skin | (6) | (5) | (2) | (7)
Epidermis, hyperkeratosis | | | | 2 (29%)
Epidermis, hyperplasia, focal | | | | 2 (29%)
Subcutaneous tissue, edema | | 1 (20%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Hemorrhage | | | 1 (7%)
Inflammation, chronic active | | 3 (20%) | | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Mineralization | | | | 1 (7%)
Nephropathy | 2 (13%) | 2 (13%) | 10 (67%) | 13 (87%)
Artery, inflammation, chronic | 2 (13%)
Renal tubule, degeneration | | | 2 (13%) | 8 (53%)
Renal tubule, dilatation | 1 (7%) | 2 (13%) | | 1 (7%)
Renal tubule, hypertrophy | | 1 (7%) | 5 (33%) | 12 (80%)
Renal tubule, necrosis | | | | 1 (7%)
Systems Examined with No Nonneoplastic Lesions Observed
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE B5 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 43-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 2 | 2 | 4 | 3
Natural deaths | 2 | 1 | | 3
Survivors
Terminal sacrifice | 6 | 7 | 6 | 4
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Salivary glands | | (1)
Carcinoma | | 1 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Squamous cell papilloma | 2 (20%) | 3 (30%) | 1 (10%) | 1 (10%)
Squamous cell papilloma, multiple | 2 (20%) | 1 (10%)
Tooth | (3) | (2) | (4) | (2)
Odontogenic tumor | 3 (100%) | 2 (100%) | 3 (75%) | 2 (100%)
Odontogenic tumor, multiple | | | 1 (25%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Adrenal medulla | (10) | (10) | (10) | (10)
Pituitary gland | (10) | (10) | (10) | (10)
Genital System
Epididymis | (10) | (10) | (10) | (10)
Hematopoietic System
Lymph node | | | | (1)
Lymph node, mandibular | (9) | (10) | (10) | (7)
Spleen | (10) | (10) | (10) | (10)
Integumentary System
Skin | (9) | (9) | (9) | (8)
Squamous cell papilloma | | 2 (22%) | 1 (11%) | 3 (38%)
Squamous cell papilloma, multiple | 5 (56%) | 6 (67%) | 5 (56%) | 4 (50%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Alveolar/bronchiolar adenoma | 1 (10%) | 3 (30%) | 1 (10%)
Trachea | | | | (1)
Adenoma | | | | 1 (100%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Leukemia erythrocytic | 2 (20%) | | 2 (20%) | 2 (20%)
Lymphoma malignant | | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 10 | 9 | 10 | 9
Total primary neoplasms | 15 | 19 | 14 | 13
Total animals with benign neoplasms | 7 | 8 | 7 | 8
Total benign neoplasms | 10 | 15 | 8 | 9
Total animals with malignant neoplasms | 2 | 2 | 2 | 2
Total malignant neoplasms | 2 | 2 | 2 | 2
Total animals with uncertain neoplasms-benign or malignant | 3 | 2 | 4 | 2
Total uncertain neoplasms | 3 | 2 | 4 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B6 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 43-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 2 | 2 | 4 | 3
Natural deaths | 2 | 1 | | 3
Survivors
Terminal sacrifice | 6 | 7 | 6 | 4
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 1 (10%) | | 2 (20%) | 1 (10%)
Inflammation, chronic active | 5 (50%) | 5 (50%) | 7 (70%) | 4 (40%)
Hepatocyte, fatty change | 2 (20%) | | 1 (10%)
Hepatocyte, necrosis | 1 (10%)
Hepatocyte, vacuolization cytoplasmic | 5 (50%) | 6 (60%) | 6 (60%) | 3 (30%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Epithelium, hyperkeratosis | 2 (20%) | 2 (20%) | 1 (10%) | 2 (20%)
Epithelium, hyperplasia | 4 (40%) | 2 (20%) | 3 (30%) | 5 (50%)
Epithelium, hyperplasia, focal | | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Hypertrophy | 5 (50%) | 7 (70%) | 6 (60%) | 1 (10%)
Pituitary gland | (10) | (10) | (10) | (10)
Pars distalis, cyst | 1 (10%)
Pars distalis, hypertrophy | | | | 2 (20%)
Thyroid gland | (10) | (10) | (10) | (9)
Infiltration cellular, lymphocyte | | | | 4 (44%)
Follicle, cyst | | 1 (10%)
Follicle, depletion secretory | 3 (30%) | 4 (40%) | 4 (40%) | 7 (78%)
Follicular cell, hypertrophy | | 6 (60%) | 8 (80%) | 8 (89%)
Genital System
Epididymis | (10) | (10) | (10) | (10)
Cyst | 1 (10%)
Degeneration | 1 (10%) | 1 (10%) | | 7 (70%)
Granuloma sperm | | | 1 (10%)
Inflammation, chronic active | 1 (10%)
Preputial gland | | (2) | (3) | (1)
Atrophy | | 1 (50%) | 1 (33%)
Duct, ectasia | | 2 (100%) | 2 (67%) | 1 (100%)
Testes | (10) | (10) | (10) | (10)
Mineralization | | 1 (10%)
Bilateral, germinal epithelium, degeneration | | | 3 (30%) | 8 (80%)
Germinal epithelium, degeneration | 1 (10%) | 1 (10%) | 2 (20%)
Interstitial cell, hyperplasia | | | | 3 (30%)
Hematopoietic System
Lymph node, mandibular | (9) | (10) | (10) | (7)
Hyperplasia, lymphoid | 2 (22%) | | 4 (40%) | 1 (14%)
Lymph node, mesenteric | (9) | (10) | (10) | (9)
Hyperplasia, lymphoid | | | 1 (10%)
Spleen | (10) | (10) | (10) | (10)
Atrophy | | | | 1 (10%)
Hematopoietic cell proliferation | | 1 (10%) | 2 (20%)
Thymus | (10) | (10) | (9) | (9)
Atrophy | 5 (50%) | 1 (10%) | 3 (33%) | 6 (67%)
Cyst | 3 (30%) | 1 (10%) | | 1 (11%)
Integumentary System
Skin | (9) | (9) | (9) | (8)
Inflammation, chronic active | 1 (11%) | 1 (11%)
Epidermis, hyperplasia, focal | 3 (33%) | 4 (44%) | 3 (33%) | 1 (13%)
Hair follicle, sebaceous gland, atrophy | | 1 (11%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Inflammation, chronic active | | 1 (10%) | 1 (10%)
Thrombosis | 1 (10%)
Alveolar epithelium, hyperplasia | | | | 1 (10%)
Alveolus, infiltration cellular, histiocyte | 1 (10%)
Perivascular, infiltration cellular, lymphocyte | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Hydronephrosis | | | | 2 (20%)
Inflammation | | | 1 (10%)
Mineralization | | | | 1 (10%)
Nephropathy | 7 (70%) | 6 (60%) | 7 (70%) | 10 (100%)
Cortex, cyst | 1 (10%) | | | 1 (10%)
Glomerulus, inflammation, membranoproliferative | 2 (20%) | | | 2 (20%)
Renal tubule, degeneration | | | 1 (10%) | 8 (80%)
Renal tubule, hypertrophy | | | 1 (10%) | 6 (60%)
Systems Examined with No Nonneoplastic Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE B7 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 43-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 3 | 4 | 4 | 7
Natural deaths | | 1 | 2 | 1
Survivors
Terminal sacrifice | 7 | 5 | 4 | 2
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Salivary glands | (1) | (1) | (2) | (2)
Carcinoma | 1 (100%) | | 2 (100%) | 2 (100%)
Carcinoma, metastatic, Zymbal’s gland | | 1 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Squamous cell papilloma | | 2 (20%) | 3 (30%)
Squamous cell papilloma, multiple | 1 (10%) | 2 (20%) | | 1 (10%)
Tooth | (3) | (5) | (2) | (5)
Odontogenic tumor | 2 (67%) | 4 (80%) | 1 (50%) | 5 (100%)
Odontogenic tumor, multiple | 1 (33%) | 1 (20%) | 1 (50%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Adrenal medulla | (10) | (10) | (10) | (10)
Pituitary gland | (10) | (10) | (9) | (10)
Genital System
Ovary | (10) | (9) | (10) | (10)
Luteoma | 1 (10%) | | 1 (10%)
Uterus | (10) | (10) | (10) | (10)
Hematopoietic System
Lymph node | (1) | (2)
Lymph node, mandibular | (9) | (10) | (10) | (9)
Carcinoma, metastatic, uncertain primary site | 1 (11%)
Carcinoma, metastatic, Zymbal’s gland | | 1 (10%)
Lymph node, mesenteric | (9) | (9) | (10) | (10)
Spleen | (10) | (10) | (10) | (10)
Thymus | (10) | (10) | (10) | (10)
Integumentary System
Mammary gland | | (1)
Adenocarcinoma | | 1 (100%)
Skin | (6) | (8) | (8) | (4)
Squamous cell papilloma | 2 (33%) | 3 (38%) | 3 (38%)
Squamous cell papilloma, multiple | 3 (50%) | 5 (63%) | 4 (50%) | 1 (25%)
Subcutaneous tissue, fibrosarcoma | | 1 (13%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Alveolar/bronchiolar adenoma | 1 (10%) | 1 (10%) | 1 (10%)
Carcinoma, metastatic, Zymbal’s gland | | 1 (10%)
Special Senses System
Zymbal’s gland | | (1) | (1)
Carcinoma | | 1 (100%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Leukemia erythrocytic | | 2 (20%) | 2 (20%) | 1 (10%)
Lymphoma malignant | | | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 8 | 9 | 9 | 8
Total primary neoplasms | 12 | 23 | 19 | 10
Total animals with benign neoplasms | 6 | 8 | 8 | 2
Total benign neoplasms | 8 | 13 | 12 | 2
Total animals with malignant neoplasms | 1 | 5 | 5 | 3
Total malignant neoplasms | 1 | 5 | 5 | 3
Total animals with metastatic neoplasms | 1 | 1
Total metastatic neoplasms | 1 | 3
Total animals with malignant neoplasms of uncertain primary site | 1
Total animals with uncertain neoplasms-benign or malignant | 3 | 5 | 2 | 5
Total uncertain neoplasms | 3 | 5 | 2 | 5

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B8 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 43-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 3 | 4 | 4 | 7
Natural deaths | | 1 | 2 | 1
Survivors
Terminal sacrifice | 7 | 5 | 4 | 2
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 3 (30%) | 4 (40%) | 6 (60%) | 1 (10%)
Inflammation, chronic active | 10 (100%) | 6 (60%) | 7 (70%) | 5 (50%)
Mineralization | 1 (10%)
Hepatocyte, fatty change | | | 1 (10%)
Hepatocyte, necrosis | 1 (10%) | 1 (10%) | | 1 (10%)
Hepatocyte, vacuolization cytoplasmic | 7 (70%) | 4 (40%) | 4 (40%) | 3 (30%)
Mesentery | (2)
Fat, fibrosis | 1 (50%)
Fat, necrosis | 2 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Epithelium, hyperkeratosis | 1 (10%) | 2 (20%) | 1 (10%) | 7 (70%)
Epithelium, hyperplasia | 5 (50%) | 6 (60%) | 4 (40%) | 8 (80%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Accessory adrenal cortical nodule | | 1 (10%) | | 1 (10%)
Mineralization | 1 (10%) | 2 (20%)
Subcapsular, hyperplasia | 5 (50%) | 6 (60%) | 1 (10%)
Parathyroid gland | | | | (1)
Necrosis | | | | 1 (100%)
Pituitary gland | (10) | (10) | (9) | (10)
Pars distalis, cyst | 3 (30%) | 2 (20%)
Pars distalis, hypertrophy | | | 2 (22%) | 6 (60%)
Pars distalis, mineralization | | | | 1 (10%)
Thyroid gland | (10) | (9) | (10) | (10)
Infiltration cellular, lymphocyte | | 2 (22%) | 7 (70%) | 8 (80%)
Follicle, degeneration | | 1 (11%)
Follicle, depletion secretory | 1 (10%) | 8 (89%) | 9 (90%) | 10 (100%)
Follicular cell, hypertrophy | | 8 (89%) | 10 (100%) | 10 (100%)
Genital System
Ovary | (10) | (9) | (10) | (10)
Atrophy | 1 (10%) | | 1 (10%) | 2 (20%)
Cyst | 1 (10%) | 1 (11%)
Inflammation, chronic active | 1 (10%) | 3 (33%) | 1 (10%)
Uterus | (10) | (10) | (10) | (10)
Inflammation, suppurative | | 3 (30%)
Endometrium, hyperplasia, cystic | 8 (80%) | 7 (70%) | 5 (50%) | 2 (20%)
Hematopoietic System
Lymph node | (1) | (2)
Mediastinal, hyperplasia, lymphoid | | 1 (50%)
Lymph node, mandibular | (9) | (10) | (10) | (9)
Hyperplasia, lymphoid | 2 (22%) | 4 (40%) | 2 (20%) | 2 (22%)
Inflammation, chronic active | | | 1 (10%)
Lymph node, mesenteric | (9) | (9) | (10) | (10)
Hyperplasia, lymphoid | | 1 (11%)
Infiltration cellular, polymorphonuclear | | 1 (11%)
Spleen | (10) | (10) | (10) | (10)
Atrophy | | | | 1 (10%)
Hematopoietic cell proliferation | 3 (30%) | 3 (30%) | 6 (60%) | 4 (40%)
Thymus | (10) | (10) | (10) | (10)
Atrophy | 2 (20%) | 5 (50%) | 6 (60%) | 9 (90%)
Cyst | | | 1 (10%) | 1 (10%)
Integumentary System
Skin | (6) | (8) | (8) | (4)
Inflammation, chronic active | 1 (17%) | 1 (13%)
Epidermis, hyperplasia, focal | 5 (83%) | 3 (38%) | 2 (25%) | 3 (75%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Alveolar epithelium, hyperplasia | | | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Mineralization | | | 1 (10%) | 2 (20%)
Nephropathy | 6 (60%) | 6 (60%) | 8 (80%) | 8 (80%)
Cortex, cyst | | 2 (20%)
Glomerulus, inflammation, membranoproliferative | | 1 (10%) | 2 (20%) | 1 (10%)
Renal tubule, degeneration | | | | 7 (70%)
Renal tubule, hypertrophy | | | 2 (20%) | 5 (50%)
Systems Examined with No Nonneoplastic Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion