# APPENDIX A SUMMARY OF LESIONS IN Tg.AC HEMIZYGOUS MICE IN THE DERMAL STUDIES OF SODIUM BROMATE

TABLE A1 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Sodium Bromate^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | 1
Natural deaths | 1 | 3 | 2
Survivors
Terminal sacrifice | 12 | 11 | 13 | 15
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Stomach, forestomach | (15) | (15) | (15) | (15)
Squamous cell papilloma | 1 (7%) | 4 (27%) | 4 (27%) | 3 (20%)
Squamous cell papilloma, multiple | 2 (13%) | 2 (13%) | 2 (13%) | 4 (27%)
Tooth | (3) | (1) | (1) | (3)
Odontogenic tumor | 3 (100%) | 1 (100%) | 1 (100%) | 3 (100%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Adrenal medulla | (15) | (15) | (15) | (15)
Pituitary gland | (15) | (14) | (15) | (15)
Hematopoietic System
Lymph node | | (1)
Lymph node, mandibular | (15) | (15) | (15) | (15)
Lymph node, mesenteric | (15) | (15) | (15) | (15)
Spleen | (15) | (15) | (15) | (15)
Integumentary System
Skin | (15) | (15) | (15) | (15)
Squamous cell papilloma | 2 (13%) | 3 (20%) | 1 (7%) | 4 (27%)
Squamous cell papilloma, multiple | | | 1 (7%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15)
Leukemia erythrocytic | | 2 (13%) | 1 (7%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Genital System
Musculoskeletal System
Nervous System
Special Senses System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 6 | 9 | 9 | 11
Total primary neoplasms | 8 | 12 | 10 | 14
Total animals with benign neoplasms | 4 | 8 | 7 | 10
Total benign neoplasms | 5 | 9 | 8 | 11
Total animals with malignant neoplasms | | 2 | 1
Total malignant neoplasms | | 2 | 1
Total animals with uncertain neoplasms-benign or malignant | 3 | 1 | 1 | 3
Total uncertain neoplasms | 3 | 1 | 1 | 3

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A2 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Sodium Bromate^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | 1
Natural deaths | 1 | 3 | 2
Survivors
Terminal sacrifice | 12 | 11 | 13 | 15
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | | 1 (7%) | 1 (7%)
Inflammation, chronic active | 10 (67%) | 6 (40%) | 9 (60%) | 11 (73%)
Hepatocyte, necrosis | 1 (7%) | 2 (13%)
Hepatocyte, vacuolization cytoplasmic | 6 (40%) | 4 (27%) | 3 (20%) | 6 (40%)
Mesentery | | (1) | (1)
Fat, necrosis | | 1 (100%) | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Epithelium, hyperplasia | 1 (7%) | 2 (13%) | 1 (7%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Accessory adrenal cortical nodule | 1 (7%)
Hypertrophy | 8 (53%) | 4 (27%) | 1 (7%) | 3 (20%)
Subcapsular, hyperplasia | | | 1 (7%)
Pituitary gland | (15) | (14) | (15) | (15)
Pars distalis, cyst | | 3 (21%) | 4 (27%) | 3 (20%)
Pars distalis, hyperplasia | | | 1 (7%)
Thyroid gland | (15) | (15) | (15) | (15)
Infiltration cellular, lymphocyte | | | 1 (7%)
Follicle, depletion secretory | 7 (47%) | 4 (27%) | 5 (33%) | 11 (73%)
Follicular cell, hypertrophy | | 7 (47%) | 10 (67%) | 14 (93%)
Genital System
Epididymis | (15) | (15) | (15) | (15)
Degeneration | 1 (7%) | | | 2 (13%)
Testes | (15) | (15) | (15) | (15)
Cyst | 1 (7%) | | | 1 (7%)
Germinal epithelium, degeneration | 2 (13%) | | 2 (13%) | 3 (20%)
Hematopoietic System
Lymph node, mandibular | (15) | (15) | (15) | (15)
Necrosis, lymphoid | 1 (7%) | 1 (7%)
Lymph node, mesenteric | (15) | (15) | (15) | (15)
Necrosis, lymphoid | 1 (7%)
Spleen | (15) | (15) | (15) | (15)
Atrophy | 1 (7%)
Hematopoietic cell proliferation | | | 1 (7%) | 2 (13%)
Thymus | (14) | (15) | (15) | (15)
Atrophy | 1 (7%) | 4 (27%) | 1 (7%) | 4 (27%)
Cyst | 2 (14%) | 2 (13%) | 2 (13%) | 5 (33%)
Ectopic parathyroid gland | | 1 (7%)
Ectopic thyroid | | 1 (7%)
Integumentary System
Skin | (15) | (15) | (15) | (15)
Hyperkeratosis | 2 (13%) | | 3 (20%) | 4 (27%)
Hyperkeratosis, focal | 1 (7%)
Inflammation, chronic active | | 1 (7%)
Epidermis, hyperplasia, focal | 3 (20%) | 2 (13%) | 3 (20%) | 4 (27%)
Site of application - epidermis, hyperplasia, focal | | | | 1 (7%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Inflammation, chronic active | | 1 (7%)
Pigmentation | | 1 (7%)
Thrombosis | | | | 1 (7%)
Alveolar epithelium, hyperplasia | 1 (7%)
Alveolus, infiltration cellular, histiocyte | | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Nephropathy | 8 (53%) | 8 (53%) | 14 (93%) | 14 (93%)
Artery, inflammation, chronic active | 1 (7%)
Renal tubule, dilatation | 1 (7%) | | | 2 (13%)
Urethra | | | | (1)
Bulbourethral gland, cyst | | | | 1 (100%)
Systems Examined with No Nonneoplastic Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A3 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Sodium Bromate^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | 4 | 1 | 3
Natural deaths | 2 | 1 | 3 | 1
Survivors
Terminal sacrifice | 11 | 10 | 11 | 11
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Stomach, forestomach | (15) | (15) | (15) | (15)
Squamous cell papilloma | 3 (20%) | 3 (20%) | 3 (20%) | 5 (33%)
Squamous cell papilloma, multiple | 3 (20%) | 3 (20%) | 4 (27%) | 3 (20%)
Tooth | (3) | (2) | (5) | (4)
Odontogenic tumor | 3 (100%) | 2 (100%) | 4 (80%) | 4 (100%)
Odontogenic tumor, multiple | | | 1 (20%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Adrenal medulla | (15) | (15) | (15) | (15)
Pituitary gland | (15) | (15) | (15) | (15)
Genital System
Ovary | (15) | (15) | (15) | (15)
Luteoma | | | | 1 (7%)
Teratoma malignant | | | | 1 (7%)
Uterus | (15) | (15) | (15) | (15)
Hematopoietic System
Lymph node | | (2) | | (2)
Lymph node, mandibular | (15) | (14) | (14) | (15)
Lymph node, mesenteric | (14) | (14) | (13) | (15)
Spleen | (15) | (15) | (15) | (15)
Integumentary System
Skin | (15) | (15) | (15) | (15)
Squamous cell papilloma | 2 (13%) | 3 (20%) | 4 (27%) | 5 (33%)
Squamous cell papilloma, multiple | 3 (20%) | | | 4 (27%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Special Senses System
Eye | | (1)
Squamous cell papilloma | | 1 (100%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15)
Leukemia erythrocytic | | 2 (13%) | 1 (7%) | 2 (13%)
Lymphoma malignant | | | 1 (7%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 9 | 12 | 12 | 14
Total primary neoplasms | 14 | 14 | 18 | 25
Total animals with benign neoplasms | 8 | 9 | 8 | 11
Total benign neoplasms | 11 | 10 | 11 | 18
Total animals with malignant neoplasms | | 2 | 2 | 3
Total malignant neoplasms | | 2 | 2 | 3
Total animals with uncertain neoplasms-benign or malignant | 3 | 2 | 5 | 4
Total uncertain neoplasms | 3 | 2 | 5 | 4

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A4 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Sodium Bromate^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | 4 | 1 | 3
Natural deaths | 2 | 1 | 3 | 1
Survivors
Terminal sacrifice | 11 | 10 | 11 | 11
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Intestine large, rectum | (1) | (2) | (1)
Anus, hyperplasia | | 1 (50%)
Liver | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | 2 (13%) | 2 (13%) | 2 (13%) | 3 (20%)
Inflammation, chronic active | 13 (87%) | 12 (80%) | 12 (80%) | 12 (80%)
Thrombosis | | | | 1 (7%)
Hepatocyte, degeneration | | 1 (7%)
Hepatocyte, fatty change | | 1 (7%)
Hepatocyte, necrosis | 1 (7%) | 2 (13%) | 1 (7%) | 1 (7%)
Hepatocyte, vacuolization cytoplasmic | 3 (20%) | 4 (27%) | 3 (20%) | 3 (20%)
Salivary glands | | | | (1)
Atrophy | | | | 1 (100%)
Inflammation, chronic active | | | | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Epithelium, hyperkeratosis | 1 (7%) | 2 (13%) | 1 (7%) | 1 (7%)
Epithelium, hyperplasia | 2 (13%) | 2 (13%) | 1 (7%) | 2 (13%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Accessory adrenal cortical nodule | 3 (20%) | 3 (20%) | 1 (7%) | 1 (7%)
Subcapsular, hyperplasia | 4 (27%) | 3 (20%) | 5 (33%) | 3 (20%)
Pituitary gland | (15) | (15) | (15) | (15)
Pars distalis, cyst | 2 (13%) | 1 (7%) | 2 (13%)
Pars intermedia, cyst | 1 (7%)
Thyroid gland | (15) | (15) | (15) | (15)
Ectopic thymus | 1 (7%)
Infiltration cellular, lymphocyte | | 6 (40%) | 3 (20%) | 12 (80%)
Follicle, cyst | 1 (7%) | | | 1 (7%)
Follicle, depletion secretory | 6 (40%) | 11 (73%) | 13 (87%) | 14 (93%)
Follicular cell, hypertrophy | 1 (7%) | 9 (60%) | 12 (80%) | 13 (87%)
Genital System
Ovary | (15) | (15) | (15) | (15)
Atrophy | | | 1 (7%)
Cyst | | | 1 (7%) | 3 (20%)
Hemorrhage | | | 1 (7%)
Pigmentation | | | 1 (7%)
Uterus | (15) | (15) | (15) | (15)
Endometrium, hyperplasia, cystic | 11 (73%) | 9 (60%) | 10 (67%) | 10 (67%)
Hematopoietic System
Lymph node | | (2) | | (2)
Mediastinal, hyperplasia, lymphoid | | 1 (50%)
Lymph node, mandibular | (15) | (14) | (14) | (15)
Hyperplasia, lymphoid | 4 (27%) | 2 (14%) | 2 (14%) | 3 (20%)
Lymph node, mesenteric | (14) | (14) | (13) | (15)
Hyperplasia, lymphoid | | | | 1 (7%)
Spleen | (15) | (15) | (15) | (15)
Atrophy | | 1 (7%) | 1 (7%) | 1 (7%)
Hematopoietic cell proliferation | 3 (20%) | 5 (33%) | 9 (60%) | 10 (67%)
Thymus | (15) | (14) | (15) | (15)
Atrophy | 1 (7%) | 3 (21%) | 4 (27%) | 2 (13%)
Cyst | 2 (13%) | 4 (29%) | 2 (13%) | 3 (20%)
Integumentary System
Skin | (15) | (15) | (15) | (15)
Hyperkeratosis | | 1 (7%)
Inflammation, chronic active | | 1 (7%) | 1 (7%) | 1 (7%)
Inflammation, suppurative | | 1 (7%)
Ulcer | | | | 1 (7%)
Epidermis, hyperplasia, focal | 2 (13%) | 3 (20%) | 3 (20%) | 1 (7%)
Musculoskeletal System
Bone | | (1)
Fracture | | 1 (100%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Inflammation, chronic active | | 2 (13%)
Thrombosis | | | | 1 (7%)
Alveolar epithelium, hyperplasia | | | | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Nephropathy | 8 (53%) | 7 (47%) | 13 (87%) | 15 (100%)
Renal tubule, dilatation | 1 (7%)
Systems Examined with No Nonneoplastic Lesions Observed
Cardiovascular System
General Body System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A5 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Sodium Bromate^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 1 | | | 2
Natural deaths | 1 | 2 | 2
Survivors
Terminal sacrifice | 8 | 8 | 8 | 8
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Salivary glands | (2)
Carcinoma | 1 (50%)
Carcinosarcoma | 1 (50%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Squamous cell papilloma | 2 (20%) | 2 (20%) | 1 (10%) | 2 (20%)
Squamous cell papilloma, multiple | 1 (10%) | 1 (10%) | 1 (10%) | 2 (20%)
Tooth | (2) | (3) | (3) | (2)
Odontogenic tumor | 1 (50%) | 2 (67%) | 3 (100%) | 2 (100%)
Odontogenic tumor, multiple | 1 (50%) | 1 (33%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Adrenal medulla | (10) | (10) | (10) | (10)
Pituitary gland | (9) | (10) | (10) | (10)
Hematopoietic System
Spleen | (10) | (10) | (10) | (10)
Integumentary System
Skin | (10) | (10) | (10) | (10)
Keratoacanthoma | | | 1 (10%)
Squamous cell carcinoma | 1 (10%) | 1 (10%)
Squamous cell papilloma | 3 (30%) | 7 (70%) | 4 (40%) | 4 (40%)
Squamous cell papilloma, multiple | 4 (40%) | 2 (20%) | 2 (20%) | 2 (20%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Alveolar/bronchiolar adenoma | 1 (10%) | 2 (20%) | 1 (10%) | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Leukemia erythrocytic | | 1 (10%) | 1 (10%) | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Genital System
Musculoskeletal System
Nervous System
Special Senses System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 9 | 10 | 7 | 7
Total primary neoplasms | 16 | 19 | 14 | 14
Total animals with benign neoplasms | 7 | 9 | 6 | 6
Total benign neoplasms | 11 | 14 | 10 | 11
Total animals with malignant neoplasms | 3 | 2 | 1 | 1
Total malignant neoplasms | 3 | 2 | 1 | 1
Total animals with uncertain neoplasms-benign or malignant | 2 | 3 | 3 | 2
Total uncertain neoplasms | 2 | 3 | 3 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A6 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Sodium Bromate^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 1 | | | 2
Natural deaths | 1 | 2 | 2
Survivors
Terminal sacrifice | 8 | 8 | 8 | 8
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | | 1 (10%) | 1 (10%) | 1 (10%)
Inflammation, chronic active | 8 (80%) | 8 (80%) | 6 (60%) | 6 (60%)
Necrosis | | | | 2 (20%)
Hepatocyte, fatty change | 1 (10%)
Hepatocyte, vacuolization cytoplasmic | 5 (50%) | 8 (80%) | 6 (60%) | 2 (20%)
Mesentery | (1) | | (2)
Fat, fibrosis | 1 (100%) | | 1 (50%)
Fat, inflammation, chronic active | 1 (100%) | | 2 (100%)
Fat, necrosis | 1 (100%) | | 2 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Epithelium, hyperkeratosis | | 2 (20%) | | 1 (10%)
Epithelium, hyperplasia | | 2 (20%) | | 1 (10%)
Tooth | (2) | (3) | (3) | (2)
Abscess, focal | | | | 1 (50%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Accessory adrenal cortical nodule | | | 2 (20%) | 1 (10%)
Hypertrophy | 6 (60%) | 5 (50%) | 6 (60%) | 6 (60%)
Pituitary gland | (9) | (10) | (10) | (10)
Pars distalis, cyst | 3 (33%) | 3 (30%) | 1 (10%) | 3 (30%)
Thyroid gland | (10) | (10) | (10) | (10)
Infiltration cellular, lymphocyte | | | 2 (20%) | 1 (10%)
Follicle, cyst | | 1 (10%)
Follicle, depletion secretory | 8 (80%) | 7 (70%) | 9 (90%) | 9 (90%)
Follicular cell, hypertrophy | | 9 (90%) | 8 (80%) | 8 (80%)
Genital System
Epididymis | (10) | (10) | (10) | (10)
Cyst | | | 2 (20%) | 2 (20%)
Degeneration | 1 (10%) | 2 (20%) | 3 (30%) | 5 (50%)
Inflammation, chronic active | | | 3 (30%) | 2 (20%)
Testes | (10) | (10) | (10) | (10)
Cyst | | 1 (10%) | 1 (10%) | 2 (20%)
Mineralization | | | 1 (10%)
Bilateral, germinal epithelium, degeneration | | 1 (10%) | 1 (10%) | 2 (20%)
Germinal epithelium, degeneration | 1 (10%) | 2 (20%) | 3 (30%) | 6 (60%)
Hematopoietic System
Lymph node, mandibular | (10) | (10) | (10) | (10)
Hyperplasia, lymphoid | 1 (10%) | | | 3 (30%)
Spleen | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 3 (30%) | 2 (20%) | 2 (20%) | 3 (30%)
Hyperplasia, lymphoid | | | | 1 (10%)
Thymus | (10) | (10) | (10) | (9)
Atrophy | 3 (30%) | 2 (20%) | 4 (40%) | 3 (33%)
Cyst | 7 (70%) | 1 (10%) | | 3 (33%)
Integumentary System
Skin | (10) | (10) | (10) | (10)
Hyperkeratosis | | 1 (10%) | | 1 (10%)
Epidermis, hyperplasia, focal | 4 (40%) | 2 (20%) | 1 (10%) | 2 (20%)
Site of application - epidermis, hyperplasia, focal | | | 1 (10%) | 1 (10%)
Subcutaneous tissue, inflammation, chronic active | 1 (10%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Inflammation, chronic active | | 2 (20%) | 1 (10%) | 1 (10%)
Alveolar epithelium, hyperplasia | | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Mineralization | | 1 (10%)
Nephropathy | 7 (70%) | 10 (100%) | 9 (90%) | 10 (100%)
Cortex, cyst | | 3 (30%) | 1 (10%)
Glomerulus, inflammation, membranoproliferative | | 1 (10%) | 1 (10%) | 1 (10%)
Papilla, mineralization | 1 (10%)
Pelvis, dilatation | | | | 1 (10%)
Renal tubule, hypertrophy | | | | 2 (20%)
Systems Examined with No Nonneoplastic Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A7 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Sodium Bromate^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 1 | 1 | 2 | 1
Natural deaths | 1 | 2 | | 1
Survivors
Terminal sacrifice | 7 | 7 | 8 | 8
Missing | 1
Animals examined microscopically | 9 | 10 | 10 | 10
Alimentary System
Liver | (9) | (10) | (10) | (10)
Salivary glands | (1) | (1) | (1)
Carcinoma | | 1 (100%) | 1 (100%)
Stomach, forestomach | (9) | (10) | (10) | (10)
Squamous cell papilloma | 2 (22%) | 1 (10%) | 4 (40%) | 3 (30%)
Squamous cell papilloma, multiple | | 1 (10%) | 3 (30%) | 1 (10%)
Tooth | (2) | (4) | (3) | (3)
Odontogenic tumor | 2 (100%) | 3 (75%) | 2 (67%) | 3 (100%)
Odontogenic tumor, multiple | | | 1 (33%)
Genital System
Ovary | (9) | (10) | (10) | (10)
Hemangioma | | 1 (10%)
Luteoma, multiple | | | 1 (10%)
Teratoma benign | 1 (11%)
Hematopoietic System
Spleen | (9) | (10) | (10) | (10)
Integumentary System
Skin | (9) | (10) | (10) | (10)
Squamous cell papilloma | 2 (22%) | 2 (20%) | 3 (30%) | 1 (10%)
Squamous cell papilloma, multiple | 4 (44%) | 3 (30%) | 2 (20%) | 3 (30%)
Site of application, squamous cell papilloma | 1 (11%) | | | 1 (10%)
Respiratory System
Lung | (9) | (10) | (10) | (10)
Alveolar/bronchiolar adenoma | | | | 1 (10%)
Carcinoma, metastatic, Zymbal’s gland | 1 (11%)
Special Senses System
Zymbal’s gland | (2)
Carcinoma | 1 (50%)
Urinary System
Kidney | (9) | (10) | (10) | (10)
Systemic Lesions
Multiple organs^b^ | (9) | (10) | (10) | (10)
Leukemia erythrocytic | 1 (11%) | | | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Musculoskeletal System
Nervous System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 7 | 7 | 10 | 9
Total primary neoplasms | 14 | 12 | 17 | 14
Total animals with benign neoplasms | 6 | 5 | 8 | 8
Total benign neoplasms | 10 | 8 | 13 | 10
Total animals with malignant neoplasms | 2 | 1 | 1 | 1
Total malignant neoplasms | 2 | 1 | 1 | 1
Total animals with metastatic neoplasms | 1
Total metastatic neoplasms | 1
Total animals with uncertain neoplasms-benign or malignant | 2 | 3 | 3 | 3
Total uncertain neoplasms | 2 | 3 | 3 | 3

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A8 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Sodium Bromate^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 1 | 1 | 2 | 1
Natural deaths | 1 | 2 | | 1
Survivors
Terminal sacrifice | 7 | 7 | 8 | 8
Missing | 1
Animals examined microscopically | 9 | 10 | 10 | 10
Alimentary System
Liver | (9) | (10) | (10) | (10)
Hematopoietic cell proliferation | 2 (22%) | 2 (20%) | 2 (20%) | 2 (20%)
Inflammation, chronic active | 7 (78%) | 9 (90%) | 10 (100%) | 9 (90%)
Necrosis | 2 (22%) | 1 (10%) | 1 (10%) | 2 (20%)
Hepatocyte, fatty change | 1 (11%)
Hepatocyte, vacuolization cytoplasmic | 7 (78%) | 4 (40%) | 7 (70%) | 8 (80%)
Stomach, forestomach | (9) | (10) | (10) | (10)
Epithelium, hyperkeratosis | 1 (11%) | 1 (10%) | 2 (20%) | 1 (10%)
Epithelium, hyperplasia | 1 (11%) | 1 (10%) | 3 (30%) | 2 (20%)
Endocrine System
Adrenal cortex | (9) | (10) | (10) | (10)
Accessory adrenal cortical nodule | 2 (22%) | 2 (20%) | 2 (20%) | 4 (40%)
Subcapsular, hyperplasia | 4 (44%) | 7 (70%) | 7 (70%) | 3 (30%)
Pituitary gland | (9) | (10) | (10) | (10)
Pars distalis, hypertrophy | | | | 1 (10%)
Pars distalis, inflammation, chronic active | 1 (11%)
Thyroid gland | (9) | (10) | (10) | (10)
Infiltration cellular, lymphocyte | | 2 (20%) | 5 (50%) | 10 (100%)
Follicle, depletion secretory | 5 (56%) | 8 (80%) | 10 (100%) | 10 (100%)
Follicular cell, hypertrophy | 1 (11%) | 9 (90%) | 9 (90%) | 10 (100%)
Genital System
Ovary | (9) | (10) | (10) | (10)
Cyst | 1 (11%) | 4 (40%) | 2 (20%) | 5 (50%)
Inflammation, chronic active | 1 (11%) | | | 1 (10%)
Pigmentation, hemosiderin | | | | 1 (10%)
Corpus luteum, degeneration | | | | 1 (10%)
Thecal cell, hyperplasia | | | | 1 (10%)
Uterus | (9) | (10) | (10) | (10)
Endometrium, hyperplasia, cystic | 8 (89%) | 7 (70%) | 8 (80%) | 10 (100%)
Hematopoietic System
Lymph node, mandibular | (9) | (10) | (10) | (10)
Hyperplasia, lymphoid | 1 (11%) | 3 (30%) | 2 (20%) | 2 (20%)
Spleen | (9) | (10) | (10) | (10)
Atrophy | 1 (11%) | 1 (10%)
Hematopoietic cell proliferation | 3 (33%) | 6 (60%) | 8 (80%) | 8 (80%)
Thymus | (8) | (10) | (10) | (10)
Atrophy | 1 (13%) | 1 (10%) | 2 (20%) | 1 (10%)
Cyst | | 1 (10%) | 2 (20%) | 5 (50%)
Integumentary System
Skin | (9) | (10) | (10) | (10)
Inflammation, chronic active | | | 1 (10%)
Ulcer | | | 1 (10%)
Epidermis, hyperplasia, focal | 2 (22%) | 2 (20%) | 6 (60%) | 3 (30%)
Site of application - dermis, cyst epithelial inclusion | | | | 1 (10%)
Site of application - epidermis, hyperplasia | | | 1 (10%)
Subcutaneous tissue, cyst epithelial inclusion | | | | 1 (10%)
Respiratory System
Lung | (9) | (10) | (10) | (10)
Inflammation, chronic active | | 1 (10%) | 1 (10%)
Metaplasia, osseous | | | | 1 (10%)
Perivascular, infiltration cellular, lymphocyte | | | | 1 (10%)
Special Senses System
Eye | (1)
Cornea, inflammation, chronic active | 1 (100%)
Zymbal’s gland | (2)
Cyst | 1 (50%)
Inflammation, chronic active | 1 (50%)
Urinary System
Kidney | (9) | (10) | (10) | (10)
Mineralization | | | 1 (10%)
Nephropathy | 5 (56%) | 6 (60%) | 8 (80%) | 10 (100%)
Artery, inflammation, chronic active | | 1 (10%)
Cortex, cyst | 1 (11%)
Renal tubule, hypertrophy | | | | 4 (40%)
Systems Examined with No Nonneoplastic Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System

a Number of animals examined microscopically at the site and the number of animals with lesion