# REFERENCES

Aggazzotti, G., Righi, E., Fantuzzi, G., Biasotti, B., Ravera, G., Kanitz, S., Barbone, F., Sansebastiano, G., Battaglia, M.A., Leoni, V., Fabiani, L., Triassi, M., and Sciacca, S. (2004). Chlorination by-products (CBPs) in drinking water and adverse pregnancy outcomes in Italy. J. Water Health 2, 233–247.15666965
Aida, Y., Yasuhara, K., Takada, K., Kurokawa, Y., and Tobe, M. (1992). Chronic toxicity of microencapsulated bromodichloromethane administered in the diet to Wistar rats. J. Toxicol. Sci. 17, 51–68.1507274
The Aldrich Library of FT-IR Spectra (1985). 1st ed. (C.J. Pouchert, Ed.). Aldrich Chemical Company, Inc., Milwaukee, WI.
Allis, J.W., and Zhao, G. (2002). Quantitative evaluation of bromodichloromethane metabolism by recombinant rat and human cytochrome P450s. Chem. Biol. Interact. 140, 137–153.12076521
Anders, M.W., Stevens, J.L., Sprague, R.W., Shaath, Z., and Ahmed, A.E. (1978). Metabolism of haloforms to carbon monoxide. II. In vivo studies. Drug Metab. Dispos. 6, 556–560.30605
Anderson, B.E., Zeiger, E., Shelby, M.D., Resnick, M.A., Gulati, D.K., Ivett, J.L., and Loveday, K.S. (1990). Chromosome aberration and sister chromatid exchange test results with 42 chemicals. Environ. Mol. Mutagen. 16 (Suppl. 18), 55–137.2091924
Boorman, G.A., Montgomery, C.A., Jr., Eustis, S.L., Wolfe, M.J., McConnell, E.E., and Hardisty, J.F. (1985). Quality assurance in pathology for rodent carcinogenicity studies. In Handbook of Carcinogen Testing (H.A. Milman and E.K. Weisburger, Eds.), pp. 345–357. Noyes Publications, Park Ridge, NJ.
Boorman, G.A., Hickman, R.L., Davis, G.W., Rhodes, L.S., White, N.W., Griffin, T.A., Mayo, J., and Hamm, T.E., Jr. (1986). Serological titers to murine viruses in 90-day and 2-year studies. In Complications of Viral and Mycoplasmal Infections in Rodents to Toxicology Research and Testing (T.E. Hamm, Jr., Ed.), pp. 11–23. Hemisphere Publishing Corporation, Washington, DC.
Boorman, G.A., Dellarco, V., Dunnick, J.K., Chapin, R.E., Hunter, S., Hauchman, F., Gardner, H., Cox, M., and Sills, R.C. (1999). Drinking water disinfection byproducts: Review and approach to toxicity evaluation. Environ. Health Perspect. 107 (Suppl. 1), 207–217.10229719
Bove, F., Shim, Y., and Zeitz, P. (2002). Drinking water contaminants and adverse pregnancy outcomes: A review. Environ. Health Perspect. 110, 61–74.
Bowman, F.J., Borzelleca, J.F., and Munson, A.E. (1978). The toxicity of some halomethanes in mice. Toxicol. Appl. Pharmacol. 44, 213–215.675691
Bucher, J.R. (1998). Update on National Toxicology Program (NTP) assays with genetically altered or “transgenic” mice. Environ. Health Perspect. 106, 619–621.9755135
Bull, R.J., Birnbaum, L.S., Canter, K.P., Rose, J.B., Butterworth, B.E., Pegram, R., and Tuomisto, J. (1995). Water chlorination: Essential process or cancer hazard? Fundam. Appl. Toxicol. 28, 155–166.8835225
Cannon, R.E., Spalding, J.W., Trempus, C.S., Szczesniak, C.J., Virgil, K.M., Humble, M.C., and Tennant, R.W. (1997). Kinetics of wound-induced v-Ha-ras transgene expression and papilloma development in transgenic Tg.AC mice. Mol. Carcinog. 20, 108–114.9328441
Chevrier, C., Junod, B., and Cordier, S. (2004). Does ozonation of drinking water reduce the risk of bladder cancer? Epidemiology 15, 605–614.15308961
Christian, M.S., York, R.G., Hoberman, A.M., Fisher, L.C., and Brown, W.R. (2002). Oral (drinking water) two-generation reproductive toxicity study of bromodichloromethane (BDCM) in rats. Int. J. Toxicol. 21, 115–146.12022631
Chu, I., Villeneuve, D.C., Secours, V.E., Becking, G.C., and Valli, V.E. (1982). Toxicity of trihalomethanes: I. The acute and subacute toxicity of chloroform, bromodichloromethane, chlorodibromomethane and bromoform in rats. J. Environ. Sci. Health B17, 205–224.
Code of Federal Regulations (CFR) 21, Part 58.
Code of Federal Regulations (CFR) 40, Part 141.
Code of Federal Regulations (CFR) 40, §141.12.
Code of Federal Regulations (CFR) 40, §141.64.
Condie, L.W., Smallwood, C.L., and Laurie, R.D. (1983). Comparative renal and hepatotoxicity of halomethanes: Bromodichloromethane, bromoform, chloroform, dibromochloromethane and methylene chloride. Drug Chem. Toxicol. 6, 563–578.6653442
Cox, D.R. (1972). Regression models and life-tables. J. R. Stat. Soc. B34, 187–220.
DeMarini, D.M., Shelton, M.L., Warren, S.H., Ross, T.M., Shim, J.-Y., Richard, A.M., and Pegram, R.A. (1997). Glutathione S-transferase-mediated induction of GC→AT transitions by halomethanes in Salmonella. Environ. Mol. Mutagen. 30, 440–447.9435885
Dixon, W.J., and Massey, F.J., Jr. (1957). Introduction to Statistical Analysis, 2nd ed., pp. 276–278, 412. McGraw-Hill Book Company, Inc., New York.
Donehower, L.A., Harvey, M., Slagle, B.L., McArthur, M.J., Montgomery, C.A., Jr., Butel, J.S., and Bradley, A. (1992). Mice deficient for p53 are developmentally normal but susceptible to spontaneous tumours. Nature 356, 215–221.1552940
Dunn, O.J. (1964). Multiple comparisons using rank sums. Technometrics 6, 241–252.
Dunnett, C.W. (1955). A multiple comparison procedure for comparing several treatments with a control. J. Am. Stat. Assoc. 50, 1096–1121.
Dunson, D.B., Haseman, J.K., van Birgelen, A.P.J.M., Stasiewicz, S., and Tennant, R.W. (2000). Statistical analysis of skin tumor data from Tg.AC mouse bioassays. Toxicol. Sci. 55, 293–302.10828260
Eastin, W.C., Haseman, J.K., Mahler, J.F., and Bucher, J.R. (1998). The National Toxicology Program evaluation of genetically altered mice as predictive models for identifying carcinogens. Toxicol. Pathol. 26, 461–473.9715504
Fawell, J., Robinson, D., Bull, R., Birnbaum, L., Boorman, G., Butterworth, B., Daniel, P., Galal-Gorchev, H., Hauchman, F., Julkunen, P., Klaassen, C., Krasner, S., Orme-Zavaleta, J., Reif, J., and Tardiff, R. (1997). Disinfection by-products in drinking water: Critical issues in health effects research. Environ. Health Perspect. 105, 108–109.9074890
Federal Register (1979). National Interim Primary Drinking Water Regulations: Control of Trihalomethanes in Drinking Water. Vol. 44, No. 231. U.S. Environmental Protection Agency, Washington, DC.
Fujie, K., Aoki, T., and Wada, M. (1990). Acute and subacute cytogenetic effects of the trihalomethanes on rat bone marrow cells in vivo. Mutat. Res. 242, 111–119.2233827
Fujie, K., Aoki, T., Ito, Y., and Maeda, S. (1993). Sister-chromatid exchanges induced by trihalomethanes in rat erythroblastic cells and their suppression by crude catechin extracted from green tea. Mutat. Res. 300, 241–246.7687024
Gart, J.J., Chu, K.C., and Tarone, R.E. (1979). Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. JNCI 62, 957–974.285297
George, M.H., Olson, G.R., Doerfler, D., Moore, T., Kilburn, S., and DeAngelo, A.B. (2002). Carcinogenicity of bromodichloromethane administered in drinking water to male F344/N rats and B6C3F_1_ mice. Int. J. Toxicol. 21, 219–230.12055023
Geter, D., George, M.H., Moore, T., Kilburn, S., Huggins-Clark, G., and DeAngelo, A.B. (2004). Vehicle and mode of administration effects on the induction of aberrant crypt foci in the colons of male F344/N rats exposed to bromodichloromethane. J. Toxicol. Environ. Health 67, 23–29.
Gibbons, J., and Laha, S. (1999). Water purification systems: A comparative analysis based on the occurrence of disinfection by-products. Environ. Pollut. 106, 425–428.15093038
Gottlieb, M.S., and Carr, J.K. (1982). Case-control cancer mortality study and chlorination of drinking water in Louisiana. Environ. Health Perspect. 46, 169–177.7151759
Harris, C.C. (1996a). Structure and function of the p53 tumor suppresor gene: Clues for rational cancer therapeutic strategies. J. Natl. Cancer Inst. 88, 1442–1455.8841019
Harris, C.C. (1996b). p53 Tumor suppressor gene: From the basic research laboraory to the clinic - an abridged historical perspective. Carcinogenesis 17, 1187–1198.8681432
Harris, C.C. (1996c). The 1995 Walter Hubert Lecture - molecular epidemiology of human cancer: Insights from the mutational analysis of the p53 tumour-suppressor gene. Brit. J. Cancer 73, 261–269.8562328
Hayashi, M., Kishi, M., Sofuni, T., and Ishidate, M., Jr. (1988). Micronucleus tests in mice on 39 food additives and eight miscellaneous chemicals. Food Chem. Toxicol. 26, 487–500.3169648
Hildesheim, M.E., Cantor, K.P., Lynch, C.F., Dosemeci, M., Lubin, J., Alavanja, M., and Craun, G. (1998). Drinking water source and chlorination by-products. II. Risk of colon and rectal cancers. Epidemiology 9, 29–35.9430265
Hoehn, R.C., Randall, C.W., Goode, R.P., and Shaffer, P.T.B. (1978). Chlorination and water treatment for minimizing trihalomethanes in drinking water. In Water Chlorination: Environmental Impact and Health Effects (R.L. Jolly, H. Gorchev, and D. Hamilton, Eds.), Vol. 2, pp. 519–535. Ann Arbor Sciences Publishers, Inc., Ann Arbor, MI.
Hollander, M., and Wolfe, D.A. (1973). Nonparametric Statistical Methods, pp. 120–123. John Wiley and Sons, New York.
Honchel, R., Rosenzweig, B.A., Thompson, K.L., Blanchard, K.T., Furst, S.M., Stoll, R.E., and Sistare, F.D. (2001). Loss of palindromic symmetry in Tg.AC mice with a nonresponder phenotype. Mol. Carcinog. 30, 99–110.11241757
Integrated Laboratory Systems (ILS) (1990). Micronucleus Data Management and Statistical Analysis Software, Version 1.4. ILS, Inc., P.O. Box 13501, Research Triangle Park, NC 27707.
International Agency for Research on Cancer (IARC) (1999a). IARC Monographs on the Evaluation of Carcinogenic Risks to Humans. Chloroform. Vol. 72. IARC, Lyon, France.
International Agency for Research on Cancer (IARC) (1999b). IARC Monographs on the Evaluation of Carcinogenic Risks to Humans. Bromodichloromethane. Vol. 71, Part 3, 1295–1304. IARC, Lyon, France.
Jonckheere, A.R. (1954). A distribution-free k-sample test against ordered alternatives. Biometrika 41, 133–145.
Källén, B.A.J., and Robert, E. (2000). Drinking water chlorination and delivery outcome – a registry-based study in Sweden. Reprod. Toxicol. 14, 303–309.10908833
Kaplan, E.L., and Meier, P. (1958). Nonparametric estimation from incomplete observations. J. Am. Stat. Assoc. 53, 457–481.
Kavlock, R., Chernoff, N., Carver, B., and Kopfler, F. (1979). Teratology studies in mice exposed to municipal drinking-water concentrates during organogenesis. Food Cosmet. Toxicol. 17, 343–347.520968
King, W.D., Marrett, L.D., and Woolcott, C.G. (2000). Case-control study of colon and rectal cancers and chlorination by-products in treated water. Cancer Epidemiol. Biomarkers Prev. 9, 813–818.10952098
Landi, S., Naccarati, A., Ross, M.K., Hanley, N.M., Dailey, L., Devlin, R.B., Vasquez, M., Pegram, R.A., and DeMarini, D.M. (2003). Induction of DNA strand breaks by trihalomethanes in primary human lung epithelial cells. Mutat. Res. 538, 41–50.12834753
Lawrence, C.E., Taylor, P.R., Trock, B.J., and Reilly, A.A. (1984). Trihalomethanes in drinking water and human colorectal cancer. J. Natl. Cancer Inst. 72, 563–568.6583440
Le Curieux, F., Gauthier, L., Erb, F., and Marzin, D. (1995). Use of the SOS chromotest, the Ames-fluctuation test and the newt micronucleus test to study the genotoxicity of four trihalomethanes. Mutagenesis 10, 333–341.7476270
Leder, A., Kuo, A., Cardiff, R.D., Sinn, E., and Leder, P. (1990). v-Ha-ras transgenic abrogates the initiation step in mouse skin tumorigenesis: Effects of phorbol esters and retinoic acid. Proc. Natl. Acad. Sci. 87, 9178–9182.2251261
Lilly, P.D., Andersen, M.E., Ross, T.M., and Pegram, R.A. (1998). A physiologically based pharmacokinetic description of the oral uptake, tissue dosimetry, and rates of metabolism of bromodichloromethane in the male rat. Toxicol. Appl. Pharmacol. 150, 205–217.9653052
McConnell, E.E., Solleveld, H.A., Swenberg, J.A., and Boorman, G.A. (1986). Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. JNCI 76, 283–289.3456066
McDorman, K.S., Chandra, S., Hooth, M.J., Hester, S.D., Schoonhoven, R., and Wolf, D.C. (2003). Induction of transitional cell hyperplasia in the urinary bladder and aberrant crypt foci in the colon of rats treated with individual and a mixture of drinking water disinfection by-products. Toxicol. Pathol. 31, 235–242.12696585
McGeehin, M.A., Reif, J.S., Becher, J.C., and Mangione, E.J. (1993). Case-control study of bladder cancer and water disinfection methods in Colorado. Am. J. Epidemiol. 138, 492–501.8213753
McGregor, D.B., Brown, A., Cattanach, P., Edwards, I., McBride, D., and Caspary, W.J. (1988). Responses of the L5178Y tk^+^/tk^−^ mouse lymphoma cell forward mutation assay. II: 18 coded chemicals. Environ. Mol. Mutagen. 11, 91–118.3338442
MacGregor, J.T., Wehr, C.M., Henika, P.R., and Shelby, M.D. (1990). The in vivo erythrocyte micronucleus test: Measurement at a steady state increases assay efficiency and permits integration with toxicity studies. Fundam. Appl. Toxicol. 14, 513–522.2111256
Mahler, J.F., Stokes, W., Mann, P.C., Takaoka, M., and Maronpot, R.R. (1996). Spontaneous lesions in aging FVB/N mice. Toxicol. Pathol. 24, 710–716.8994298
Mahler, J.F., Flagler, N.D., Malarkey, D.E., Mann, P.C., Haseman, J.K., and Eastin, W. (1998). Spontaneous and chemically induced proliferative lesions in Tg.AC transgenic and p53-heterozygous mice. Toxicol. Pathol. 26, 501–511.9715509
Maronpot, R.R., and Boorman, G.A. (1982). Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol. Pathol. 10, 71–80.28094716
Matsuoka, A., Yamakage, K., Kusakabe, H., Wakuri, S., Asakura, M., Noguchi, T., Sugiyama, T., Shimada, H., Nakayama, S., Kasahara, Y., Takahashi, Y., Miura, K.F., Hatanaka, M., Ishidate, M., Jr., Morita, T., Watanabe, K., Hara, M., Odawara, K., Tanaka, N., Hayashi, M., and Sofuni, T. (1996). Re-evaluation of chromosomal aberration induction on nine mouse lymphoma assay “unique positive” NTP carcinogens. Mutat. Res. 369, 243–252.8792842
Mink, F.L., Brown, T.J., and Rickabaugh, J. (1986). Absorption, distribution, and excretion of ^14^C-trihalomethanes in mice and rats. Bull. Environ. Contam. Toxicol. 37, 752–758.3779162
Munson, A.E., Sain, L.E., Sanders, V.M., Kauffmann, B.M., White, K.L., Jr., Page, D.G., Barnes, D.W., and Borzelleca, J.F. (1982). Toxicology of organic drinking water contaminants: Trichloromethane, bromodichlormethane, dibromochloromethane and tribromomethane. Environ. Health Perspect. 46, 117–126.7151752
Narotsky, M.G., Pegram, R.A., and Kavlock, R.J. (1997). Effect of dosing vehicle on the developmental toxicity of bromodichloromethane and carbon tetrachloride in rats. Fundam. Appl. Toxicol. 40, 30–36.9398485
National Toxicology Program (NTP) (1987). Toxicology and Carcinogenesis Studies of Bromodichloromethane (CAS No. 75-27-4) in F344/N Rats and B6C3F_1_ Mice (Gavage Studies). Technical Report Series No. 321. NIH Publication No. 88-2537. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (1989). Toxicology and Carcinogenesis Studies of N-Methylolacrylamide (CAS No. 924-42-5) in F344/N Rats and B6C3F_1_ Mice (Gavage Studies). Technical Report Series No. 352. NIH Publication No. 89-2807. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (2006). Toxicology and Carcinogenesis Studies of Bromodichloromethane (CAS No. 75-27-4) in F344/N Rats and B6C3F_1_ Mice (Drinking Water Studies). Technical Report Series No. 532. NIH Publication No. 06-4468. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007a). Toxicology Studies of Dichloroacetic Acid (CAS No. 79-43-6) in Genetically Modified (FVB Tg.AC Hemizygous) Mice (Dermal and Drinking Water Studies) and Carcinogenicity Studies Of Dichloroacetic Acid in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Drinking Water Studies). Report Series No. GMM 11. NIH Publication No. 07-4428. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007b). Toxicology Studies of Sodium Bromate (CAS No. 7789-38-0) in Genetically Modified (FVB Tg.AC Hemizygous) Mice (Dermal and Drinking Water Studies) and Carcinogenicity Studies Of Dichloroacetic Acid in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Drinking Water Studies). Report Series No. GMM 6. NIH Publication No. 07-4423. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
Pegram, R.A., Andersen, M.E., Warren, S.H., Ross, T.M., and Claxton, L.D. (1997). Glutathione S-transferase-mediated mutagenicity of trihalomethanes in Salmonella typhimurium: Contrasting results with bromodichloromethane and chloroform. Toxicol. Appl. Pharmacol. 144, 183–188.9169083
Potter, C.L., Chang, L.W., DeAngelo, A.B., and Daniel, F.B. (1996). Effects of four trihalomethanes on DNA strand breaks, renal hyaline droplet formation and serum testosterone in male F-344 rats. Cancer Lett. 106, 235–242.8844978
Pritchard, J.B., French, J.E., Davis, B.J., and Haseman, J.K. (2003). The role of transgenic mouse models in carcinogen identification. Environ. Health Perspect. 111, 444–454.12676597
Rao, G.N., Haseman, J.K., and Edmondson, J. (1989a). Influence of viral infections on body weight, survival, and tumor prevalence in Fischer 344/NCr rats on two-year studies. Lab. Anim. Sci. 39, 389–393.2554057
Rao, G.N., Piegorsch, W.W., Crawford, D.D., Edmondson, J., and Haseman, J.K. (1989b). Influence of viral infections on body weight, survival, and tumor prevalence of B6C3F_1_ (C57BL/6N × C3H/HeN) mice in carcinogenicity studies. Fundam. Appl. Toxicol. 13, 156–164.2767355
Rook, J.J. (1974). Formation of haloforms during chlorination of natural waters. J. Water Treat. Exam. 23, 234–243.
Rook, J.J. (1980). Possible pathways for the formation of chlorinated degradation products during chlorination of humic acids and resorcinol. In Water Chlorination: Environmental Impact and Health Effects, (R.L. Jolly, W.A. Brungs, and R.B. Cumming, Eds.), Vol. 3, pp. 85–98. Ann Arbor Science Publishers, Inc., Ann Arbor, MI.
Ruddick, J.A., Villeneuve, D.C., Chu, I., and Valli, V.E. (1983). A teratological assessment of four trihalomethanes in the rat. J. Environ. Sci. Health B18, 333–349.
Shirley, E. (1977). A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics 33, 386–389.884197
Simmon, V.F., Kauhanen, K., and Tardiff, R.G. (1977). Mutagenic activity of chemicals identified in drinking water. Dev. Toxicol. Environ. Sci. 2, 249–258.
Spalding, J.W., Momma, J., Elwell, M.R., and Tennant, R.W. (1993). Chemically induced skin carcinogenesis in a transgenic mouse line (TG.AC) carrying a v-Ha-ras gene. Carcinogenesis 14, 1335–1341.8330346
Spalding, J.W., French, J.E., Tice, R.R., Furedi-Machacek, M., Haseman, J.K., and Tennant, R.W. (1999). Development of a transgenic mouse model for carcinogenesis bioassays: Evaluation of chemically induced skin tumors in Tg.AC mice. Toxicol. Sci. 49, 241–254.10416269
Stevens, A.A., Slocum, C.J., Seeger, D.R., and Rebeck, G.G. (1976). Chlorination of organics in drinking water. J. Am. Water Works Assoc. 68, 615–620.
Stocker, K.J., Statham, J., Howard, W.R., and Proudlock, R.J. (1997). Assessment of the potential in vivo genotoxicity of three trihalomethanes: Chlorodibromomethane, bromodichloromethane, and bromoform. Mutagenesis 12, 169–173.9175643
Tarone, R.E. (1975). Tests for trend in life table analysis. Biometrika 62, 679–682.
Tennant, R.W., French, J.E., and Spalding, J.W. (1995). Identifying chemical carcinogens and assessing potential risk in short-term bioassays using transgenic mouse models. Environ. Health Perspect. 103, 942–950.8529591
Tennant, R.W., Spalding, J.W., and French, J.E. (1996). Evaluation of transgenic mouse bioassays for identifying carcinogens and noncarcinogens. Mutat. Res. 365, 119–127.8898993
Tennant, R.W., Stasiewicz, S., Mennear, J., French, J.E., and Spalding, J.W. (1999). Genetically altered mouse models for identifying carcinogens. IARC Sci. Publ. 146, 123–150.
Tennant, R.W., Stasiewicz, S., Eastin, W.C., Mennear, J.H., and Spalding, J.W. (2001). The Tg.AC (v-Ha-ras) transgenic mouse: Nature of the model. Toxicol. Pathol. 29, 51–59.11695562
Thompson, K.L., Rosenzweig, B.A., and Sistare, F.D. (1998). An evaluation of the hemizygous transgenic Tg.AC mouse for carcinogenicity testing of pharmaceuticals. II. A genotypic marker that predicts tumorigenic responsiveness. Toxicol. Pathol. 26, 548–555.9715514
Torti, V.R., Cobb, A.J., Wong, V.A., and Butterworth, B.E. (2002). Induction of micronuclei in wild-type and p53^+/−^ transgenic mice by inhaled bromodichloromethane. Mutat. Res. 520, 171–178.12297157
Trempus, C.S., Mahler, J.F., Ananthaswamy, H.N., Loughlin, S.M., French, J.E., and Tennant, R.W. (1998). Photocarcinogenesis and susceptibility to UV radiation in the v-Ha-ras transgenic Tg.AC mouse. J. Invest. Dermatol. 111, 445–451.9740239
Tumasonis, C., McMartin, D.N., and Bush, B. (1985). Lifetime toxicity of chloroform and bromodichloromethane when administered over a lifetime in rats. Ecotoxicol. Environ. Saf. 9, 233–240.3987603
Villanueva, C.M., Fernández, F., Malats, N., Grimalt, J.O., and Kogevinas, M. (2003). Meta-analysis of studies on individual consumption of chlorinated drinking water and bladder cancer. J. Epidemiol. Community Health 57, 166–173.12594192
Weisel, C.P., Kim, H., Haltmeier, P., and Klotz, J.B. (1999). Exposure estimates to disinfection by-products of chlorinated drinking water. Environ. Health Perspect. 107, 103–110.9924004
Williams, D.A. (1971). A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics 27, 103–117.5547548
Williams, D.A. (1972). The comparison of several dose levels with a zero dose control. Biometrics 28, 519–531.5037867
Williams, D.A. (1986). A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics 42, 183–186.3719054
Wright, J.M., Schwartz, J., and Dockery, D.W. (2004). The effect of disinfection by-products and mutagenic activity on birth weight and gestational duration. Environ. Health Perspect. 112, 920–925.15175183
Wright, J.T., Hansen, L., Mahler, J., Szczesniak, C., and Spalding, J.W. (1995). Odontogenic tumours in the v-Ha-ras (TG.AC) transgenic mouse. Arch. Oral Biol. 40, 631–638.7575235
Yang, C.-Y. (2004). Drinking water chlorination and adverse birth outcomes in Taiwan. Toxicology 198, 249–250.15138048
Young, T.B., Wolf, D.A., and Kanarek, M.S. (1987). Case-control study of colon cancer and drinking water trihalomethanes in Wisconsin. Int. J. Epidemiol. 16, 190–197.3610446
Zhao, G., and Allis, J.W. (2002). Kinetics of bromodichloromethane metabolism by cytochrome P450 isoenzymes in human liver microsomes. Chem. Biol. Interact. 140, 155–168.12076522