# SUMMARY OF TECHNICAL REPORTS REVIEW SUBCOMMITTEE COMMENTS

On September 27, 2005, the draft Report on the toxicology and carcinogenesis studies of bromodichloromethane received public review by the National Toxicology Program’s Board of Scientific Counselors’ Technical Reports Review Subcommittee. The review meeting was held at the National Institute of Environmental Health Sciences (NIEHS), Research Triangle Park, NC.

Dr. G.A. Boorman, NIEHS, introduced the studies of the water disinfection by-product bromodichloromethane in Tg.AC hemizygous and p53 haploinsufficient mice by different routes of administration. The proposed conclusions were:

Under the conditions of these drinking water studies, there was no evidence of carcinogenic activity of bromodichloromethane in male or female p53 haploinsufficient mice exposed to 175, 350, or 700 mg/L for 26 or 42 weeks.

Under the conditions of these gavage studies, there was no evidence of carcinogenic activity of bromodichloromethane in male or female p53 haploinsufficient mice exposed to 25, 50, or 100 mg/kg body weight 5 days per week for 26 or 41 weeks.

In both the drinking water and the gavage studies in p53 haploinsufficient mice, there were increased incidences of renal tubule degeneration in male mice and fatty change of the hepatocyte in female mice exposed to bromodichloromethane.

No treatment-related neoplasms or nonneoplastic lesions were seen in male or female Tg.AC hemizygous mice exposed dermally to 64, 128, or 256 mg bromodichloromethane/kg body weight 5 days per week for 26 or 39 weeks.

No treatment-related neoplasms were seen in male or female Tg.AC hemizygous mice exposed by drinking water to 175, 350, or 700 mg bromodichloromethane/L for 26 or 42 weeks.

No treatment-related neoplasms were seen in male Tg.AC hemizygous mice exposed by gavage to 25, 50, or 100 mg bromodichloromethane/kg body weight 5 days per week for 26 or 41 weeks. An increased incidence of multiple forestomach papillomas was seen in female Tg.AC hemizygous mice exposed to bromodichloromethane by gavage for 26 or 41 weeks.

In the drinking water and gavage studies in Tg.AC hemizygous mice, there were increased incidences of nephropathy and/or renal tubule degeneration in male mice and fatty changes and/or cytoplasmic vacuolization of the hepatocyte in female mice exposed to bromodichloromethane.

Dr. Birt, the first principal reviewer, thought the studies were well designed and conducted. She suggested adding details about the animal sources and also historical data, particularly regarding forestomach papillomas.

Dr. Vore, the second principal reviewer, also felt the study was well conducted, and she agreed with the conclusions.

Dr. Birt moved, and Dr. Vore seconded, that the conclusions be accepted as written. The motion was carried unanimously with six votes.