# NATIONAL TOXICOLOGY PROGRAM BOARD OF SCIENTIFIC COUNSELORS TECHNICAL REPORTS REVIEW SUBCOMMITTEE

The members of the Technical Reports Review Subcommittee who evaluated the draft NTP Report on bromodichloromethane on September 27, 2005, are listed below. Subcommittee members serve as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, subcommittee members have five major responsibilities in reviewing the NTP studies:

- to ascertain that all relevant literature data have been adequately cited and interpreted,
- to determine if the design and conditions of the NTP studies were appropriate,
- to ensure that the Technical Report presents the experimental results and conclusions fully and clearly,
- to judge the significance of the experimental results by scientific criteria, and
- to assess the evaluation of the evidence of carcinogenic activity and other observed toxic responses.

- Charlene A. McQueen, Ph.D., Chairperson
  College of Pharmacy
  University of Arizona
  Tucson, AZ
- Diane F. Birt, Ph.D., Principal Reviewer
  Department of Food Science & Human Nutrition
  Iowa State University
  Ames, IA
- Michael R. Elwell, D.V.M., Ph.D.
  Pathology, Drug Safety Evaluation
  Pfizer Global Research and Development
  Groton, CT
- Thomas A. Gasiewicz, Ph.D.
  Department of Environmental Medicine
  Environmental Health Sciences Center
  University of Rochester School of Medicine
  Rochester, NY
- John P. Giesy, Jr., Ph.D.
  Department of Zoology
  Michigan State University
  East Lansing, MI
- Shuk-Mei Ho, Ph.D.^*^
  Department of Surgery, Division of Urology
  University of Massachusetts Medical School
  Worcester, MA
- Stephen M. Roberts, Ph.D.
  Center for Environmental & Human Toxicology
  University of Florida
  Gainesville, FL
- Mary Vore, Ph.D., Principal Reviewer
  Graduate Center for Toxicology
  University of Kentucky
  Lexington, KY

## Special Ad Hoc Reviewers

- Kenny Crump, Ph.D.
  Environ International
  Ruston, LA
- Prescott Deininger, Ph.D.^*^
  Tulane University Medical Center
  New Orleans, LA
- Harish Sikka, Ph.D.
  Environmental Toxicology and Chemistry Laboratory
  State University of New York College at Buffalo
  Buffalo, NY
- Keith Soper, Ph.D.
  Merck Research Laboratories
  West Point, PA
- Vernon Walker, Ph.D.^*^
  Lovelace Respiratory Institute
  Albuquerque, NM

* Did not attend