# DISCUSSION AND CONCLUSIONS

Bromodichloromethane is a disinfection by-product of the chlorination of drinking water (Weisel et al., 1999). Bromodichloromethane was nominated to the NTP by the United States Environmental Protection Agency (EPA) for toxicity and carcinogenicity studies in transgenic mice to provide additional information in support of EPA drinking water regulations (40 CFR Part 141). A second goal was to determine whether transgenic mouse models could prove effective in either hazard identification or in prioritizing which disinfection by-products warranted further research (Fawell et al., 1997; Boorman et al., 1999).

The combined use of Tg.AC hemizygous mice and p53 haploinsufficient mice has been suggested as an effective means of identifying chemical carcinogens and assessing potential risk (Tennant et al., 1995). Tg.AC hemizygous mice were reported to respond to tumor promoters, mutagenic chemicals, and nonmutagenic chemicals, while p53 haploinsufficient mice responded to mutagens within 6 months, allowing the testing of more chemicals within a shorter period of time. The NTP evaluated drinking water and gavage routes of exposure both to evaluate the utility of the transgenic models and because inconsistent results had been reported between drinking water exposure and gavage administration for bromodichloromethane in 2-year rodent studies (IARC, 1999b). Dermal studies were also included for the Tg.AC hemizygous mice because it was reported that tumors usually occurred within 10 weeks of initiation of exposure (Tennant et al., 1995). A visually observable and quantitative tumor response could allow evaluation of either individual chemicals or disinfection by-product mixtures as they might be found with different disinfection processes in a very rapid and cost-effective manner.

Tg.AC hemizygous mice were dermally administered 0, 64, 128, or 256 mg bromodichloromethane/kg body weight for 26 or 39 weeks. There were no neoplastic or nonneoplastic lesions associated with dermal administration in either males or females at 26 or 39 weeks. The highest dose for this dermal study was more than twice that achieved on a mg/kg basis in either the drinking water or gavage studies conducted at the same time in this strain. The dose was administered in 3.3 mL acetone/kg body weight resulting in dose concentrations of 19.4, 38.8, and 77.6 mg/mL or 19,400 to 77,600 mg/L. The maximum allowable exposure concentration for a total of four common trihalomethanes found in drinking water is 0.1 mg/L (40 CFR §141.12). Measured concentrations of bromodichloromethane in drinking water samples are usually less than 10 µg/L (Gibbons and Laha, 1999; Wright et al., 2004).

In a study involving New Jersey municipal drinking water samples, the mean bromodichloromethane concentration was 5.7 µg/L with the maximum concentration of 48 µg/L (Weisel et al., 1999). Nearly identical bromodichloromethane drinking water concentrations were found in samples from 109 New England towns (Wright et al., 2004). The lowest concentration applied dermally in this study was more than 400,000 times the maximum bromodichloromethane concentrations reported in these studies (Weisel et al., 1999; Wright et al., 2004). One might conclude, based on this one dermal study, that bromodichloromethane is not toxic. Based on high cancer incidences reported in both rats and mice with bromodichloromethane gavage studies (NTP, 1987), one might alternatively conclude that dermal administration in Tg.AC hemizygous mice is a relatively insensitive model to predict toxicity or carcinogenicity of trihalomethanes.

Tg.AC hemizygous mice were exposed to drinking water containing 0, 175, 350, or 700 mg/L bromodichloromethane for 26 or 42 weeks. These exposure concentrations were the same as those used in the bromodichloromethane studies in male F344/N rats and female B6C3F_1_ mice conducted by the NTP (2006). In the Tg.AC hemizygous mice, exposures to 0, 175, 350, or 700 mg/L corresponded to doses of 18 to 64 mg bromodichloromethane/kg body weight to males and between 28 and 130 mg/kg to females. The mean body weights of the 700 mg/L males and females tended to be less than controls at the end of the studies. Water consumption declined with increasing exposure concentration, especially in males, suggesting that higher concentration exposures were not feasible. The incidences of hepatocyte fatty change were generally increased in exposed groups of females at 26 and 42 weeks. Nephropathy was observed in exposed groups of males, especially in the 700 mg/L group at 26 and 42 weeks. Renal tubule degeneration was also increased in male Tg.AC hemizygous mice exposed to bromodichloromethane in drinking water. This change was considered related to the bromodichloromethane exposure and was considered a less severe toxic change than nephropathy.

p53 Haploinsufficient mice were also exposed to drinking water containing 0, 175, 350, or 700 mg/L bromodichloromethane for 26 or 42 weeks. The highest exposures ranged from 55 to 65 mg bromodichloromethane/kg body weight to males and 98 to 100 mg/kg to females. The survival of exposed males and females was unaffected by bromodichloromethane exposure. The mean body weights of the 700 mg/L males and females were less than control mean body weights in both studies. Water consumption declined with increasing exposure concentration in males, but not females. The change was dramatic with 700 mg/L males drinking only 68% as much as the control group during the first 13 weeks of the study. They appeared to tolerate the bromodichloromethane somewhat better in the second half of the study, but water consumption by 700 mg/L males was only 74% to 76% that by controls at the end of the study. The incidences of renal tubule degeneration in 350 and 700 mg/L males were significantly greater than those in the control group at both 26 and 42 weeks. Whether the decreased water consumption contributed to the renal disease is not known. There was also a modest increase in nephropathy in the male mice. Incidences of fatty change in the liver were increased in females in the 26-week study and only marginally increased in the 42-week study. Increased incidences of fatty change in the liver were found in male and female rats and male mice in the NTP (1987) gavage study of bromodichloromethane, with only a marginal increase in female mice. In both the Tg.AC hemizygous and p53 haploinsufficient mice, fatty change was more pronounced in females. This may have been due to the fact that female mice tolerated the bromodichloromethane and drank more, resulting in doses nearly double those of male mice.

There were no increases in neoplasms at any site in male or female Tg.AC hemizygous or p53 haploinsufficient mice exposed to bromodichloromethane in drinking water. These results are consistent with the lack of neoplasms in other bromodichloromethane drinking water studies in female mice (George et al., 2002; NTP, 2006). Thus, bromodichloromethane drinking water studies in two strains of transgenic mice dosed for up to 42 weeks and in B6C3F_1_ mice dosed for up to 2 years provide no evidence of carcinogenicity.

The results for rats exposed to bromodichloromethane in the drinking water are less clear. George et al. (2002) observed increased liver neoplasms in male rats exposed to 3.9 mg bromodichloromethane/kg body weight per day in drinking water; however, as exposure levels increased, liver neoplasm incidences decreased. Rats exposed to 20.6 mg/kg had a marginal increase in liver neoplasms (P≤0.1), and those exposed to 36.3 mg/kg had liver neoplasm rates similar to the control group. This decrease in liver neoplasm rates with increasing dose cannot be explained by increased mortality, and high dose male rat weights were 96% that of the control group. In an NTP (2006) study, no increase in the incidences of neoplasms was found in male F344/N rats exposed to bromodichloromethane in drinking water at daily levels of 6, 12, and 25 mg bromodichloromethane/kg body weight. Thus, bromodichloromethane drinking water results in rats are generally negative except for a marginal increased incidence of liver neoplasms in one low dose group without increased incidences of neoplasms at higher doses.

Male and female Tg.AC hemizygous mice were administered 25, 50, or 100 mg/kg bromodichloromethane in corn oil by gavage for 26 or 41 weeks. The survival of dosed males and females was similar to that of the vehicle control groups in both studies. There was no effect of bromodichloromethane exposure on mean body weights in males, while the mean body weights of dosed females tended to be greater than those of vehicle controls. The incidences of multiple squamous cell papilloma of the forestomach in the 100 mg/kg females were significantly greater than those of the vehicle controls in both studies. However, the incidence of single forestomach papillomas in female mice generally decreased with increasing exposure concentration. It is perhaps noteworthy that the increased forestomach neoplasms were not seen in the males. There were no increases in papillomas in the integumentary system of males or females in this drinking water study. Further, there was no increase in papillomas at the site of application in dermal studies in Tg.AC hemizygous mice of either sex.

This suggests that there was no direct or systemic effect of bromodichloromethane on the squamous epithelial cells of the integumentary system. The incidences of hepatocyte fatty change were increased in dosed females compared to vehicle control groups in both studies. The incidences of renal tubule degeneration in 100 mg/kg males were significantly increased in both studies. The incidences of renal changes in male mice receiving approximately 30 or 60 mg/kg in drinking water were higher than those in mice receiving 50 or 100 mg/kg by gavage. This suggests that the decrease in water consumption associated with drinking water exposure may have contributed to the renal disease. The changes in the kidney in male mice and in the liver of female mice related to toxicity suggest that a toxic dose was reached in this gavage study.

Male and female p53 haploinsufficient mice were administered 0, 25, 50, or 100 mg bromodichloromethane/kg corn oil by gavage for 26 or 41 weeks. The survival of dosed males and females was similar to that of the vehicle control groups in both studies. The mean body weights of 50 and 100 mg/kg males were decreased as were those for females administered 50 mg/kg for 26 or 41 weeks. The incidences of fatty change in hepatocytes of 100 mg/kg females were significantly greater than those of the vehicle control groups for both studies. The incidences of renal tubule degeneration in 100 mg/kg males were significantly greater than those of the vehicle control groups for both studies. There were no increases in neoplasms at any site for male or female mice in either study.

In contrast to the 2-year studies where all four of the sex and species combinations evaluated had increased incidences of tumors with bromodichloromethane gavage exposure (NTP, 1987), only one of four of the transgenic models showed increased cancer rates. Only a marginal increase in multiple forestomach papillomas was observed in the female Tg.AC hemizygous mice. The lack of an increase in neoplasms at other sites and lack of an increase of neoplasms in the males is surprising. Tg.AC hemizygous mice are reported to be very sensitive to tumor induction (Tennant et al., 1995). Male B6C3F_1_ mice had increased incidences of kidney adenomas and adenocarcinomas when given 50 mg/kg by gavage for 2 years (NTP, 1987). In the same study, bromodichloromethane exposure caused an increase in both hepatocellular adenomas and hepatocellular carcinomas at 75 and 150 mg/kg. In the current study, doses of bromodichloromethane in the Tg.AC hemizygous mouse exceeded those that caused increased tumor incidences in the B6C3F_1_ mouse.

Other chemicals that cause cancer in 2-year rodent studies have also failed to cause neoplasms in the Tg.AC hemizygous mouse model. N-methylolacrylamide exposure caused increased incidences of harderian gland, liver, and lung neoplasms in male and female B6C3F_1_ mice as well as increased incidences of ovarian neoplasms in females in 2-year studies (NTP, 1989). N-methylolacrylamide failed to cause tumors in Tg.AC hemizygous mice when evaluated both by oral gavage and dermal application at the highest dose used in the 2-year study (Eastin, 1998). In a review of 38 chemicals evaluated by NIEHS/NTP in genetically altered mice, eleven (29%) of the chemicals that produced tumors in the 2-year assays were not detected as carcinogens in the transgenic mouse models (Bucher, 1998). A larger review found that the Tg.AC model has about a 77% accuracy for detecting potential carcinogens (Pritchard et al., 2003).

The results in the p53 haploinsufficient mice are also somewhat surprising, as this strain is expected to respond to mutagenic chemicals. Bromodichloromethane has been shown to be mutagenic in some assays (McGregor et al., 1988; DeMarini et al., 1997; Landi et al., 2003), although negative results have been reported in several other assays (NTP, 1987; Anderson et al., 1990), perhaps as a result of inadequate exposure due to the volatility of the chemical. However, results of erythrocyte micronucleus assays reported in the current study also provide no clear indication of mutagenicity following subchronic exposure of mice to bromodichloromethane. In the current study, p53 haploinsufficient mice administered bromodichloromethane by gavage failed to produce increased incidences of neoplasms at any site.

One goal of the current studies was to determine whether genetically modified mice would prove useful as a rapid screen for disinfection by-products found in drinking water. However, these studies, which use several routes of exposure, provide no evidence that two common strains of transgenic mice are a sensitive or rapid means of assessing potential toxicity of trihalomethanes in the drinking water. The utility of these strains for assessing other classes of disinfection by-products is under study. Another goal of the current studies was to attempt to replicate the previously observed disparity in neoplasm incidences between bromodichloromethane given by gavage and bromodichloromethane given in drinking water. Bromodichloromethane has been shown to cause colon and kidney neoplasms in rats and kidney (males) and liver (females) neoplasms in mice in 2-year gavage studies, but failed to cause neoplasms in male rats or female mice in a 2-year drinking water study (NTP, 1987, 2006). In the present study, bromodichloromethane failed to cause neoplasms in p53 haploinsufficient or male Tg.AC hemizygous mice by either route. The modest increase in multiple stomach papillomas in female Tg.AC hemizygous mice in the gavage studies but not in the drinking water studies is consistent with the route differences found in the previous 2-year studies. However, the lack of concordance between neoplasm sites in the 2-year studies (colon, liver, kidney) and the current studies suggests that the Tg.AC hemizygous mouse is perhaps not the best model for pursuing which route of bromodichloromethane exposure may be most predictive for humans. This remains the crucial question for bromodichloromethane because the role of trihalomethane exposure in the drinking water and the potential risk for colon cancer in humans is still subject to debate (Lawrence et al., 1984; Young et al., 1987; King et al., 2000).

In conclusion, though bromodichloromethane is a known rodent carcinogen, no neoplastic lesions observed in p53 haploinsufficient mice administered bromodichloromethane by gavage or in drinking water were attributable to chemical exposure. In Tg.AC hemizygous mice administered bromodichloromethane dermally, by gavage, or in drinking water, a marginal increase in forestomach papillomas was found only in the female mice dosed by gavage. These studies suggest that these transgenic mouse models are not a sensitive and rapid means of assessing potential toxicity and carcinogenicity of trihalomethanes as they occur in the drinking water.

## Conclusions

Under the conditions of these drinking water studies, there was no evidence of carcinogenic activity^*^ of bromodichloromethane in male or female p53 haploinsufficient mice exposed to 175, 350, or 700 mg/L for 26 or 42 weeks.

Under the conditions of these gavage studies, there was no evidence of carcinogenic activity^*^ of bromodichloromethane in male or female p53 haploinsufficient mice exposed to 25, 50, or 100 mg/kg body weight 5 days per week for 26 or 41 weeks.

In both the drinking water and the gavage studies in p53 haploinsufficient mice, there were increased incidences of renal tubule degeneration in male mice and fatty change of the hepatocyte in female mice exposed to bromodichloromethane.

No treatment-related neoplasms or nonneoplastic lesions were seen in male or female Tg.AC hemizygous mice exposed dermally to 64, 128, or 256 mg bromodichloromethane/kg body weight 5 days per week for 26 or 39 weeks.

No treatment-related neoplasms were seen in male or female Tg.AC hemizygous mice exposed by drinking water to 175, 350, or 700 mg bromodichloromethane/L for 26 or 42 weeks.

No treatment-related neoplasms were seen in male Tg.AC hemizygous mice exposed by gavage to 25, 50, or 100 mg bromodichloromethane/kg body weight 5 days per week for 26 or 41 weeks. An increased incidence of multiple forestomach papillomas was seen in female Tg.AC hemizygous mice exposed to bromodichloromethane by gavage for 26 or 41 weeks.

In the drinking water and gavage studies in Tg.AC hemizygous mice, there were increased incidences of nephropathy and/or renal tubule degeneration in male mice and fatty change and/or cytoplasmic vacuolization of the hepatocyte in female mice exposed to bromodichloromethane.

* Explanation of Levels of Evidence of Carcinogenic Activity is on page 13. A summary of the Technical Reports Review Subcommittee comments and the public the discussion on this Report appears on page 15.