# RESULTS

## 26-Week Dermal Study in Tg.AC Hemizygous Mice

### Dose Selection Rationale

The bromodichloromethane doses administered in this 26-week dermal study (64, 128, and 256 mg/kg) were the three highest doses administered in a 2-week NTP range-finding study in FVB/N mice. In the range-finding study, these doses were not found to produce serious survival or toxicity effects and thus would be appropriate for longer term studies. Because 256 mg/kg was more than twice the gavage dose and expected drinking water dose, this was considered a reasonable high dose for the dermal study.

### Positive Control Tg.AC Hemizygous Mice

12-O-Tetradecanoylphorbol-13-acetate (TPA) (1.25 µg) was dermally administered to groups of 15 males and 15 females three times weekly. Eighty-seven percent of males and all females developed more than 20 skin papillomas each by week 24 (data not shown). This is consistent with historical rates found in other studies (Tennant et al., 2001).

### Survival

Estimates of 26-week survival probabilities for male and female Tg.AC hemizygous mice are shown in Table 2. The survival of dosed males and females was similar to that of the vehicle controls.

### Body Weights, Clinical Findings, and Organ Weights

Mean body weights of dosed groups of males and females were similar to those of the vehicle controls (Figure 1 and Tables 3 and 4). There were no clinical findings related to bromodichloromethane administration. Organ weights of treated males and females were similar to those of the vehicle controls (Table H1).

### Hematology

The hematology data for Tg.AC hemizygous mice in the 26-week dermal study of bromodichloromethane are listed in Table G1. A very minimal (2%) decrease in mean cell hemoglobin concentration was identified in 256 mg/kg female mice; the value was not below what would be considered an acceptable reference limit and was not considered clinically or toxicologically relevant. No changes occurred in other variables.

### Pathology and Statistical Analyses

There were no statistically or biologically significant increases in the incidences of neoplasms or nonneoplastic lesions in Tg.AC hemizygous mice dermally administered bromodichloromethane for 26 weeks. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables A1, A2, A3, and A4.

TABLE 2 Survival of Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Bromodichloromethane

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Male
Animals initially in study | 15 | 15 | 15 | 15
Moribund | 2 | 1 | 0 | 0
Natural deaths | 0 | 0 | 0 | 2
Animals surviving to study termination | 13 | 14 | 15 | 13
Percent probability of survival at end of study^a^ | 87 | 93 | 100 | 87
Mean survival (days)^b^ | 176 | 180 | 183 | 177
Survival analysis^c^ | P=1.000 | P=0.984N | p=0.464N | P=1.000N
Female
Animals initially in study | 15 | 15 | 15 | 15
Moribund | 2 | 3 | 1 | 4
Natural deaths | 2 | 2 | 2 | 1
Animals surviving to study termination | 11 | 10 | 12 | 10
Percent probability of survival at end of study | 73 | 67 | 80 | 67
Mean survival (days) | 165 | 167 | 172 | 164
Survival analysis | P=0.966 | P=1.000 | P=0.945N | P=1.000

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice)

c The result of the life table trend test (Tarone, 1975) is in the vehicle control column, and the results of the life table pairwise comparisons (Cox, 1972) with the vehicle controls are in the dosed group columns. A lower mortality in a dose group is indicated by N.

FIGURE 1 Growth Curves for Male and Female Tg.AC Hemizygous Mice Administered Bromodichloromethane Dermally for 26 Weeks

TABLE 3 Mean Body Weights and Survival of Male Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Bromodichloromethane

Weeks on Study | Vehicle Control | | 64 mg/kg | | | 128 mg/kg | | | 256 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 24.0 | 15 | 23.9 | 100 | 15 | 23.9 | 100 | 15 | 24.3 | 101 | 15
2 | 24.3 | 15 | 23.6 | 97 | 15 | 24.4 | 100 | 15 | 25.4 | 105 | 15
3 | 25.5 | 15 | 24.8 | 97 | 15 | 25.1 | 98 | 15 | 25.2 | 99 | 15
4 | 26.3 | 15 | 26.0 | 99 | 15 | 26.2 | 100 | 15 | 26.6 | 101 | 15
5 | 26.7 | 15 | 26.3 | 99 | 15 | 27.0 | 101 | 15 | 27.2 | 102 | 15
6 | 27.7 | 15 | 27.2 | 98 | 15 | 27.8 | 100 | 15 | 28.1 | 101 | 15
7 | 27.6 | 15 | 27.7 | 100 | 15 | 28.6 | 104 | 15 | 28.1 | 102 | 15
8 | 29.0 | 15 | 28.6 | 99 | 15 | 29.0 | 100 | 15 | 29.1 | 100 | 15
9 | 29.0 | 15 | 29.0 | 100 | 15 | 29.4 | 101 | 15 | 29.1 | 100 | 15
10 | 29.4 | 15 | 29.3 | 100 | 15 | 29.7 | 101 | 15 | 29.3 | 100 | 15
11 | 29.7 | 15 | 29.7 | 100 | 15 | 30.1 | 101 | 15 | 29.9 | 101 | 15
12 | 30.5 | 15 | 29.7 | 97 | 15 | 30.3 | 99 | 15 | 30.0 | 98 | 15
13 | 30.9 | 15 | 30.1 | 97 | 15 | 30.9 | 100 | 15 | 30.7 | 99 | 15
14 | 31.1 | 15 | 30.7 | 99 | 15 | 31.5 | 101 | 15 | 31.6 | 102 | 15
15 | 31.1 | 15 | 31.2 | 100 | 15 | 32.3 | 104 | 15 | 31.6 | 102 | 15
16 | 31.6 | 15 | 30.8 | 98 | 15 | 32.4 | 103 | 15 | 32.0 | 101 | 15
17 | 32.3 | 14 | 31.0 | 96 | 15 | 32.5 | 101 | 15 | 31.7 | 98 | 15
18 | 32.4 | 14 | 31.2 | 96 | 15 | 32.2 | 99 | 15 | 32.0 | 99 | 14
19 | 31.9 | 14 | 31.4 | 98 | 15 | 32.7 | 103 | 15 | 32.5 | 102 | 14
20 | 32.3 | 14 | 32.2 | 100 | 14 | 33.0 | 102 | 15 | 32.9 | 102 | 14
21 | 33.3 | 14 | 33.4 | 100 | 14 | 34.1 | 102 | 15 | 33.4 | 100 | 14
22 | 33.8 | 13 | 33.4 | 99 | 14 | 34.3 | 102 | 15 | 33.6 | 99 | 14
23 | 34.3 | 13 | 34.2 | 100 | 14 | 34.3 | 100 | 15 | 33.9 | 99 | 13
24 | 34.6 | 13 | 33.6 | 97 | 14 | 34.8 | 101 | 15 | 33.7 | 97 | 13
25 | 34.8 | 13 | 34.1 | 98 | 14 | 35.3 | 101 | 15 | 33.9 | 97 | 13
26 | 35.1 | 13 | 34.5 | 98 | 14 | 36.0 | 103 | 15 | 34.4 | 98 | 13
Mean for weeks
1–13 | 27.7 | | 27.4 | 99 | | 27.9 | 100 | | 27.9 | 101
14–26 | 33.0 | | 32.4 | 98 | | 33.5 | 102 | | 32.9 | 100

TABLE 4 Mean Body Weights and Survival of Female Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Bromodichloromethane

Weeks on Study | Vehicle Control | | 64 mg/kg | | | 128 mg/kg | | | 256 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 20.1 | 15 | 20.0 | 100 | 15 | 20.2 | 101 | 15 | 20.5 | 102 | 15
2 | 20.6 | 15 | 20.2 | 98 | 15 | 20.1 | 98 | 15 | 20.7 | 101 | 15
3 | 21.3 | 15 | 21.0 | 99 | 15 | 21.0 | 99 | 15 | 21.9 | 103 | 15
4 | 22.0 | 15 | 21.8 | 99 | 15 | 21.3 | 97 | 15 | 22.7 | 103 | 15
5 | 22.7 | 15 | 22.4 | 99 | 15 | 22.5 | 99 | 15 | 23.5 | 104 | 15
6 | 23.4 | 15 | 23.0 | 98 | 15 | 23.4 | 100 | 15 | 23.9 | 102 | 15
7 | 24.0 | 15 | 23.5 | 98 | 15 | 23.8 | 99 | 15 | 24.0 | 100 | 15
8 | 24.2 | 15 | 24.2 | 100 | 15 | 23.2 | 96 | 15 | 24.1 | 100 | 15
9 | 24.3 | 15 | 24.2 | 100 | 15 | 23.5 | 97 | 15 | 24.1 | 99 | 15
10 | 24.4 | 15 | 24.7 | 101 | 15 | 24.2 | 99 | 15 | 24.6 | 101 | 15
11 | 25.0 | 15 | 24.4 | 98 | 15 | 24.4 | 98 | 15 | 24.8 | 99 | 15
12 | 25.0 | 14 | 24.8 | 99 | 15 | 24.3 | 97 | 15 | 25.3 | 101 | 14
13 | 25.2 | 14 | 25.4 | 101 | 15 | 25.2 | 100 | 15 | 25.9 | 103 | 14
14 | 25.6 | 14 | 25.7 | 100 | 15 | 25.7 | 100 | 15 | 26.1 | 102 | 14
15 | 25.8 | 13 | 26.1 | 101 | 14 | 25.7 | 100 | 15 | 26.9 | 104 | 14
16 | 26.2 | 13 | 25.8 | 99 | 14 | 25.9 | 99 | 15 | 26.7 | 102 | 13
17 | 26.0 | 13 | 26.1 | 100 | 14 | 25.5 | 98 | 14 | 27.2 | 105 | 13
18 | 26.5 | 13 | 25.7 | 97 | 13 | 26.3 | 99 | 14 | 26.6 | 100 | 13
19 | 26.8 | 13 | 25.8 | 96 | 12 | 26.1 | 97 | 13 | 26.9 | 100 | 13
20 | 25.8 | 12 | 26.4 | 102 | 12 | 26.9 | 104 | 12 | 27.7 | 107 | 13
21 | 26.4 | 12 | 27.2 | 103 | 12 | 27.6 | 105 | 12 | 28.5 | 108 | 13
22 | 26.5 | 12 | 26.7 | 101 | 12 | 27.7 | 105 | 12 | 29.2 | 110 | 11
23 | 26.6 | 12 | 27.4 | 103 | 11 | 27.9 | 105 | 12 | 29.8 | 112 | 11
24 | 28.7 | 11 | 27.9 | 97 | 11 | 28.4 | 99 | 12 | 30.0 | 105 | 10
25 | 28.8 | 11 | 27.9 | 97 | 11 | 29.1 | 101 | 12 | 30.2 | 105 | 10
26 | 28.3 | 11 | 28.0 | 99 | 11 | 28.7 | 101 | 12 | 29.5 | 104 | 10
Mean for weeks
1–13 | 23.2 | | 23.0 | 99 | | 22.9 | 98 | | 23.5 | 101
14–26 | 26.8 | | 26.7 | 100 | | 27.0 | 101 | | 28.1 | 105

## 39-Week Dermal Study in Tg.AC Hemizygous Mice

### Survival

Estimates of 39-week survival probabilities for male and female Tg.AC hemizygous mice are shown in Table 5. The survival of dosed males and females was similar to that of the vehicle controls.

### Body Weights, Clinical Findings, and Organ Weights

Mean body weights of dosed groups of males and females were similar to those of the vehicle controls (Figure 2 and Tables 6 and 7). There were no clinical findings related to bromodichloromethane administration. Absolute heart weights of 128 and 256 mg/kg females and the absolute lung weight of 256 mg/kg females were greater than those of the vehicle controls (Table H2). No differences in organ weights were observed in males.

### Pathology and Statistical Analyses

There were no statistically or biologically significant increases in the incidences of neoplasms or nonneoplastic lesions in Tg.AC hemizygous mice dermally administered bromodichloromethane for 39 weeks. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables A5, A6, A7, and A8.

TABLE 5 Survival of Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Bromodichloromethane

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Male
Animals initially in study | 10 | 10 | 10 | 10
Moribund | 3 | 0 | 1 | 1
Natural deaths | 1 | 2 | 0 | 1
Animals surviving to study termination | 6 | 8 | 9 | 8
Percent probability of survival at end of study^a^ | 60 | 80 | 90 | 80
Mean survival (days)^b^ | 244 | 243 | 273 | 262
Survival analysis^c^ | P=0.424N | P=0.730N | P=0.242N | P=0.566N
Female
Animals initially in study | 10 | 10 | 10 | 10
Moribund | 4 | 4 | 3 | 4
Natural deaths | 1 | 2 | 0 | 1
Animals surviving to study termination | 5 | 4 | 7 | 5
Percent probability of survival at end of study | 50 | 40 | 70 | 50
Mean survival (days) | 199 | 186 | 261 | 204
Survival analysis | P=0.849N | P=0.879 | P=0.472N | P=1.000N

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice)

c The result of the life table trend test (Tarone, 1975) is in the vehicle control column, and the results of the life table pairwise comparisons (Cox, 1972) with the vehicle controls are in the dosed group columns. A negative trend or lower mortality in a dose group is indicated by N.

FIGURE 2 Growth Curves for Male and Female Tg.AC Hemizygous Mice Administered Bromodichloromethane Dermally for 39 Weeks

TABLE 6 Mean Body Weights and Survival of Male Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Bromodichloromethane

Weeks on Study | Vehicle Control | | 64 mg/kg | | | 128 mg/kg | | | 256 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 24.1 | 10 | 24.5 | 102 | 10 | 24.4 | 101 | 10 | 24.9 | 103 | 10
2 | 23.5 | 10 | 25.2 | 107 | 10 | 24.9 | 106 | 10 | 24.9 | 106 | 10
3 | 25.6 | 10 | 26.4 | 103 | 10 | 26.0 | 102 | 10 | 26.3 | 103 | 10
4 | 26.2 | 10 | 27.4 | 105 | 10 | 26.8 | 102 | 10 | 27.0 | 103 | 10
5 | 26.6 | 10 | 27.6 | 104 | 10 | 27.0 | 102 | 10 | 27.1 | 102 | 10
6 | 27.7 | 10 | 28.2 | 102 | 10 | 27.6 | 100 | 10 | 28.2 | 102 | 10
7 | 28.2 | 10 | 28.7 | 102 | 10 | 28.2 | 100 | 10 | 28.4 | 101 | 10
8 | 28.8 | 10 | 29.4 | 102 | 10 | 29.2 | 101 | 10 | 29.4 | 102 | 10
9 | 29.4 | 10 | 30.2 | 103 | 10 | 29.2 | 99 | 10 | 29.8 | 101 | 10
10 | 29.4 | 10 | 30.3 | 103 | 10 | 29.2 | 99 | 10 | 29.0 | 99 | 10
11 | 30.6 | 10 | 31.6 | 103 | 10 | 29.9 | 98 | 10 | 30.9 | 101 | 10
12 | 30.5 | 10 | 31.1 | 102 | 10 | 30.3 | 99 | 10 | 31.1 | 102 | 10
13 | 31.1 | 10 | 31.6 | 102 | 10 | 31.1 | 100 | 10 | 31.2 | 100 | 10
14 | 31.1 | 10 | 32.5 | 105 | 9 | 31.1 | 100 | 10 | 30.8 | 99 | 10
15 | 31.7 | 10 | 33.0 | 104 | 9 | 31.3 | 99 | 10 | 32.2 | 102 | 10
16 | 31.6 | 10 | 33.5 | 106 | 9 | 31.8 | 101 | 10 | 32.3 | 102 | 10
17 | 31.3 | 10 | 33.0 | 105 | 9 | 31.6 | 101 | 10 | 31.4 | 100 | 10
18 | 32.3 | 10 | 32.9 | 102 | 9 | 31.6 | 98 | 10 | 29.9 | 93 | 10
19 | 33.1 | 10 | 33.9 | 102 | 9 | 32.2 | 97 | 10 | 32.2 | 97 | 10
20 | 32.7 | 10 | 34.3 | 105 | 9 | 33.0 | 101 | 10 | 32.0 | 98 | 10
21 | 33.4 | 10 | 35.1 | 105 | 9 | 33.8 | 101 | 10 | 33.6 | 101 | 10
22 | 33.3 | 10 | 35.9 | 108 | 8 | 33.6 | 101 | 10 | 33.9 | 102 | 10
23 | 33.6 | 9 | 36.0 | 107 | 8 | 34.7 | 103 | 10 | 34.0 | 101 | 10
24 | 34.2 | 9 | 36.2 | 106 | 8 | 34.3 | 100 | 10 | 33.1 | 97 | 10
25 | 34.8 | 9 | 36.2 | 104 | 8 | 35.0 | 101 | 10 | 33.8 | 97 | 9
26 | 34.5 | 9 | 36.5 | 106 | 8 | 35.2 | 102 | 10 | 34.9 | 101 | 9
27 | 34.9 | 9 | 36.7 | 105 | 8 | 34.8 | 100 | 10 | 34.7 | 99 | 9
28 | 34.8 | 9 | 36.6 | 105 | 8 | 34.6 | 99 | 10 | 34.6 | 99 | 9
29 | 35.3 | 9 | 36.9 | 105 | 8 | 36.0 | 102 | 10 | 35.4 | 100 | 9
30 | 37.1 | 8 | 37.5 | 101 | 8 | 36.0 | 97 | 10 | 36.3 | 98 | 9
31 | 36.1 | 7 | 38.0 | 105 | 8 | 36.2 | 100 | 10 | 35.7 | 99 | 9
32 | 35.5 | 7 | 38.2 | 108 | 8 | 35.9 | 101 | 10 | 35.9 | 101 | 9
33 | 36.9 | 7 | 38.8 | 105 | 8 | 35.8 | 97 | 10 | 35.6 | 97 | 9
34 | 37.1 | 7 | 39.0 | 105 | 8 | 36.8 | 99 | 10 | 36.2 | 98 | 9
35 | 38.9 | 6 | 39.0 | 100 | 8 | 36.8 | 95 | 10 | 36.3 | 93 | 9
36 | 38.2 | 6 | 37.7 | 99 | 8 | 36.8 | 96 | 10 | 37.1 | 97 | 9
37 | 37.9 | 6 | 38.9 | 103 | 8 | 36.3 | 96 | 10 | 36.0 | 95 | 9
38 | 37.5 | 6 | 38.5 | 103 | 8 | 35.9 | 96 | 10 | 34.2 | 91 | 9
39 | 37.7 | 6 | 39.0 | 103 | 8 | 37.4 | 99 | 9 | 35.6 | 94 | 8
Mean for weeks
1–13 | 27.8 | | 28.6 | 103 | | 28.0 | 101 | | 28.3 | 102
14–39 | 34.8 | | 36.3 | 104 | | 34.6 | 99 | | 34.1 | 98

TABLE 7 Mean Body Weights and Survival of Female Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Bromodichloromethane

Weeks on Study | Vehicle Control | | 64 mg/ka | | | 128 mg/kg | | | 256 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 20.0 | 10 | 20.2 | 101 | 10 | 20.0 | 100 | 10 | 20.1 | 101 | 10
2 | 20.1 | 10 | 19.9 | 99 | 10 | 20.3 | 101 | 10 | 19.9 | 99 | 10
3 | 20.5 | 10 | 20.9 | 102 | 10 | 21.1 | 103 | 10 | 21.0 | 102 | 10
4 | 21.7 | 10 | 21.3 | 98 | 10 | 21.6 | 100 | 10 | 21.5 | 99 | 10
5 | 22.6 | 10 | 22.1 | 98 | 10 | 22.2 | 98 | 10 | 22.2 | 98 | 10
6 | 23.3 | 10 | 22.8 | 98 | 10 | 22.5 | 97 | 10 | 22.6 | 97 | 10
7 | 23.7 | 10 | 23.6 | 100 | 10 | 23.8 | 100 | 10 | 24.0 | 101 | 9
8 | 22.8 | 10 | 23.4 | 103 | 10 | 23.4 | 103 | 10 | 23.9 | 105 | 9
9 | 24.1 | 9 | 23.7 | 98 | 10 | 23.8 | 99 | 10 | 24.7 | 103 | 9
10 | 24.3 | 9 | 23.5 | 97 | 10 | 23.9 | 98 | 10 | 24.4 | 100 | 9
11 | 24.9 | 9 | 24.3 | 98 | 10 | 24.8 | 100 | 10 | 25.5 | 102 | 9
12 | 25.2 | 9 | 24.1 | 96 | 10 | 24.6 | 98 | 10 | 25.5 | 101 | 9
13 | 25.1 | 9 | 24.6 | 98 | 9 | 25.3 | 101 | 10 | 25.4 | 101 | 9
14 | 25.2 | 9 | 24.4 | 97 | 9 | 25.6 | 102 | 10 | 25.4 | 101 | 9
15 | 25.5 | 7 | 25.2 | 99 | 7 | 26.0 | 102 | 10 | 26.0 | 102 | 8
16 | 25.4 | 7 | 25.1 | 99 | 6 | 25.7 | 101 | 10 | 26.5 | 104 | 8
17 | 24.7 | 7 | 26.1 | 106 | 6 | 25.8 | 105 | 10 | 26.2 | 106 | 8
18 | 26.0 | 6 | 24.7 | 95 | 6 | 26.1 | 100 | 10 | 26.4 | 102 | 8
19 | 25.7 | 6 | 25.8 | 100 | 6 | 26.4 | 103 | 10 | 26.7 | 104 | 8
20 | 25.7 | 6 | 25.9 | 101 | 6 | 26.6 | 104 | 10 | 25.7 | 100 | 7
21 | 25.5 | 6 | 27.4 | 108 | 6 | 27.3 | 107 | 10 | 26.3 | 103 | 7
22 | 26.1 | 6 | 26.7 | 102 | 6 | 27.4 | 105 | 10 | 26.4 | 101 | 7
23 | 26.3 | 6 | 26.9 | 102 | 6 | 27.6 | 105 | 10 | 26.0 | 99 | 7
24 | 26.7 | 6 | 27.0 | 101 | 6 | 28.1 | 105 | 10 | 26.0 | 97 | 7
25 | 26.3 | 6 | 27.6 | 105 | 6 | 27.9 | 106 | 10 | 26.2 | 100 | 7
26 | 27.1 | 6 | 27.5 | 102 | 6 | 28.6 | 106 | 10 | 26.1 | 96 | 7
27 | 27.3 | 6 | 27.5 | 101 | 6 | 28.3 | 104 | 10 | 25.5 | 93 | 7
28 | 27.4 | 6 | 27.7 | 101 | 5 | 28.4 | 104 | 10 | 26.5 | 97 | 6
29 | 27.0 | 6 | 26.9 | 100 | 4 | 29.1 | 108 | 10 | 27.5 | 102 | 6
30 | 27.0 | 6 | 27.0 | 100 | 4 | 29.5 | 109 | 10 | 27.4 | 102 | 6
31 | 26.2 | 6 | 26.7 | 102 | 4 | 29.5 | 113 | 10 | 27.3 | 104 | 6
32 | 26.3 | 6 | 27.1 | 103 | 4 | 28.4 | 108 | 10 | 27.7 | 105 | 5
33 | 26.8 | 6 | 27.0 | 101 | 4 | 27.8 | 104 | 10 | 27.8 | 104 | 5
34 | 25.8 | 6 | 26.7 | 104 | 4 | 30.2 | 117 | 8 | 28.2 | 109 | 5
35 | 26.6 | 6 | 27.6 | 104 | 4 | 31.5 | 118 | 7 | 27.8 | 105 | 5
36 | 26.7 | 6 | 28.5 | 107 | 4 | 30.9 | 116 | 7 | 28.2 | 106 | 5
37 | 26.6 | 6 | 27.4 | 103 | 4 | 31.2 | 117 | 7 | 28.2 | 106 | 5
38 | 27.6 | 5 | 26.0 | 94 | 4 | 31.5 | 114 | 7 | 28.4 | 103 | 5
39 | 27.7 | 5 | 27.9 | 101 | 4 | 32.2 | 116 | 7 | 28.8 | 104 | 5
Mean for weeks
1–13 | 22.9 | | 22.6 | 99 | | 22.9 | 100 | | 23.1 | 101
14–39 | 26.4 | | 26.7 | 101 | | 28.4 | 108 | | 26.9 | 102

## 26-Week Drinking Water Study in Tg.AC Hemizygous Mice

### Dose Selection Rationale

The exposure concentrations used in this 26-week drinking water study (175, 350, and 700 mg/L) were the same as those used in a previous 2-year drinking water study of bromodichloromethane in male F344/N rats and female B6C3F_1_ mice (NTP, 2006a).

### Positive Control Tg.AC Hemizygous Mice

TPA (1.25 µg) was dermally administered to groups of 15 males and 15 females three times weekly. All males and females developed more than 20 skin papillomas each by week 20 (data not shown). This is consistent with historical rates found in other studies (Tennant et al., 2001).

### Survival

Estimates of 26-week survival probabilities for male and female Tg.AC hemizygous mice are shown in Table 8. The survival of exposed males and females was similar to that of the control groups.

### Body Weights, Water and Compound Consumption, Clinical Findings, and Organ Weights

Mean body weights of males exposed to 350 mg/L were less than those of the controls after week 9 and those of 700 mg/L males were less after week 5 (Tables 9 and 10 and Figure 3). Mean body weights of 175, 350, and 700 mg/L females were greater than those of the controls after weeks 10, 22, and 23, respectively. Water consumption declined with increasing exposure concentration at the beginning of the study due to poor palatability (Tables J1 and J2). Females recovered from this taste aversion by the end of the study. While water consumption by exposed males did improve, it was still lower than controls at the end of the study. Drinking water concentrations of 175, 350, or 700 mg/L delivered average daily doses of approximately 20, 36, or 61 mg bromodichloromethane/kg body weight to males and 31, 61, or 130 mg/kg to females. No clinical findings related to bromodichloromethane exposure were observed. Absolute heart and right kidney weights of exposed males were significantly less than those of the control group (Table H3). The weights of these organs decreased with increasing dose, mirroring a similar pattern in overall body weight.

### Hematology

The hematology data for Tg.AC hemizygous mice in the 26-week drinking water study of bromodichloromethane are listed in Table G2. An apparent dose-related decrease in platelet counts occurred in 350 (7% decrease) and 700 (13% decrease) mg/L male mice; the values were not below what would be considered an acceptable reference limit, and the relevance was unknown. A treatment-related, but not exposure concentration-related, decrease in neutrophil counts occurred in 350 and 700 mg/L male mice; the relevance of this finding was questionable and may reflect a slightly higher than expected neutrophil count in the control males. No changes occurred in other variables.

TABLE 8 Survival of Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Bromodichloromethane

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Male
Animals initially in study | 15 | 15 | 15 | 15
Moribund | 2 | 3 | 3 | 1
Animals surviving to study termination | 13 | 12 | 12 | 14
Percent probability of survival at end of study^a^ | 87 | 80 | 80 | 93
Mean survival (days)^b^ | 178 | 167 | 177 | 181
Survival analysis^c^ | P=0.635N | P=0.922 | P=1.000 | P=0.984N
Female
Animals initially in study | 15 | 15 | 15 | 15
Moribund | 1 | 0 | 3 | 1
Natural deaths | 4 | 2 | 1 | 1
Animals surviving to study termination | 10 | 13 | 11 | 13
Percent probability of survival at end of study | 67 | 87 | 73 | 87
Mean survival (days) | 155 | 170 | 168 | 181
Survival analysis | P=0.343N | P=0.381N | P=0.855N | P=0.297N

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice)

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

TABLE 9 Mean Body Weights and Survival of Male Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Bromodichloromethane

Weeks on Study | 0 mg/L | | 175 mg/L | | | 350 mg/L | | | 700 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 23.1 | 15 | 22.6 | 98 | 15 | 22.6 | 98 | 15 | 22.7 | 98 | 15
2 | 24.6 | 15 | 24.1 | 98 | 15 | 23.2 | 94 | 15 | 20.8 | 85 | 15
3 | 26.1 | 15 | 25.7 | 99 | 15 | 25.0 | 96 | 15 | 23.9 | 92 | 15
4 | 26.8 | 15 | 26.7 | 100 | 15 | 25.8 | 96 | 15 | 25.9 | 97 | 15
5 | 27.8 | 15 | 27.7 | 100 | 15 | 27.3 | 98 | 15 | 26.5 | 95 | 15
6 | 29.4 | 15 | 28.9 | 98 | 15 | 28.1 | 96 | 15 | 27.3 | 93 | 15
7 | 30.0 | 15 | 29.4 | 98 | 15 | 28.6 | 95 | 15 | 27.4 | 91 | 15
S | 30.2 | 15 | 29.9 | 99 | 15 | 28.9 | 96 | 15 | 28.1 | 93 | 15
9 | 31.0 | 15 | 30.5 | 98 | 15 | 29.5 | 95 | 15 | 28.7 | 93 | 15
10 | 32.0 | 15 | 31.1 | 97 | 15 | 30.1 | 94 | 15 | 29.3 | 92 | 15
11 | 32.8 | 15 | 31.4 | 96 | 15 | 30.0 | 92 | 15 | 30.2 | 92 | 15
12 | 32.6 | 15 | 32.2 | 99 | 14 | 30.6 | 94 | 15 | 30.7 | 94 | 15
13 | 34.2 | 15 | 33.1 | 97 | 14 | 31.4 | 92 | 15 | 31.8 | 93 | 15
14 | 34.9 | 15 | 33.5 | 96 | 14 | 31.6 | 91 | 15 | 32.1 | 92 | 15
15 | 35.2 | 15 | 33.6 | 96 | 14 | 31.3 | 89 | 15 | 32.1 | 91 | 15
16 | 35.7 | 15 | 34.5 | 97 | 13 | 31.9 | 89 | 15 | 33.1 | 93 | 15
17 | 35.8 | 15 | 34.7 | 97 | 13 | 32.0 | 89 | 15 | 32.8 | 92 | 15
18 | 35.9 | 15 | 35.0 | 98 | 13 | 32.1 | 89 | 15 | 33.1 | 92 | 15
19 | 35.6 | 15 | 34.6 | 97 | 13 | 32.7 | 92 | 15 | 32.9 | 92 | 15
20 | 36.9 | 14 | 35.4 | 96 | 13 | 33.5 | 91 | 15 | 32.7 | 89 | 15
21 | 37.6 | 14 | 36.4 | 97 | 12 | 34.7 | 92 | 14 | 32.6 | 87 | 15
22 | 38.4 | 14 | 37.9 | 99 | 12 | 34.9 | 91 | 14 | 33.2 | 87 | 15
23 | 39.2 | 14 | 38.7 | 99 | 12 | 35.6 | 91 | 14 | 34.9 | 89 | 14
24 | 39.6 | 13 | 39.9 | 101 | 12 | 35.9 | 91 | 14 | 36.2 | 91 | 14
25 | 40.2 | 13 | 40.2 | 100 | 12 | 37.3 | 93 | 12 | 35.9 | 89 | 14
26 | 41.0 | 13 | 40.4 | 99 | 12 | 38.3 | 93 | 12 | 36.5 | 89 | 14
Mean for weeks
1–13 | 29.3 | | 28.7 | 98 | | 27.8 | 95 | | 27.2 | 93
14–26 | 37.4 | | 36.5 | 98 | | 34.0 | 91 | | 33.7 | 90

TABLE 10 Mean Body Weights and Survival of Female Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Bromodichloromethane

Weeks on Study | 0 mg/L | | 175 mg/L | | | 350 mg/L | | | 700 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 19.2 | 15 | 19.1 | 100 | 15 | 19.0 | 99 | 15 | 18.9 | 98 | 15
2 | 20.0 | 15 | 20.3 | 102 | 15 | 20.2 | 101 | 15 | 20.2 | 101 | 15
3 | 21.2 | 15 | 21.4 | 101 | 15 | 21.3 | 101 | 15 | 21.4 | 101 | 15
4 | 22.3 | 15 | 22.3 | 100 | 15 | 22.3 | 100 | 15 | 22.3 | 100 | 15
5 | 23.2 | 15 | 23.1 | 100 | 15 | 22.7 | 98 | 15 | 22.7 | 98 | 15
6 | 24.2 | 15 | 24.1 | 100 | 15 | 23.6 | 98 | 14 | 23.8 | 98 | 15
7 | 24.6 | 15 | 24.3 | 99 | 15 | 23.9 | 97 | 14 | 23.8 | 97 | 15
8 | 24.5 | 15 | 24.7 | 101 | 15 | 24.4 | 100 | 14 | 24.0 | 98 | 15
9 | 24.8 | 14 | 25.8 | 104 | 15 | 24.8 | 100 | 14 | 25.0 | 101 | 15
10 | 25.4 | 13 | 25.6 | 101 | 15 | 25.1 | 99 | 14 | 25.3 | 100 | 15
11 | 24.5 | 13 | 27.1 | 111 | 15 | 25.5 | 104 | 14 | 25.8 | 105 | 15
12 | 25.3 | 13 | 27.2 | 108 | 13 | 26.2 | 104 | 14 | 26.2 | 104 | 15
13 | 26.3 | 13 | 28.2 | 107 | 13 | 26.7 | 102 | 14 | 26.8 | 102 | 15
14 | 26.4 | 13 | 28.5 | 108 | 13 | 26.9 | 102 | 14 | 26.8 | 102 | 15
15 | 26.6 | 13 | 29.0 | 109 | 13 | 27.8 | 105 | 14 | 27.9 | 105 | 15
16 | 27.6 | 13 | 29.5 | 107 | 13 | 28.0 | 101 | 14 | 28.1 | 102 | 15
17 | 27.0 | 11 | 29.1 | 108 | 13 | 27.8 | 103 | 14 | 28.2 | 104 | 15
18 | 27.5 | 11 | 30.4 | 111 | 13 | 27.8 | 101 | 14 | 28.4 | 103 | 15
19 | 27.9 | 11 | 30.5 | 109 | 13 | 29.0 | 104 | 13 | 28.6 | 103 | 15
20 | 29.3 | 11 | 31.0 | 106 | 13 | 29.8 | 102 | 13 | 29.5 | 101 | 15
21 | 29.2 | 11 | 31.6 | 108 | 13 | 29.9 | 102 | 13 | 30.1 | 103 | 15
22 | 29.5 | 10 | 31.9 | 108 | 13 | 30.7 | 104 | 13 | 30.7 | 104 | 15
23 | 29.9 | 10 | 33.1 | 111 | 13 | 31.8 | 106 | 13 | 31.2 | 104 | 15
24 | 30.2 | 10 | 33.9 | 112 | 13 | 32.1 | 106 | 13 | 32.5 | 108 | 14
25 | 28.5 | 10 | 34.6 | 121 | 13 | 33.5 | 118 | 11 | 32.9 | 115 | 13
26 | 29.9 | 10 | 34.9 | 117 | 13 | 33.9 | 113 | 11 | 33.2 | 111 | 13
Mean for weeks
1–13 | 23.5 | | 24.1 | 103 | | 23.5 | 100 | | 23.6 | 100
14–26 | 28.4 | | 31.4 | 110 | | 29.9 | 105 | | 29.9 | 105

FIGURE 3 Growth Curves for Male and Female Tg.AC Hemizygous Mice Exposed to Bromodichloromethane in Drinking Water for 26 Weeks

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions of the liver and kidney. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables B1, B2, B3, and B4.

Liver: The incidences of hepatocyte fatty change in all exposed groups of females and hypertrophy in 350 and 700 mg/L females were significantly greater than those in the controls (Tables 11 and B4). The incidence of cytoplasmic vacuolization in 700 mg/L females was also significantly greater than that in the control group (Tables 11 and B4).

Liver lesions were generally of minimal severity and included hepatocyte fatty change, vacuolization, and hypertrophy. Fatty change and cytoplasmic vacuolization occurred together and were generally diffuse within the liver sections. Fatty change was characterized by the presence of variably sized, discrete, round (punch-hole) vacuoles within the cytoplasm. This change was considered to be consistent with intracytoplasmic lipid accumulation. Hepatocyte vacuolization was characterized by vacuoles that were not sharply defined and consisted of poorly demarcated clear spaces in the cytosol that separated irregular strands of eosinophilic cytoplasm. The vacuole area sometimes displayed light basophilic staining, a discoloration occasionally observed in controls. This change was considered to be consistent with hepatocellular glycogen accumulation. Hypertrophy was generally centrilobular and characterized by an increase in the size of the hepatocytes around the central vein. This was reflected in a decreased number of nuclei per unit of area in the affected areas.

Kidney: The incidences of renal tubule dilatation and renal tubule degeneration in all exposed groups of males, renal tubule hypertrophy in 350 and 700 mg/L males, and nephropathy in 700 mg/L males were significantly greater than those in the control group (Tables 11 and B2).

Kidney changes were generally of minimal severity and included nephropathy, renal tubule degeneration, renal tubule hypertrophy, renal tubular dilatation, and protein casts. Nephropathy consisted of a spectrum of changes that included small clusters of tubules with cytoplasmic basophilia (regeneration), tubular dilatation, proteinaceous casts, basement membrane thickening, and interstitial inflammation. Renal tubular degeneration consisted of vacuolization or flocculent cytoplasm in epithelial cells, necrosis of tubular epithelial cells, and faint tubular basophilia. The affected cells occasionally had large, bizarre nuclei, or were binucleated or multinucleated. Renal tubule hypertrophy consisted of tubules containing pale-stained hypertrophic epithelial cells that did not show other features suggestive of degeneration. Renal tubule dilatation was predominantly observed at the corticomedullary junction and consisted of enlarged tubular lumens lined by attenuated epithelium and filled with eosinophilic flocculent material (consistent with granular casts). Protein casts were evidenced as eosinophilic hyaline material filling the lumen of a tubule. On occasion, these casts could distend the tubule.

TABLE 11 Incidences of Selected Nonneoplastic Lesions in Male and Female Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Bromodichloromethane

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Male
Kidney^a^ | 15 | 15 | 15 | 15
Nephropathy^b^ | 4 (1.0)^c^ | 3 (1.3) | 4 (1.3) | 11^*^ (1.3)
Renal Tubule, Degeneration | 0 | 4^*^ (1.0) | 4^*^ (1.0) | 9^*^ (1.3)
Renal Tubule, Dilatation | 4 (1.0) | 11^*^ (1.2) | 14^**^ (1.6) | 15^**^ (1.7)
Renal Tubule, Hypertrophy | 1 (1.0) | 3 (1.0) | 6^*^ (1.2) | 11^**^ (1.0)
Protein Casts | 1 (1.0) | 2 (1.0) | 1 (1.0) | 1 (1.0)
Female
Liver | 15 | 15 | 15 | 15
Hepatocyte, Fatty Change | 0 | 4^*^ (1.0) | 8^**^ (1.1) | 10^**^ (1.5)
Hepatocyte, Hypertrophy | 1 (2.0) | 2 (2.5) | 8^**^ (2.4) | 12^**^ (2.8)
Hepatocyte, Vacuolization Cytoplasmic | 2 (1.5) | 5 (1.2) | 4 (1.5) | 8^*^ (1.6)

* Significantly different (P≤0.05) from the control group by the Fisher exact test

** (P≤0.01)

a Number of mice with tissue examined microscopically

b Number of mice with lesion

c Average severity of lesions in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked

## 42-Week Drinking Water Study in Tg.AC Hemizygous Mice

### Survival

Estimates of 42-week survival probabilities for male and female Tg.AC hemizygous mice are shown in Table 12. The survival of exposed males and females was similar to that of the control groups.

### Body Weights, Water and Compound Consumption, Clinical Findings, and Organ Weights

Although mean body weights of exposed males and females were similar to those of the controls during most of the study, mean body weights of 350 and 700 mg/L males were less than those of the controls during the last 2 weeks of the study, and mean body weights of 350 mg/L females were greater than those of the controls during the last half of the study (Figure 4 and Tables 13 and 14). Due to poor palatability, water consumption declined with increasing exposure concentration (Tables J3 and J4). During the first 13 weeks of the study, water consumption by males averaged 5.0 g/day for the controls and 3.2, 2.8, and 2.5 g/day for the 175, 350, and 700 mg/L groups, respectively. The decrease was less marked during weeks 14 to 42, averaging 4.5 g/day for the controls and 3.2 g/day for the 700 mg/L exposed group. In females, the decrease in water consumption with increasing exposure concentration was less, averaging 6.1 g/day for the controls, and between 4.2 and 4.6 g/day for exposed groups during the first 13 weeks of the study. As in the males, the decrease was less during weeks 14 to 42, averaging 5.3 g/day in the controls and between 4.4 and 4.8 g/day in the exposed females. Drinking water concentrations of 175, 350, or 700 mg/L delivered average daily doses of approximately 18, 33, or 64 mg/kg to males and 28, 49, or 111 mg/kg to females. No clinical findings related to bromodichloromethane exposure were observed. Absolute right kidney weights of 350 and 700 mg/L males were significantly less than those of the control group (Table H4). The weights of these organs decreased with increasing dose, mirroring a similar pattern in overall body weight.

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions of the liver and kidney. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables B5, B6, B7, and B8.

Liver: The incidences of hepatocyte fatty change in all exposed groups of females were significantly greater than that in the controls (0 mg/L, 0/10; 175 mg/L, 6/10; 350 mg/L, 6/10; 700 mg/L, 6/10; Table B8). Hepatocyte fatty change was morphologically similar to that previously described in the 26-week drinking water study.

Kidney: The incidences of renal tubule dilatation (1/10, 8/10, 8/10, 10/10) in exposed groups of males and nephropathy (4/10, 7/10, 8/10, 9/10) in 700 mg/L males were significantly greater than those in the control group (Table B6). The kidney lesions were morphologically similar to those previously described in the 26-week drinking water study.

TABLE 12 Survival of Tg.AC Hemizygous Mice in the 42-Week Drinking Water Study of Bromodichloromethane

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Male
Animals initially in study | 10 | 10 | 10 | 10
Moribund | 4 | 0 | 0 | 1
Natural deaths | 0 | 1 | 2 | 0
Animals surviving to study termination | 6 | 9 | 8 | 9
Percent probability of survival at end of study^a^ | 60 | 90 | 80 | 90
Mean survival (days)^b^ | 260 | 280 | 279 | 294
Survival analysis^c^ | P=0.263N | P=0.346N | P=0.610N | P=0.256N
Female
Animals initially in study | 10 | 10 | 10 | 10
Moribund | 3 | 2 | 5 | 5
Natural deaths | 2 | 0 | 1 | 1
Animals surviving to study termination | 5 | 8 | 4 | 4
Percent probability of survival at end of study | 50 | 80 | 40 | 40
Mean survival (days) | 251 | 276 | 254 | 248
Survival analysis | P=0.504 | P=0.332N | P=0.977 | P=1.000

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice)

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

FIGURE 4 Growth Curves for Male and Female Tg.AC Hemizygous Mice Exposed to Bromodichloromethane in Drinking Water for 42 Weeks

TABLE 13 Mean Body Weights and Survival of Male Tg.AC Hemizygous Mice in the 42-Week Drinking Water Study of Bromodichloromethane

Weeks on Study | 0 mg/L | | 175 mg/L | | | 350 mg/L | | | 700 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 22.4 | 10 | 22.7 | 101 | 10 | 23.2 | 104 | 10 | 22.8 | 102 | 10
2 | 23.7 | 10 | 24.0 | 101 | 10 | 23.3 | 98 | 10 | 20.6 | 87 | 10
3 | 25.0 | 10 | 26.1 | 104 | 10 | 25.0 | 100 | 10 | 23.8 | 95 | 10
4 | 25.6 | 10 | 27.5 | 107 | 10 | 26.5 | 104 | 10 | 25.6 | 100 | 10
5 | 27.2 | 10 | 28.6 | 105 | 10 | 27.6 | 102 | 10 | 26.3 | 97 | 10
6 | 27.9 | 10 | 29.1 | 104 | 10 | 28.5 | 102 | 10 | 27.0 | 97 | 10
7 | 28.5 | 10 | 29.4 | 103 | 10 | 28.7 | 101 | 10 | 27.6 | 97 | 10
8 | 28.1 | 10 | 30.6 | 109 | 10 | 29.5 | 105 | 10 | 27.4 | 98 | 10
9 | 28.7 | 10 | 32.0 | 112 | 10 | 30.8 | 107 | 10 | 28.7 | 100 | 10
10 | 29.4 | 10 | 33.1 | 113 | 10 | 31.8 | 108 | 10 | 29.5 | 100 | 10
11 | 30.8 | 10 | 33.5 | 109 | 10 | 32.5 | 106 | 10 | 30.5 | 99 | 10
12 | 31.2 | 10 | 34.0 | 109 | 10 | 33.0 | 106 | 10 | 31.3 | 100 | 10
13 | 31.4 | 10 | 33.9 | 108 | 10 | 33.1 | 105 | 10 | 30.4 | 97 | 10
14 | 31.7 | 10 | 34.7 | 110 | 10 | 33.1 | 104 | 10 | 30.7 | 97 | 10
15 | 31.6 | 10 | 34.6 | 110 | 10 | 33.6 | 106 | 10 | 31.0 | 98 | 10
16 | 32.4 | 10 | 35.2 | 109 | 10 | 34.3 | 106 | 10 | 31.9 | 99 | 10
17 | 32.2 | 10 | 35.5 | 110 | 10 | 34.5 | 107 | 10 | 32.5 | 101 | 10
18 | 32.5 | 10 | 36.0 | 111 | 10 | 35.2 | 108 | 10 | 32.3 | 99 | 10
19 | 33.4 | 10 | 36.3 | 109 | 10 | 35.6 | 107 | 10 | 33.2 | 99 | 10
20 | 34.2 | 10 | 39.1 | 114 | 9 | 37.0 | 108 | 10 | 34.3 | 100 | 10
21 | 35.1 | 10 | 39.2 | 112 | 9 | 36.8 | 105 | 10 | 33.0 | 94 | 10
22 | 35.3 | 10 | 40.2 | 114 | 9 | 37.5 | 106 | 10 | 35.1 | 99 | 10
23 | 36.3 | 8 | 40.5 | 112 | 9 | 37.2 | 103 | 10 | 35.2 | 97 | 10
24 | 36.6 | 8 | 41.6 | 114 | 9 | 37.9 | 104 | 10 | 36.0 | 98 | 10
25 | 36.7 | 8 | 42.0 | 114 | 9 | 37.0 | 101 | 10 | 36.2 | 99 | 10
26 | 36.9 | 8 | 42.2 | 114 | 9 | 38.6 | 105 | 10 | 36.7 | 100 | 10
27 | 36.9 | 8 | 42.2 | 114 | 9 | 39.4 | 107 | 9 | 35.4 | 96 | 10
28 | 37.6 | 8 | 42.4 | 113 | 9 | 40.2 | 107 | 9 | 35.0 | 93 | 10
29 | 37.5 | 8 | 42.9 | 114 | 9 | 39.8 | 106 | 9 | 35.1 | 94 | 10
30 | 37.5 | 8 | 42.6 | 114 | 9 | 40.2 | 107 | 9 | 36.3 | 97 | 10
31 | 37.6 | 8 | 42.8 | 114 | 9 | 40.6 | 108 | 9 | 36.6 | 97 | 10
32 | 37.0 | 8 | 43.1 | 117 | 9 | 40.4 | 109 | 9 | 37.1 | 100 | 10
33 | 38.9 | 8 | 42.8 | 110 | 9 | 40.0 | 103 | 9 | 37.5 | 96 | 10
34 | 37.6 | 8 | 42.2 | 112 | 9 | 40.5 | 108 | 9 | 37.1 | 99 | 10
35 | 37.2 | 8 | 40.7 | 109 | 9 | 40.3 | 108 | 9 | 36.8 | 99 | 10
36 | 35.8 | 8 | 40.5 | 113 | 9 | 39.5 | 110 | 8 | 37.3 | 104 | 10
37 | 37.2 | 7 | 41.3 | 111 | 9 | 38.8 | 104 | 8 | 37.5 | 101 | 10
38 | 38.2 | 7 | 41.6 | 109 | 9 | 39.1 | 102 | 8 | 37.9 | 99 | 10
39 | 38.9 | 7 | 41.8 | 108 | 9 | 39.3 | 101 | 8 | 38.3 | 99 | 10
40 | 39.9 | 7 | 42.0 | 105 | 9 | 39.1 | 98 | 8 | 38.1 | 96 | 10
41 | 41.7 | 6 | 40.8 | 98 | 9 | 38.5 | 92 | 8 | 37.8 | 91 | 9
42 | 42.4 | 6 | 41.8 | 99 | 9 | 39.1 | 92 | 8 | 38.3 | 90 | 9
Mean for weeks
1–13 | 27.7 | | 29.6 | 107 | | 28.7 | 104 | | 27.0 | 98
14–42 | 36.4 | | 40.3 | 111 | | 38.0 | 105 | | 35.5 | 98

TABLE 14 Mean Body Weights and Survival of Female Tg.AC Hemizygous Mice in the 42-Week Drinking Water Study of Bromodichloromethane

Weeks on Study | 0 mg/L | | 175 mg/L | | | 350 mg/L | | | 700 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 19.2 | 10 | 19.1 | 100 | 10 | 18.9 | 98 | 10 | 19.3 | 101 | 10
2 | 20.0 | 10 | 20.6 | 103 | 10 | 20.0 | 100 | 10 | 18.8 | 94 | 10
3 | 21.2 | 10 | 22.2 | 105 | 10 | 21.6 | 102 | 10 | 20.8 | 98 | 10
4 | 22.0 | 10 | 22.9 | 104 | 10 | 22.4 | 102 | 10 | 21.9 | 100 | 10
5 | 23.3 | 10 | 23.7 | 102 | 10 | 23.1 | 99 | 10 | 23.2 | 100 | 10
6 | 23.8 | 10 | 24.0 | 101 | 10 | 23.8 | 100 | 10 | 23.1 | 97 | 10
7 | 24.2 | 10 | 23.8 | 98 | 10 | 23.4 | 97 | 10 | 23.3 | 96 | 10
S | 24.8 | 10 | 25.1 | 101 | 10 | 24.1 | 97 | 10 | 24.5 | 99 | 10
9 | 25.2 | 10 | 25.9 | 103 | 10 | 24.7 | 98 | 10 | 24.8 | 98 | 10
10 | 26.4 | 10 | 26.1 | 99 | 10 | 25.4 | 96 | 10 | 24.8 | 94 | 10
11 | 26.9 | 10 | 27.0 | 100 | 10 | 26.5 | 99 | 10 | 25.8 | 96 | 10
12 | 26.7 | 10 | 26.2 | 98 | 10 | 26.2 | 98 | 10 | 26.5 | 99 | 10
13 | 27.3 | 10 | 26.7 | 98 | 10 | 26.2 | 96 | 10 | 26.8 | 98 | 10
14 | 27.8 | 10 | 27.1 | 98 | 10 | 27.1 | 98 | 10 | 26.7 | 96 | 10
15 | 28.1 | 10 | 27.3 | 97 | 10 | 27.9 | 99 | 9 | 27.4 | 98 | 10
16 | 28.9 | 10 | 27.6 | 96 | 10 | 28.4 | 98 | 9 | 27.6 | 96 | 10
17 | 28.5 | 10 | 27.9 | 98 | 10 | 29.2 | 103 | 9 | 27.4 | 96 | 10
18 | 28.2 | 10 | 28.6 | 101 | 10 | 29.4 | 104 | 9 | 27.8 | 99 | 10
19 | 29.3 | 9 | 29.0 | 99 | 10 | 30.4 | 104 | 9 | 29.2 | 100 | 10
20 | 29.9 | 9 | 29.8 | 100 | 10 | 31.4 | 105 | 9 | 29.6 | 99 | 10
21 | 30.3 | 8 | 29.5 | 97 | 10 | 30.6 | 101 | 9 | 30.5 | 101 | 9
22 | 30.2 | 8 | 30.3 | 100 | 10 | 32.0 | 106 | 9 | 31.7 | 105 | 9
23 | 31.3 | 8 | 30.2 | 97 | 10 | 33.1 | 106 | 9 | 32.6 | 104 | 8
24 | 30.4 | 8 | 30.9 | 102 | 10 | 33.9 | 112 | 9 | 33.4 | 110 | 8
25 | 31.5 | 8 | 32.7 | 104 | 9 | 35.0 | 111 | 9 | 33.7 | 107 | 8
26 | 31.8 | 8 | 33.6 | 106 | 9 | 35.8 | 113 | 9 | 33.9 | 107 | 8
27 | 31.5 | 8 | 33.9 | 108 | 9 | 37.2 | 118 | 9 | 35.0 | 111 | 7
28 | 31.3 | 8 | 34.0 | 109 | 9 | 37.5 | 120 | 9 | 34.8 | 111 | 7
29 | 32.7 | 8 | 34.2 | 105 | 9 | 37.9 | 116 | 9 | 35.1 | 107 | 7
30 | 32.9 | 8 | 34.6 | 105 | 9 | 38.1 | 116 | 9 | 33.2 | 101 | 7
31 | 32.6 | 8 | 34.0 | 104 | 9 | 38.3 | 118 | 9 | 33.1 | 102 | 7
32 | 32.9 | 8 | 32.2 | 98 | 9 | 36.6 | 111 | 9 | 32.9 | 100 | 7
33 | 32.9 | 8 | 32.0 | 97 | 9 | 37.7 | 115 | 9 | 32.9 | 100 | 7
34 | 33.2 | 7 | 33.3 | 100 | 9 | 36.6 | 110 | 9 | 33.3 | 100 | 7
35 | 33.5 | 7 | 33.7 | 101 | 8 | 38.3 | 114 | 8 | 32.3 | 96 | 7
36 | 32.7 | 7 | 34.0 | 104 | 8 | 39.2 | 120 | 8 | 33.0 | 101 | 7
37 | 33.3 | 7 | 32.8 | 99 | 8 | 41.0 | 123 | 7 | 33.2 | 100 | 7
38 | 34.8 | 6 | 33.5 | 96 | 8 | 42.3 | 122 | 5 | 32.8 | 94 | 7
39 | 35.3 | 6 | 34.2 | 97 | 8 | 42.7 | 121 | 5 | 33.2 | 94 | 7
40 | 35.7 | 6 | 34.8 | 98 | 8 | 41.9 | 117 | 4 | 36.5 | 102 | 5
41 | 36.6 | 6 | 34.9 | 95 | 8 | 41.2 | 113 | 4 | 35.8 | 98 | 5
42 | 35.7 | 5 | 35.8 | 100 | 8 | 42.8 | 120 | 4 | 34.9 | 98 | 5
Mean for weeks
1–13 | 23.9 | | 24.1 | 101 | | 23.6 | 99 | | 23.4 | 98
14–42 | 31.9 | | 31.9 | 100 | | 35.6 | 112 | | 32.2 | 101

## 26-Week Gavage Study in Tg.AC Hemizygous Mice

### Dose Selection Rationale

The doses administered in this 26-week gavage study (25, 50, and 100 mg/kg) were based on findings from previous 2- and 13-week gavage studies of bromodichloromethane performed in B6C3F_1_ mice and F344/N rats (NTP, 1987).

### Positive Control Tg.AC Hemizygous Mice

TPA (1.25 µg) was dermally administered to groups of 15 males and 15 females three times weekly. Ninety-three percent of dosed males and females developed 20 skin papillomas. Two males developed fewer than 20 skin papillomas and survived to the end of the study; all other mice were terminated by week 18 (data not shown). This is consistent with historical rates found in other studies (Tennant et al., 2001).

### Survival

Estimates of 26-week survival probabilities for male and female Tg.AC hemizygous mice are shown in Table 15. The survival of dosed males and females was similar to that of the vehicle control groups.

TABLE 15 Survival of Tg.AC Hemizygous Mice in the 26-Week Gavage Study of Bromodichloromethane

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Male
Animals initially in study | 15 | 15 | 15 | 15
Accidental death^a^ | 1 | 0 | 0 | 0
Moribund | 1 | 1 | 3 | 0
Natural death | 0 | 0 | 0 | 0.
Animals surviving to study termination | 13 | 14 | 12 | 15^b^
Percent probability of survival at end of study^c^ | 93 | 93 | 80 | 100
Mean survival (days)^d^ | 167 | 179 | 170 | 182
Survival analysis^e^ | P=0.761N | P=1.000N | P=0.678 | P=0.972N
Female
Animals initially in study | 15 | 15 | 15 | 15
Accidental deaths^a^ | 1 | 0 | 0 | 1
Moribund | 1 | 0 | 0 | 1
Natural deaths | 2 | 1 | 2 | 0
Animals surviving to study termination | 11 | 14 | 13 | 13
Percent probability of survival at end of study | 79 | 93 | 87 | 93
Mean survival (days) | 170 | 180 | 174 | 170
Survival analysis | P=0.587N | P=0.565N | P=0.987N | P=0.616N

a Censored from survival analyses

b Includes one animal that died last week of study

c Kaplan-Meier determinations

d Mean of all deaths (uncensored, censored, and terminal sacrifice)

e The result of the life table trend test (Tarone, 1975) is in the vehicle control column, and the results of the life table pairwise comparisons (Cox, 1972) with the vehicle controls are in the dosed group columns. A negative trend or lower mortality in a dose group is indicated by N.

### Body Weights, Clinical Findings, and Organ Weights

Mean body weights of dosed males were similar to those of the vehicle controls (Tables 16 and 17 and Figure 5). In general, mean body weights of 25, 50, and 100 mg/kg females were greater than those of the vehicle controls after weeks 17, 23, and 17, respectively. No clinical findings were attributed to administration of bromodichloromethane. The relative liver weight of 100 mg/kg males was significantly greater than that of the vehicle control group (Table H5).

### Hematology

The hematology data for Tg.AC hemizygous mice in the 26-week gavage study of bromodichloromethane are listed in Table G3. A decrease (approximately 40%) in white blood cell counts occurred in the 25 and 50 mg/kg male mice; this decrease was reflected in decreased lymphocyte counts. No leukocyte decreases occurred in the 100 mg/kg males or in any of the treated female groups, so the clinical and toxicological relevance of this finding was questionable. There were minimal (approximately 4%) increases in mean cell hemoglobin and mean cell volume values in 100 mg/kg male mice; again, toxicological significance of these changes was questionable. There were increased platelet counts in treated female mice. This change appears, however, to reflect a slightly lower than expected platelet count for the vehicle control female mice and would not appear to be clinically or toxicologically relevant. No changes occurred in other variables.

TABLE 16 Mean Body Weights and Survival of Male Tg.AC Hemizygous Mice in the 26-Week Gavage Study of Bromodichloromethane

Weeks on Study | Vehicle Control | | 25 mg/kg | | | 50 mg/kg | | | 100 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 24.3 | 15 | 24.1 | 99 | 15 | 23.9 | 98 | 15 | 24.0 | 99 | 15
2 | 24.7 | 15 | 25.2 | 102 | 15 | 25.1 | 102 | 15 | 25.0 | 101 | 15
3 | 26.0 | 15 | 26.2 | 101 | 15 | 26.2 | 101 | 15 | 26.2 | 101 | 15
4 | 27.0 | 15 | 27.2 | 101 | 15 | 27.5 | 102 | 15 | 27.4 | 102 | 15
5 | 27.5 | 15 | 28.0 | 102 | 15 | 27.8 | 101 | 15 | 27.9 | 102 | 15
6 | 28.1 | 15 | 28.5 | 101 | 15 | 28.8 | 103 | 15 | 28.5 | 101 | 15
7 | 28.8 | 14 | 28.5 | 99 | 15 | 28.8 | 100 | 15 | 29.3 | 102 | 15
8 | 29.0 | 14 | 29.4 | 101 | 15 | 29.1 | 100 | 15 | 29.1 | 100 | 15
9 | 30.1 | 14 | 30.0 | 100 | 15 | 29.9 | 99 | 15 | 30.3 | 101 | 15
10 | 30.3 | 14 | 30.2 | 100 | 15 | 29.7 | 98 | 15 | 30.3 | 100 | 15
11 | 30.3 | 14 | 30.8 | 102 | 15 | 29.8 | 98 | 15 | 30.8 | 102 | 15
12 | 31.2 | 14 | 31.4 | 101 | 15 | 30.9 | 99 | 15 | 30.8 | 99 | 15
13 | 31.6 | 14 | 31.9 | 101 | 15 | 31.6 | 100 | 15 | 31.1 | 98 | 15
14 | 31.5 | 14 | 31.2 | 99 | 15 | 30.9 | 98 | 15 | 31.5 | 100 | 15
15 | 32.2 | 13 | 32.2 | 100 | 15 | 31.2 | 97 | 15 | 31.5 | 98 | 15
16 | 32.4 | 13 | 32.6 | 101 | 15 | 31.1 | 96 | 15 | 32.1 | 99 | 15
17 | 32.3 | 13 | 33.2 | 103 | 15 | 30.8 | 95 | 15 | 32.5 | 101 | 15
18 | 33.2 | 13 | 33.4 | 101 | 15 | 32.7 | 99 | 13 | 32.3 | 97 | 15
19 | 33.9 | 13 | 33.9 | 100 | 15 | 33.2 | 98 | 13 | 33.2 | 98 | 15
20 | 34.4 | 13 | 34.0 | 99 | 15 | 33.0 | 96 | 13 | 33.2 | 97 | 15
21 | 33.9 | 13 | 33.6 | 99 | 15 | 32.6 | 96 | 13 | 33.1 | 98 | 15
22 | 34.7 | 13 | 34.5 | 99 | 14 | 34.1 | 98 | 12 | 33.6 | 97 | 15
23 | 34.5 | 13 | 34.8 | 101 | 14 | 34.1 | 99 | 12 | 32.8 | 95 | 15
24 | 35.3 | 13 | 35.4 | 100 | 14 | 35.2 | 100 | 12 | 33.1 | 94 | 15
25 | 34.5 | 13 | 35.3 | 102 | 14 | 33.9 | 98 | 12 | 32.9 | 95 | 15
26 | 35.2 | 13 | 35.8 | 102 | 14 | 33.8 | 96 | 12 | 33.5 | 95 | 15
Mean for weeks
1–13 | 28.4 | | 28.6 | 101 | | 28.4 | 100 | | 28.5 | 101
14–26 | 33.7 | | 33.8 | 100 | | 32.8 | 97 | | 32.7 | 97

TABLE 17 Mean Body Weights and Survival of Female Tg.AC Hemizygous Mice in the 26-Week Gavage Study of Bromodichloromethane

Weeks on Study | Vehicle Control | | 25 mg/kg | | | 50 mg/kg | | | 100 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 20.5 | 15 | 20.6 | 101 | 15 | 20.3 | 99 | 15 | 20.1 | 98 | 15
2 | 20.5 | 15 | 20.9 | 102 | 15 | 20.9 | 102 | 15 | 20.7 | 101 | 15
3 | 21.6 | 15 | 21.4 | 99 | 15 | 21.7 | 101 | 15 | 21.7 | 101 | 15
4 | 22.8 | 15 | 23.0 | 101 | 15 | 22.7 | 100 | 15 | 22.8 | 100 | 15
5 | 23.0 | 15 | 23.4 | 102 | 15 | 23.5 | 102 | 15 | 23.7 | 103 | 15
6 | 23.1 | 15 | 23.6 | 102 | 15 | 23.8 | 103 | 15 | 24.2 | 105 | 15
7 | 23.7 | 14 | 23.9 | 101 | 15 | 24.0 | 101 | 15 | 24.2 | 102 | 14
8 | 23.7 | 14 | 24.4 | 103 | 15 | 24.4 | 103 | 15 | 25.0 | 106 | 14
9 | 24.4 | 14 | 24.4 | 100 | 15 | 24.6 | 101 | 15 | 24.8 | 102 | 14
10 | 24.7 | 14 | 25.3 | 102 | 15 | 25.3 | 102 | 15 | 26.1 | 106 | 14
11 | 24.8 | 14 | 25.5 | 103 | 15 | 25.6 | 103 | 15 | 26.6 | 107 | 14
12 | 25.1 | 14 | 25.3 | 101 | 15 | 25.7 | 102 | 15 | 26.2 | 104 | 14
13 | 25.1 | 14 | 26.6 | 106 | 15 | 25.9 | 103 | 15 | 26.5 | 106 | 14
14 | 25.6 | 14 | 26.6 | 104 | 15 | 26.1 | 102 | 15 | 26.7 | 104 | 14
15 | 25.8 | 14 | 26.5 | 103 | 15 | 26.2 | 102 | 15 | 27.0 | 105 | 14
16 | 25.7 | 14 | 26.9 | 105 | 15 | 26.3 | 102 | 14 | 26.7 | 104 | 14
17 | 25.7 | 14 | 27.0 | 105 | 15 | 27.4 | 107 | 14 | 27.0 | 105 | 14
18 | 26.0 | 14 | 27.8 | 107 | 15 | 28.0 | 108 | 14 | 28.0 | 108 | 14
19 | 26.5 | 14 | 28.0 | 106 | 15 | 28.2 | 106 | 13 | 28.1 | 106 | 14
20 | 26.7 | 14 | 28.6 | 107 | 15 | 27.5 | 103 | 13 | 28.6 | 107 | 13
21 | 26.7 | 14 | 28.6 | 107 | 15 | 27.9 | 105 | 13 | 28.4 | 106 | 13
22 | 26.8 | 14 | 28.6 | 107 | 14 | 27.5 | 103 | 13 | 29.0 | 108 | 13
23 | 27.4 | 14 | 29.5 | 108 | 14 | 28.2 | 103 | 13 | 28.6 | 104 | 13
24 | 27.4 | 12 | 30.6 | 112 | 14 | 29.5 | 108 | 13 | 29.6 | 108 | 13
25 | 27.1 | 11 | 29.6 | 109 | 14 | 29.0 | 107 | 13 | 28.6 | 106 | 13
26 | 27.2 | 11 | 30.2 | 111 | 14 | 28.7 | 106 | 13 | 28.6 | 105 | 13
Mean for weeks
1–13 | 23.3 | | 23.7 | 102 | | 23.7 | 102 | | 24.0 | 103
14–26 | 26.5 | | 28.3 | 107 | | 27.7 | 105 | | 28.1 | 106

FIGURE 5 Growth Curves for Male and Female Tg.AC Hemizygous Mice Administered Bromodichloromethane by Gavage for 26 Weeks

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms of the forestomach and nonneoplastic lesions of the liver and kidney. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables C1, C2, C3, and C4.

Forestomach: The incidence of multiple squamous cell papilloma in 100 mg/kg females was significantly greater than that in the vehicle controls (Tables 18 and C3). However, when single and multiple squamous cell papillomas were combined, there were no significant differences between the dosed and vehicle control groups. Squamous cell papillomas occurred in the mucosa of the forestomach. Typically, papillomas were exophytic lesions projecting from the mucosa of the forestomach and consisting of frond-like proliferations of squamous epithelium that radiated from a central stalk of stromal tissue that was continuous with the lamina propria.

Liver: The incidences of hepatocyte fatty change in all dosed groups of females and hepatocyte cytoplasmic vacuolization in 25 and 50 mg/kg females were significantly greater than those in the vehicle controls (Tables 18 and C4). These lesions were morphologically similar to those previously described in the 26-week drinking water study.

Kidney: The incidences of renal tubule degeneration in 100 mg/kg males and renal tubule hypertrophy in 100 mg/kg females were significantly greater than those in the vehicle controls (Tables 18, C2, and C4). The incidences of nephropathy, renal tubule dilatation, and renal tubule hypertrophy were not increased in males as they were in the drinking water study (Tables B2 and C2). These lesions were morphologically similar to those previously described in the 26-week drinking water study.

TABLE 18 Incidences of Selected Neoplasms and Nonneoplastic Lesions in Tg.AC Hemizygous Mice in the 26-Week Gavage Study of Bromodichloromethane

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Male
Kidney^a^ | 15 | 15 | 15 | 15
Renal Tubule, Degeneration^b^ | 0 | 0 | 0 | 4^*^ (1.0)^c^
Female
Forestomach | 15 | 15 | 15 | 15
Squamous Cell Papilloma, Multiple | 3 | 5 | 6 | 11^**^
Squamous Cell Papilloma (includes multiple) | 6 | 8 | 10 | 11
Kidney | 15 | 15 | 15 | 15
Renal Tubule, Hypertrophy | 1 (1.0) | 1 (1.0) | 1 (1.0) | 8^**^ (1.0)
Liver | 15 | 15 | 15 | 15
Hepatocyte, Fatty Change | 0 | 5^*^ (1.0) | 8^**^ (1.0) | 7^**^ (1.1)
Hepatocyte, Vacuolization Cytoplasmic | 0 | 6^**^ (1.0) | 4^*^ (1.3) | 3 (1.0)

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

** (P≤0.01)

a Number of mice with tissue examined microscopically

b Number of mice with lesion

c Average severity of lesions in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked

## 41-Week Gavage Study in Tg.AC Hemizygous Mice

### Survival

Estimates of 41-week survival probabilities for male and female Tg.AC hemizygous mice are shown in Table 19. The survival of dosed males and females was similar to that of the vehicle control groups.

### Body Weights, Clinical Findings, and Organ Weights

Although mean body weights of dosed groups tended to be greater than those of the vehicle controls toward the end of the study, only 25 mg/kg males and 100 mg/kg females ended the study with mean body weights that were greater (Tables 20 and 21 and Figure 6). No clinical findings were attributed to administration of bromodichloromethane. Absolute and relative organ weights of dosed males and females were similar to those of the vehicle controls (Table H6).

TABLE 19 Survival of Tg.AC Hemizygous Mice in the 41-Week Gavage Study of Bromodichloromethane

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Male
Animals initially in study | 10 | 10 | 10 | 10
Accidental deaths^a^ | 1 | 3 | 0 | 0
Moribund | 3 | 1 | 4 | 2
Animals surviving to study termination | 6 | 6 | 6 | 8
Percent probability of survival at end of study^b^ | 69 | 86 | 60 | 80
Mean survival (days)^c^ | 240 | 195 | 248 | 257
Survival analysis^d^ | P=0.964N | P=0.780N | P=1.000 | P=0.974N
Female
Animals initially in study | 10 | 10 | 10 | 10
Moribund | 1 | 0 | 0 | 2
Natural deaths | 2 | 1 | 1 | 1
Animals surviving to study termination | 7 | 9 | 9 | 7
Percent probability of survival at end of study | 70 | 90 | 90 | 70
Mean survival (days) | 248 | 287 | 272 | 263
Survival analysis | P=1.000 | P=0.500N | P=0.578N | P=1.000N

a Censored from survival analyses

b Kaplan-Meier determinations

c Mean of all deaths (uncensored, censored, and terminal sacrifice)

d The result of the life table trend test (Tarone, 1975) is in the vehicle control column, and the results of the life table pairwise comparisons (Cox, 1972) with the vehicle controls are in the dosed group columns. A negative trend or lower mortality in a dose group is indicated by N.

TABLE 20 Mean Body Weights and Survival of Male Tg.AC Hemizygous Mice in the 41-Week Gavage Study of Bromodichloromethane

Weeks on Study | Vehicle Control | | 25 mg/kg | | | 50 mg/kg | | | 100 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 24.5 | 10 | 24.3 | 99 | 10 | 24.3 | 99 | 10 | 23.9 | 98 | 10
2 | 25.2 | 10 | 25.9 | 103 | 10 | 25.5 | 101 | 10 | 25.5 | 101 | 10
3 | 26.0 | 10 | 26.6 | 102 | 8 | 26.1 | 100 | 10 | 25.7 | 99 | 10
4 | 27.6 | 10 | 27.6 | 100 | 8 | 27.2 | 99 | 10 | 27.4 | 99 | 10
5 | 27.8 | 10 | 28.5 | 103 | 8 | 27.8 | 100 | 10 | 27.6 | 99 | 10
6 | 28.4 | 10 | 28.9 | 102 | 8 | 28.7 | 101 | 10 | 28.3 | 100 | 10
7 | 28.9 | 10 | 29.0 | 100 | 8 | 28.4 | 98 | 10 | 29.2 | 101 | 10
8 | 29.1 | 10 | 29.6 | 102 | 8 | 29.2 | 100 | 10 | 29.0 | 100 | 10
9 | 30.0 | 10 | 29.8 | 99 | 7 | 28.4 | 95 | 10 | 29.5 | 98 | 10
10 | 30.0 | 10 | 29.9 | 100 | 7 | 27.9 | 93 | 10 | 29.7 | 99 | 10
11 | 30.8 | 10 | 30.0 | 97 | 7 | 29.9 | 97 | 10 | 30.4 | 99 | 10
12 | 31.5 | 10 | 31.5 | 100 | 7 | 30.5 | 97 | 10 | 30.5 | 97 | 10
13 | 31.9 | 10 | 31.6 | 99 | 7 | 31.2 | 98 | 10 | 30.1 | 94 | 10
14 | 31.7 | 10 | 30.7 | 97 | 7 | 30.7 | 97 | 10 | 30.0 | 95 | 10
15 | 32.0 | 10 | 31.7 | 99 | 7 | 31.2 | 98 | 10 | 31.6 | 99 | 9
16 | 32.8 | 10 | 32.0 | 98 | 7 | 31.9 | 97 | 10 | 31.5 | 96 | 9
17 | 33.8 | 10 | 32.4 | 96 | 7 | 32.9 | 97 | 10 | 32.0 | 95 | 9
18 | 34.9 | 10 | 32.9 | 94 | 7 | 33.5 | 96 | 10 | 32.3 | 93 | 9
19 | 35.6 | 10 | 32.9 | 92 | 7 | 33.1 | 93 | 10 | 32.8 | 92 | 9
20 | 33.0 | 8 | 32.9 | 100 | 7 | 32.9 | 100 | 8 | 32.3 | 98 | 9
21 | 33.5 | 8 | 33.5 | 100 | 7 | 32.9 | 98 | 8 | 33.0 | 99 | 9
22 | 32.7 | 8 | 34.4 | 105 | 6 | 32.7 | 100 | 8 | 33.2 | 102 | 9
23 | 34.1 | 8 | 35.1 | 103 | 6 | 32.9 | 97 | 8 | 32.9 | 97 | 9
24 | 34.8 | 8 | 35.4 | 102 | 6 | 32.2 | 93 | 8 | 33.6 | 97 | 9
25 | 33.7 | 8 | 35.6 | 106 | 6 | 33.3 | 99 | 8 | 34.1 | 101 | 9
26 | 34.2 | 8 | 37.0 | 108 | 6 | 33.9 | 99 | 8 | 34.2 | 100 | 8
27 | 35.0 | 8 | 36.2 | 103 | 6 | 33.5 | 96 | 8 | 31.7 | 91 | 8
28 | 33.6 | 7 | 36.6 | 109 | 6 | 34.1 | 102 | 8 | 32.8 | 98 | 8
29 | 33.2 | 7 | 37.4 | 113 | 6 | 34.3 | 103 | 8 | 34.4 | 104 | 8
30 | 33.4 | 7 | 36.4 | 109 | 6 | 34.3 | 103 | 8 | 34.5 | 103 | 8
31 | 33.9 | 7 | 37.4 | 110 | 6 | 34.2 | 101 | 8 | 35.2 | 104 | 8
32 | 33.8 | 7 | 37.5 | 111 | 6 | 34.4 | 102 | 8 | 34.6 | 102 | 8
33 | 33.2 | 7 | 38.0 | 115 | 6 | 34.5 | 104 | 8 | 34.4 | 104 | 8
34 | 34.1 | 6 | 35.7 | 105 | 6 | 35.8 | 105 | 7 | 34.7 | 102 | 8
35 | 33.6 | 6 | 37.8 | 113 | 6 | 35.4 | 105 | 7 | 34.2 | 102 | 8
36 | 31.9 | 6 | 38.4 | 120 | 6 | 35.3 | 111 | 7 | 34.3 | 108 | 8
37 | 32.6 | 6 | 38.5 | 118 | 6 | 35.6 | 109 | 7 | 33.9 | 104 | 8
38 | 32.8 | 6 | 38.9 | 119 | 6 | 36.4 | 111 | 7 | 34.6 | 106 | 8
39 | 33.8 | 6 | 39.2 | 116 | 6 | 36.6 | 108 | 7 | 34.5 | 102 | 8
40 | 33.2 | 6 | 37.6 | 113 | 6 | 35.5 | 107 | 7 | 33.7 | 102 | 8
41 | 34.4 | 6 | 39.6 | 115 | 6 | 34.2 | 99 | 6 | 34.2 | 99 | 8
Mean for weeks
1–13 | 28.6 | | 28.7 | 100 | | 28.1 | 98 | | 28.2 | 99
14–41 | 33.5 | | 35.8 | 107 | | 33.9 | 101 | | 33.4 | 100

TABLE 21 Mean Body Weights and Survival of Female Tg.AC Hemizygous Mice in the 41-Week Gavage Study of Bromodichloromethane

Weeks on Study | Vehicle Control | | 25 mg/kg | | | 50 mg/kg | | | 100 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 20.6 | 10 | 20.9 | 102 | 10 | 20.7 | 101 | 10 | 20.4 | 99 | 10
2 | 20.8 | 10 | 21.2 | 102 | 10 | 20.8 | 100 | 10 | 20.8 | 100 | 10
3 | 21.7 | 10 | 21.4 | 99 | 10 | 21.7 | 100 | 10 | 21.4 | 99 | 10
4 | 22.8 | 10 | 22.9 | 100 | 10 | 22.4 | 98 | 10 | 22.8 | 100 | 10
5 | 23.3 | 10 | 23.3 | 100 | 10 | 23.0 | 99 | 10 | 23.0 | 99 | 10
6 | 23.6 | 10 | 23.7 | 100 | 10 | 23.5 | 100 | 10 | 24.1 | 102 | 10
7 | 24.3 | 10 | 24.2 | 100 | 10 | 24.0 | 99 | 10 | 24.2 | 100 | 10
8 | 24.4 | 10 | 25.1 | 103 | 10 | 24.9 | 102 | 10 | 24.7 | 101 | 10
9 | 24.4 | 10 | 24.1 | 99 | 10 | 24.4 | 100 | 10 | 24.5 | 100 | 10
10 | 24.8 | 10 | 24.4 | 98 | 10 | 25.4 | 102 | 10 | 25.8 | 104 | 10
11 | 25.3 | 10 | 26.1 | 103 | 10 | 25.7 | 102 | 10 | 25.9 | 102 | 10
12 | 25.4 | 10 | 26.1 | 103 | 10 | 26.6 | 105 | 10 | 25.8 | 102 | 10
13 | 25.8 | 10 | 26.0 | 101 | 10 | 26.3 | 102 | 10 | 26.0 | 101 | 10
14 | 26.1 | 10 | 26.2 | 100 | 10 | 25.7 | 99 | 10 | 26.4 | 101 | 10
15 | 26.9 | 10 | 27.4 | 102 | 10 | 27.0 | 100 | 10 | 26.5 | 99 | 10
16 | 26.6 | 9 | 26.9 | 101 | 10 | 26.7 | 100 | 10 | 26.7 | 100 | 10
17 | 27.3 | 9 | 27.9 | 102 | 10 | 27.4 | 100 | 10 | 27.1 | 99 | 10
18 | 27.6 | 9 | 27.7 | 100 | 10 | 28.1 | 102 | 10 | 27.6 | 100 | 10
19 | 28.1 | 8 | 28.0 | 100 | 10 | 27.7 | 99 | 9 | 27.7 | 99 | 10
20 | 28.5 | 8 | 27.8 | 98 | 10 | 27.5 | 97 | 9 | 28.0 | 98 | 10
21 | 29.3 | 8 | 28.4 | 97 | 10 | 28.1 | 96 | 9 | 28.9 | 99 | 10
22 | 29.3 | 8 | 27.6 | 94 | 10 | 27.9 | 95 | 9 | 28.7 | 98 | 10
23 | 29.0 | 8 | 27.6 | 95 | 10 | 28.7 | 99 | 9 | 28.5 | 98 | 10
24 | 30.3 | 8 | 28.0 | 92 | 10 | 29.2 | 96 | 9 | 29.6 | 98 | 10
25 | 30.0 | 8 | 29.2 | 97 | 10 | 29.1 | 97 | 9 | 29.6 | 99 | 9
26 | 30.3 | 8 | 29.3 | 97 | 10 | 28.6 | 94 | 9 | 29.8 | 98 | 9
27 | 30.0 | 8 | 29.0 | 97 | 10 | 28.7 | 96 | 9 | 29.5 | 98 | 9
28 | 30.7 | 8 | 29.7 | 97 | 10 | 29.1 | 95 | 9 | 31.2 | 102 | 8
29 | 30.9 | 8 | 30.1 | 97 | 10 | 28.9 | 94 | 9 | 30.9 | 100 | 8
30 | 31.5 | 8 | 30.5 | 97 | 10 | 29.0 | 92 | 9 | 31.6 | 100 | 8
31 | 31.8 | 8 | 30.5 | 96 | 10 | 29.1 | 92 | 9 | 31.9 | 100 | 8
32 | 31.1 | 8 | 30.4 | 98 | 10 | 29.4 | 95 | 9 | 32.5 | 105 | 8
33 | 32.5 | 8 | 31.3 | 96 | 10 | 29.8 | 92 | 9 | 32.0 | 99 | 8
34 | 33.3 | 8 | 31.6 | 95 | 10 | 30.2 | 91 | 9 | 32.2 | 97 | 8
35 | 29.3 | 7 | 32.2 | 110 | 10 | 29.6 | 101 | 9 | 32.5 | 111 | 8
36 | 28.9 | 7 | 32.3 | 112 | 10 | 29.9 | 104 | 9 | 32.5 | 113 | 8
37 | 29.1 | 7 | 32.5 | 112 | 10 | 29.8 | 102 | 9 | 32.5 | 112 | 8
38 | 29.8 | 7 | 32.3 | 108 | 10 | 30.1 | 101 | 9 | 32.9 | 110 | 8
39 | 30.2 | 7 | 31.7 | 105 | 10 | 30.4 | 101 | 9 | 34.1 | 113 | 7
40 | 28.5 | 7 | 30.3 | 106 | 9 | 29.2 | 103 | 9 | 34.0 | 119 | 7
41 | 29.8 | 7 | 30.4 | 102 | 9 | 29.9 | 100 | 9 | 33.5 | 112 | 7
Mean for weeks
1–13 | 23.6 | | 23.8 | 101 | | 23.8 | 101 | | 23.8 | 101
14–41 | 29.5 | | 29.5 | 100 | | 28.7 | 98 | | 30.3 | 103

FIGURE 6 Growth Curves for Male and Female Tg.AC Hemizygous Mice Administered Bromodichloromethane by Gavage for 41 Weeks

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms of the forestomach and nonneoplastic lesions of the liver and kidney. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables C5, C6, C7, and C8.

Forestomach: The incidences of multiple squamous cell papilloma in dosed females were increased, and the difference was significant at 25 and 100 mg/kg (Tables 22 and C7). The combined incidence of single and multiple squamous cell papilloma was also significantly increased in 100 mg/kg females (Table 22). These lesions were morphologically similar to those previously described in the 26-week gavage study.

Liver: The incidences of hepatocyte cytoplasmic vacuolization were increased in all dosed females compared to the vehicle controls, but the difference was significant only in the 50 mg/kg group (Tables 22 and C8). The incidences of hepatocellular fatty change in 50 and 100 mg/kg females were significantly increased compared to that of the vehicle control group. These lesions were morphologically similar to those previously described in the 26-week drinking water study.

Kidney: In 100 mg/kg males, the incidence of renal tubule degeneration was significantly greater than that in the vehicle control group (Tables 22 and C6). Renal tubule degeneration was morphologically similar to that previously described in the 26-week drinking water study.

TABLE 22 Incidences of Selected Neoplasms and Nonneoplastic Lesions in Tg.AC Hemizygous Mice in the 41-Week Gavage Study of Bromodichloromethane

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Male
Kidney^a^ | 10 | 10 | 10 | 10
Renal Tubule, Degeneration^b^ | 0 | 0 | 0 | 6^**^ (1.7)^c^
Forestomach | 10 | 10 | 10 | 10
Squamous Cell Papilloma, Multiple | 6 | 5 | 5 | 5
Squamous Cell Papilloma (includes multiple) | 8 | 6 | 9 | 6
Female
Forestomach | 10 | 10 | 10 | 10
Squamous Cell Papilloma, Multiple | 1 | 6^*^ | 5 | 9^**^
Squamous Cell Papilloma (includes multiple) | 4 | 7 | 8 | 10^**^
Liver | 10 | 10 | 10 | 10
Hepatocyte, Fatty Change | 0 | 2 (1.5) | 8^**^ (1.4) | 5^*^ (1.6)
Hepatocyte, Vacuolization Cytoplasmic | 6 (1.3) | 9 (1.3) | 10^*^ (1.1) | 9 (1.7)

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

** (P≤0.01)

a Number of mice with site examined microscopically

b Number of mice with lesion

c Average severity of lesions in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked

## 26-Week Drinking Water Study in p53 Haploinsufficient Mice

### Dose Selection Rationale

The doses administered in this 26-week drinking water study (175, 350, and 700 mg/L) were the same as those used in a previous 2-year drinking water study of bromodichloromethane in male F344/N rats and female B6C3F_1_ mice (NTP, 2006).

### Survival

Estimates of 26-week survival probabilities for male and female p53 haploinsufficient mice are shown in Table 23. The survival of exposed males and females was similar to that of the control groups.

### Body Weights, Water and Compound Consumption, Clinical Findings, and Organ Weights

Mean body weights of males exposed to 350 or 700 mg/L were less than those of the controls throughout most of the study (Table 24 and Figure 7). Mean body weights of 175, 350, and 700 mg/L females were less than control body weights after weeks 15, 23, and 18, respectively (Table 25 and Figure 7). Water consumption by exposed males and females declined with increasing exposure concentration at the beginning of the study (Tables J5 and J6). Water consumption by exposed females was similar to that by controls by the end of the study, but that by males remained low. Drinking water concentrations of 175, 350, and 700 mg/L delivered average daily doses of approximately 16, 31, or 65 mg/kg to males and 26, 50, or 100 mg/kg to females. There were no chemical-related clinical findings. The absolute heart weight in 700 mg/L males and absolute right kidney and liver weights in 350 and 700 mg/L males were significantly less than those of the control group (Table H7). The weights of these organs decreased with increasing dose, mirroring a similar pattern in overall body weight. The relative lung weight in 700 mg/L males, the relative right testis weight in 350 and 700 mg/L males, and the relative liver weight in 700 mg/L females were all greater than those of the control groups.

### Hematology

The hematology data for p53 haploinsufficient mice in the 26-week drinking water study of bromodichloromethane are listed in Table G4. Very minimal decreases in hematocrit (3%) and hemoglobin concentration (4%) values occurred in the 700 mg/kg male mice. The significance, if any, was not known, and females were not affected.

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions of the kidney and liver. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables D1, D2, D3, and D4.

Kidney: The incidences of renal tubule dilatation in all exposed groups of males (0 mg/L, 0/15; 175 mg/L 5/15; 350 mg/L, 4/15; 700 mg/L, 6/15), renal tubule degeneration in 350 and 700 mg/L males (0/15, 0/15, 9/15, 12/15), and protein casts in 700 mg/L males (1/15, 5/15, 4/15, 7/15) were significantly greater than those in controls (Table D2). These lesions were morphologically similar to those previously described in the 26-week drinking water study in Tg.AC hemizygous mice.

Liver: The incidence of fatty change in hepatocytes of 700 mg/L females was significantly greater than that in the control group (0/15, 1/15, 1/15, 10/15; Table D4). Hepatocyte fatty change was morphologically similar to that previously described in the 26-week drinking water study in Tg.AC hemizygous mice.

TABLE 23 Survival of p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Bromodichloromethane

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Male
Animals initially in study | 15 | 15 | 15 | 15
Animals surviving to study termination | 15 | 15 | 15 | 15
Percent probability of survival at end of study^a^ | 100 | 100 | 100 | 100
Mean survival (days)^b^ | 184 | 184 | 184 | 184
Survival analysis^c^ | —^d^ | — | — | —
Female
Animals initially in study | 15 | 15 | 15 | 15
Natural death | 0 | 0 | 1 | 0
Animals surviving to study termination | 15 | 15 | 14 | 15
Percent probability of survival at end of study | 100 | 100 | 93 | 100
Mean survival (days) | 185 | 185 | 175 | 185
Survival analysis | P= 1.000 | — | P=1.000 | —

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice)

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns.

d No deaths occurred in this group; value of statistic cannot be calculated.

TABLE 24 Mean Body Weights and Survival of Male p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Bromodichloromethane

Weeks on Study | 0 mg/L | | 175 mg/L | | | 350 mg/L | | | 700 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 22.8 | 15 | 23.0 | 101 | 15 | 22.9 | 100 | 15 | 22.5 | 99 | 15
2 | 24.2 | 15 | 23.7 | 98 | 15 | 21.8 | 90 | 15 | 20.1 | 83 | 15
3 | 25.6 | 15 | 25.0 | 98 | 15 | 24.2 | 95 | 15 | 22.0 | 86 | 15
4 | 26.7 | 15 | 26.2 | 98 | 15 | 25.2 | 94 | 15 | 24.1 | 90 | 15
5 | 27.9 | 15 | 26.9 | 96 | 15 | 26.4 | 95 | 15 | 24.8 | 89 | 15
6 | 28.3 | 15 | 28.1 | 99 | 15 | 26.9 | 95 | 15 | 24.8 | 88 | 15
7 | 30.2 | 15 | 28.5 | 94 | 15 | 27.4 | 91 | 15 | 25.2 | 83 | 15
8 | 31.1 | 15 | 30.3 | 97 | 15 | 28.3 | 91 | 15 | 26.0 | 84 | 15
9 | 33.0 | 15 | 32.1 | 97 | 15 | 29.7 | 90 | 15 | 27.2 | 82 | 15
10 | 34.7 | 15 | 33.5 | 97 | 15 | 30.7 | 89 | 15 | 27.9 | 80 | 15
11 | 36.1 | 15 | 35.2 | 98 | 15 | 32.1 | 89 | 15 | 27.9 | 77 | 15
12 | 37.0 | 15 | 36.3 | 98 | 15 | 33.1 | 90 | 15 | 29.0 | 78 | 15
13 | 38.4 | 15 | 37.3 | 97 | 15 | 33.3 | 87 | 15 | 29.6 | 77 | 15
14 | 38.9 | 15 | 38.3 | 99 | 15 | 34.2 | 88 | 15 | 30.1 | 77 | 15
15 | 39.8 | 15 | 38.9 | 98 | 15 | 35.2 | 88 | 15 | 30.8 | 77 | 15
16 | 40.8 | 15 | 39.2 | 96 | 15 | 36.1 | 89 | 15 | 31.2 | 77 | 15
17 | 42.0 | 15 | 40.6 | 97 | 15 | 37.1 | 88 | 15 | 32.1 | 76 | 15
18 | 42.9 | 15 | 40.8 | 95 | 15 | 37.5 | 87 | 15 | 33.0 | 77 | 15
19 | 43.4 | 15 | 42.0 | 97 | 15 | 37.6 | 87 | 15 | 33.3 | 77 | 15
20 | 43.8 | 15 | 43.0 | 98 | 15 | 38.8 | 89 | 15 | 33.9 | 77 | 15
21 | 45.1 | 15 | 43.7 | 97 | 15 | 39.4 | 87 | 15 | 34.7 | 77 | 15
22 | 45.9 | 15 | 44.2 | 96 | 15 | 39.6 | 86 | 15 | 34.8 | 76 | 15
23 | 46.4 | 15 | 45.0 | 97 | 15 | 41.0 | 88 | 15 | 35.1 | 76 | 15
24 | 47.1 | 15 | 45.6 | 97 | 15 | 41.1 | 87 | 15 | 36.9 | 78 | 15
25 | 47.4 | 15 | 45.2 | 95 | 15 | 41.5 | 88 | 15 | 36.0 | 76 | 15
26 | 47.8 | 15 | 46.3 | 97 | 15 | 42.7 | 89 | 15 | 36.5 | 76 | 15
Mean for weeks
1–13 | 30.5 | | 29.7 | 98 | | 27.8 | 92 | | 25.5 | 84
14–26 | 43.9 | | 42.5 | 97 | | 38.6 | 88 | | 33.7 | 77

TABLE 25 Mean Body Weights and Survival of Female p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Bromodichloromethane

Weeks on Study | 0 mg/L | | 175 mg/L | | | 350 mg/L | | | 700 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 18.9 | 15 | 18.9 | 100 | 15 | 18.8 | 100 | 15 | 18.6 | 98 | 15
2 | 19.6 | 15 | 19.6 | 100 | 15 | 19.3 | 99 | 15 | 19.1 | 97 | 15
3 | 20.8 | 15 | 20.2 | 97 | 15 | 20.0 | 96 | 15 | 20.0 | 96 | 15
4 | 21.8 | 15 | 21.4 | 98 | 15 | 21.4 | 98 | 15 | 21.1 | 97 | 15
5 | 22.1 | 15 | 21.9 | 99 | 15 | 21.9 | 99 | 15 | 22.0 | 100 | 15
6 | 22.0 | 15 | 21.9 | 100 | 15 | 22.4 | 102 | 14 | 22.3 | 101 | 15
7 | 22.3 | 15 | 22.1 | 99 | 15 | 21.8 | 98 | 14 | 21.9 | 98 | 15
8 | 23.3 | 15 | 22.5 | 97 | 15 | 23.2 | 100 | 14 | 22.7 | 97 | 15
9 | 23.6 | 15 | 23.0 | 98 | 15 | 23.5 | 100 | 14 | 22.4 | 95 | 15
10 | 24.6 | 15 | 23.7 | 96 | 15 | 24.3 | 99 | 14 | 24.1 | 98 | 15
11 | 24.7 | 15 | 24.4 | 99 | 15 | 24.6 | 100 | 14 | 24.1 | 98 | 15
12 | 25.3 | 15 | 24.5 | 97 | 15 | 25.2 | 100 | 14 | 24.6 | 97 | 15
13 | 26.5 | 15 | 25.2 | 95 | 15 | 25.8 | 97 | 14 | 24.9 | 94 | 15
14 | 27.1 | 15 | 26.0 | 96 | 15 | 27.0 | 100 | 14 | 25.9 | 96 | 15
15 | 27.9 | 15 | 26.4 | 95 | 15 | 27.3 | 98 | 14 | 26.3 | 94 | 15
16 | 29.0 | 15 | 26.4 | 91 | 15 | 27.8 | 96 | 14 | 26.9 | 93 | 15
17 | 28.7 | 15 | 26.8 | 93 | 15 | 28.3 | 99 | 14 | 28.4 | 99 | 15
18 | 29.1 | 15 | 27.6 | 95 | 15 | 28.7 | 99 | 14 | 27.6 | 95 | 15
19 | 29.8 | 15 | 28.1 | 94 | 15 | 29.2 | 98 | 14 | 27.5 | 92 | 15
20 | 30.6 | 15 | 29.1 | 95 | 15 | 29.4 | 96 | 14 | 28.3 | 93 | 15
21 | 31.5 | 15 | 29.7 | 94 | 15 | 30.4 | 97 | 14 | 29.2 | 93 | 15
22 | 32.7 | 15 | 30.8 | 94 | 15 | 30.9 | 95 | 14 | 30.0 | 92 | 15
23 | 34.0 | 15 | 32.2 | 95 | 15 | 32.9 | 97 | 14 | 30.4 | 89 | 15
24 | 35.3 | 15 | 32.1 | 91 | 15 | 33.2 | 94 | 14 | 30.8 | 87 | 15
25 | 35.6 | 15 | 32.1 | 90 | 15 | 32.6 | 92 | 14 | 31.3 | 88 | 15
26 | 36.4 | 15 | 33.2 | 91 | 15 | 34.0 | 93 | 14 | 31.7 | 87 | 15
Mean for weeks
1–13 | 22.7 | | 22.3 | 98 | | 22.5 | 99 | | 22.1 | 97
14–26 | 31.4 | | 29.3 | 93 | | 30.1 | 96 | | 28.8 | 92

FIGURE 7 Growth Curves for Male and Female p53 Haploinsufficient Mice Exposed to Bromodichloromethane in Drinking Water for 26 Weeks

## 42-Week Drinking Water Study in p53 Haploinsufficient Mice

### Survival

Estimates of 42-week survival probabilities for male and female p53 haploinsufficient mice are shown in Table 26. The survival of exposed males and females was similar to that of the control groups.

### Body Weights, Water and Compound Consumption, Clinical Findings, and Organ Weights

The mean body weights of males exposed to 350 or 700 mg/L were less than those of the controls after week 8 and week 1, respectively (Figure 8 and Table 27). Mean body weights of females were generally similar to those of the controls but were less than controls in 700 mg/L females during the last 3 weeks of the study (Figure 8 and Table 28). Water consumption by exposed groups was less than that by controls at the beginning of the study (Tables J7 and J8). Water consumption by exposed males and females improved, but that by exposed males remained lower at the end of the study. Drinking water concentrations of 175, 350, and 700 mg/L delivered average daily doses of approximately 14, 30, or 55 mg/kg to males and 22, 43, or 98 mg/kg to females. There were no chemical-related clinical findings. Absolute right kidney weights in 350 and 700 mg/L males were significantly less than those of the control group (Table H8). The weights of these organs decreased with increasing dose, mirroring a similar pattern in overall body weight. The relative right testis weight in 700 mg/L males and the relative liver weight in 700 mg/L females were greater than those of the control groups.

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions of the kidney. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables D5, D6, D7, and D8.

Kidney: The incidences of renal tubule degeneration in 350 and 700 mg/L males were significantly greater than that in the control group (0 mg/L, 0/10; 175 mg/L 0/10; 350 mg/L, 6/10; 700 mg/L, 10/10; Table D6). Renal tubule degeneration was morphologically similar to that previously described in the 26-week drinking water study in Tg.AC hemizygous mice.

TABLE 26 Survival of p53 Haploinsufficient Mice in the 42-Week Drinking Water Study of Bromodichloromethane

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Male
Animals initially in study | 10 | 10 | 10 | 10
Moribund | 1 | 0 | 0 | 3
Natural death | 0 | 0 | 1 | 0
Animals surviving to study termination | 9 | 10 | 9 | 7
Percent probability of survival at end of study^a^ | 90 | 100 | 90 | 70
Mean survival (days)^b^ | 289 | 296 | 294 | 258
Survival analysis^c^ | P=0.147 | P=1.000N | P=1.000N | P=0.540
Female
Animals initially in study | 10 | 10 | 10 | 10
Moribund | 1 | 1 | 0 | 1
Natural death | 0 | 0 | 0 | 1
Animals surviving to study termination | 9 | 9 | 10 | 8
Percent probability of survival at end of study | 90 | 90 | 100 | 80
Mean survival (days) | 296 | 286 | 297 | 266
Survival analysis | P=0.681 | P=1.000 | P=1.000N | P=0.924

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice)

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns. A lower mortality in an exposure group is indicated by N.

FIGURE 8 Growth Curves for Male and Female p53 Haploinsufficient Mice Exposed to Bromodichloromethane in Drinking Water for 42 Weeks

TABLE 27 Mean Body Weights and Survival of Male p53 Haploinsufficient Mice in the 42-Week Drinking Water Study of Bromodichloromethane

Weeks on Study | 0 mg/L | | 175 mg/L | | | 350 mg/L | | | 700 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 23.0 | 10 | 22.5 | 98 | 10 | 23.0 | 100 | 10 | 22.8 | 99 | 10
2 | 23.8 | 10 | 23.3 | 98 | 10 | 23.0 | 97 | 10 | 20.3 | 85 | 10
3 | 24.8 | 10 | 24.2 | 98 | 10 | 24.1 | 97 | 10 | 22.8 | 92 | 10
4 | 25.5 | 10 | 25.4 | 100 | 10 | 25.5 | 100 | 10 | 24.3 | 95 | 10
5 | 26.3 | 10 | 26.5 | 101 | 10 | 26.0 | 99 | 10 | 24.6 | 94 | 10
6 | 27.2 | 10 | 27.5 | 101 | 10 | 26.4 | 97 | 10 | 25.0 | 92 | 10
7 | 29.1 | 10 | 28.9 | 99 | 10 | 27.4 | 94 | 10 | 25.7 | 88 | 10
8 | 29.4 | 10 | 29.8 | 101 | 10 | 28.2 | 96 | 10 | 27.1 | 92 | 10
9 | 31.7 | 10 | 31.0 | 98 | 10 | 28.9 | 91 | 10 | 28.2 | 89 | 10
10 | 33.5 | 10 | 32.3 | 96 | 10 | 30.8 | 92 | 10 | 29.5 | 88 | 10
11 | 34.6 | 10 | 32.7 | 95 | 10 | 30.9 | 89 | 10 | 30.3 | 88 | 10
12 | 35.7 | 10 | 34.8 | 98 | 10 | 32.4 | 91 | 10 | 31.7 | 89 | 10
13 | 36.8 | 10 | 35.1 | 95 | 10 | 33.5 | 91 | 10 | 31.3 | 85 | 10
14 | 37.4 | 10 | 36.2 | 97 | 10 | 33.9 | 91 | 10 | 31.8 | 85 | 10
15 | 38.2 | 10 | 37.0 | 97 | 10 | 34.8 | 91 | 10 | 32.9 | 86 | 9
16 | 39.3 | 10 | 38.0 | 97 | 10 | 35.6 | 91 | 10 | 33.5 | 85 | 9
17 | 40.5 | 10 | 39.8 | 98 | 10 | 37.0 | 91 | 10 | 34.4 | 85 | 9
18 | 41.5 | 10 | 40.2 | 97 | 10 | 38.0 | 92 | 10 | 34.5 | 83 | 9
19 | 41.3 | 10 | 41.3 | 100 | 10 | 38.3 | 93 | 10 | 35.7 | 86 | 9
20 | 41.5 | 10 | 41.8 | 101 | 10 | 38.9 | 94 | 10 | 36.6 | 88 | 9
21 | 43.0 | 10 | 42.3 | 98 | 10 | 39.1 | 91 | 10 | 37.2 | 87 | 9
22 | 43.7 | 10 | 43.5 | 100 | 10 | 40.2 | 92 | 10 | 36.6 | 84 | 9
23 | 44.9 | 10 | 43.9 | 98 | 10 | 41.5 | 92 | 10 | 37.1 | 83 | 9
24 | 45.8 | 10 | 44.5 | 97 | 10 | 41.6 | 91 | 10 | 37.6 | 82 | 9
25 | 46.0 | 10 | 44.6 | 97 | 10 | 40.7 | 89 | 10 | 36.4 | 79 | 9
26 | 46.8 | 10 | 44.3 | 95 | 10 | 41.1 | 88 | 10 | 39.7 | 85 | 8
27 | 47.4 | 10 | 45.4 | 96 | 10 | 41.5 | 88 | 10 | 40.4 | 85 | 8
28 | 47.9 | 10 | 45.8 | 96 | 10 | 42.5 | 89 | 10 | 39.6 | 83 | 8
29 | 48.2 | 10 | 46.3 | 96 | 10 | 42.9 | 89 | 10 | 41.0 | 85 | 8
30 | 48.3 | 10 | 46.4 | 96 | 10 | 41.6 | 86 | 10 | 41.4 | 86 | 8
31 | 47.2 | 10 | 46.2 | 98 | 10 | 42.6 | 90 | 10 | 40.9 | 87 | 8
32 | 47.0 | 10 | 46.7 | 99 | 10 | 44.3 | 94 | 10 | 42.4 | 90 | 8
33 | 49.1 | 9 | 47.5 | 97 | 10 | 44.1 | 90 | 10 | 43.0 | 88 | 8
34 | 49.8 | 9 | 47.7 | 96 | 10 | 44.9 | 90 | 10 | 44.1 | 89 | 8
35 | 50.1 | 9 | 47.7 | 95 | 10 | 45.3 | 90 | 10 | 43.4 | 87 | 8
36 | 49.9 | 9 | 48.3 | 97 | 10 | 45.4 | 91 | 10 | 43.0 | 86 | 8
37 | 49.7 | 9 | 47.2 | 95 | 10 | 45.5 | 92 | 10 | 44.5 | 90 | 7
38 | 50.3 | 9 | 48.7 | 97 | 10 | 46.5 | 92 | 10 | 45.0 | 90 | 7
39 | 50.9 | 9 | 48.2 | 95 | 10 | 46.7 | 92 | 10 | 44.5 | 87 | 7
40 | 51.0 | 9 | 48.5 | 95 | 10 | 45.8 | 90 | 10 | 44.3 | 87 | 7
41 | 51.3 | 9 | 48.8 | 95 | 10 | 46.1 | 90 | 9 | 44.3 | 86 | 7
42 | 51.6 | 9 | 49.1 | 95 | 10 | 45.6 | 88 | 9 | 43.7 | 85 | 7
Mean for weeks
1–13 | 29.3 | | 28.8 | 98 | | 27.7 | 95 | | 26.4 | 90
14–42 | 46.2 | | 44.7 | 97 | | 41.8 | 91 | | 39.6 | 86

TABLE 28 Mean Body Weights and Survival of Female p53 Haploinsufficient Mice in the 42-Week Drinking Water Study of Bromodichloromethane

Weeks on Study | 0 mg/L | | 175 mg/L | | | 350 mg/L | | | 700 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 18.8 | 10 | 18.7 | 100 | 10 | 18.4 | 98 | 10 | 19.1 | 102 | 10
2 | 19.5 | 10 | 19.6 | 101 | 10 | 18.7 | 96 | 10 | 19.4 | 100 | 10
3 | 20.0 | 10 | 20.5 | 103 | 10 | 19.5 | 98 | 10 | 19.6 | 98 | 10
4 | 21.0 | 10 | 21.4 | 102 | 10 | 20.7 | 99 | 10 | 21.5 | 102 | 10
5 | 21.3 | 10 | 21.5 | 101 | 10 | 21.0 | 99 | 10 | 21.7 | 102 | 10
6 | 22.2 | 10 | 22.4 | 101 | 10 | 22.0 | 99 | 10 | 22.7 | 102 | 10
7 | 22.5 | 10 | 22.8 | 101 | 10 | 21.8 | 97 | 10 | 23.1 | 103 | 10
8 | 23.0 | 10 | 23.5 | 102 | 10 | 22.8 | 99 | 10 | 23.5 | 102 | 10
9 | 23.7 | 10 | 23.6 | 100 | 10 | 23.3 | 98 | 10 | 23.9 | 101 | 9
10 | 24.2 | 10 | 24.4 | 101 | 10 | 23.9 | 99 | 10 | 24.9 | 103 | 9
11 | 24.0 | 10 | 25.1 | 105 | 10 | 24.0 | 100 | 10 | 24.6 | 103 | 9
12 | 23.9 | 10 | 25.9 | 108 | 10 | 24.3 | 102 | 10 | 24.8 | 104 | 9
13 | 24.9 | 10 | 26.5 | 106 | 10 | 25.3 | 102 | 10 | 25.3 | 102 | 9
14 | 25.6 | 10 | 26.9 | 105 | 10 | 25.6 | 100 | 10 | 26.1 | 102 | 9
15 | 25.6 | 10 | 27.1 | 106 | 10 | 25.6 | 100 | 10 | 26.1 | 102 | 9
16 | 25.8 | 10 | 27.2 | 105 | 10 | 26.5 | 103 | 10 | 26.4 | 102 | 9
17 | 27.0 | 10 | 28.4 | 105 | 10 | 27.4 | 102 | 10 | 27.3 | 101 | 9
18 | 27.6 | 10 | 29.0 | 105 | 10 | 27.8 | 101 | 10 | 28.3 | 103 | 9
19 | 27.9 | 10 | 29.4 | 105 | 10 | 28.0 | 100 | 10 | 28.9 | 104 | 9
20 | 28.7 | 10 | 30.6 | 107 | 10 | 28.7 | 100 | 10 | 28.7 | 100 | 9
21 | 28.7 | 10 | 30.0 | 105 | 10 | 28.4 | 99 | 10 | 28.3 | 99 | 9
22 | 29.5 | 10 | 31.0 | 105 | 10 | 29.6 | 100 | 10 | 30.0 | 102 | 9
23 | 30.4 | 10 | 32.1 | 106 | 10 | 30.8 | 101 | 10 | 31.0 | 102 | 9
24 | 30.8 | 10 | 32.5 | 106 | 10 | 31.2 | 101 | 10 | 32.1 | 104 | 9
25 | 31.5 | 10 | 32.0 | 102 | 10 | 30.9 | 98 | 10 | 32.0 | 102 | 9
26 | 32.1 | 10 | 31.9 | 99 | 10 | 32.3 | 101 | 10 | 32.3 | 101 | 9
27 | 32.9 | 10 | 31.6 | 96 | 10 | 32.8 | 100 | 10 | 33.6 | 102 | 9
28 | 34.0 | 10 | 34.3 | 101 | 9 | 33.8 | 99 | 10 | 35.3 | 104 | 9
29 | 35.3 | 10 | 35.3 | 100 | 9 | 35.3 | 100 | 10 | 35.2 | 100 | 9
30 | 36.3 | 10 | 36.3 | 100 | 9 | 36.5 | 101 | 10 | 36.9 | 102 | 9
31 | 35.4 | 10 | 36.1 | 102 | 9 | 36.4 | 103 | 10 | 34.5 | 98 | 9
32 | 37.0 | 10 | 37.3 | 101 | 9 | 36.6 | 99 | 10 | 34.4 | 93 | 9
33 | 37.8 | 10 | 37.8 | 100 | 9 | 37.4 | 99 | 10 | 36.0 | 95 | 9
34 | 38.3 | 10 | 39.3 | 103 | 9 | 39.1 | 102 | 10 | 38.6 | 101 | 8
35 | 39.0 | 10 | 39.7 | 102 | 9 | 38.9 | 100 | 10 | 39.3 | 101 | 8
36 | 39.7 | 10 | 40.4 | 102 | 9 | 38.9 | 98 | 10 | 39.9 | 101 | 8
37 | 39.4 | 10 | 40.8 | 104 | 9 | 38.9 | 99 | 10 | 39.5 | 100 | 8
38 | 40.8 | 10 | 41.4 | 102 | 9 | 40.2 | 99 | 10 | 39.4 | 97 | 8
39 | 41.5 | 10 | 42.3 | 102 | 9 | 41.2 | 99 | 10 | 40.0 | 96 | 8
40 | 42.4 | 10 | 43.5 | 103 | 9 | 41.2 | 97 | 10 | 39.7 | 94 | 8
41 | 43.6 | 10 | 44.2 | 101 | 9 | 42.5 | 98 | 10 | 39.9 | 92 | 8
42 | 44.5 | 9 | 43.6 | 98 | 9 | 43.9 | 99 | 10 | 40.4 | 91 | 8
Mean for weeks
1–13 | 22.2 | | 22.8 | 102 | | 22.0 | 99 | | 22.6 | 102
14–42 | 34.1 | | 34.9 | 103 | | 34.0 | 100 | | 33.8 | 100

## 26-Week Gavage Study in p53 Haploinsufficient Mice

### Dose Selection Rationale

The doses administered in this 26-week gavage study (25, 50, and 100 mg/kg) were based on findings from previous 2- and 13-week gavage studies of bromodichloromethane in B6C3F_1_ mice and F344/N rats (NTP, 1987).

### Survival

Estimates of 26-week survival probabilities for male and female p53 haploinsufficient mice are shown in Table 29. The survival of dosed males and females was similar to that of the vehicle control groups.

### Body Weights, Clinical Findings, and Organ Weights

The mean body weights of males administered 50 or 100 mg/kg were less than those of the vehicle controls after weeks 5 and 1, respectively (Table 30 and Figure 9). Mean body weights of 50 mg/kg females were less than those of the vehicle control group after week 12, but those of 25 and 100 mg/kg females were generally similar to those of the vehicle controls throughout the study (Table 31 and Figure 9). No clinical findings related to bromodichloromethane administration occurred. The absolute heart, right kidney, and right testis weights in 100 mg/kg males were significantly less than those in the vehicle controls, and the relative weights in 50 and 100 mg/kg males were significantly greater (Table H9). The relative lung and liver weights in 100 mg/kg males were also greater. The absolute and relative liver weights in 100 mg/kg females were significantly greater than those in the vehicle control group.

### Hematology

The hematology data for p53 haploinsufficient mice in the 26-week gavage study of bromodichloromethane are listed in Table G5. There was a minimal decrease (5%) in erythrocyte count in 100 mg/kg male mice; the significance, if any, was not known, and females were not affected. Apparent dose-related increases in platelet counts occurred in 50 (2%) and 100 (7%) mg/kg male mice; however, the values were within what would be considered an acceptable reference limit; the relevance was not known, and females were unaffected.

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions of the liver and kidney. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables E1, E2, E3, and E4.

Liver: The incidence of fatty change in hepatocytes of 100 mg/kg females was significantly greater than that in the vehicle control group (vehicle control, 2/15; 25 mg/kg, 2/15; 50 mg/kg, 3/15; 100 mg/kg, 11/15; Table E4). Fatty change was morphologically similar to that previously described in the 26-week drinking water study in Tg.AC hemizygous mice.

Kidney: In 100 mg/kg males, the incidence of renal tubule degeneration was significantly greater than that in the vehicle control group (0/15, 0/15, 0/15, 4/15; Table E2). Renal tubule degeneration was morphologically similar to that previously described in the 26-week drinking water study in Tg.AC hemizygous mice.

TABLE 29 Survival of p53 Haploinsufficient Mice in the 26-Week Gavage Study of Bromodichloromethane

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Male
Animals initially in study | 15 | 15 | 15 | 15
Animals surviving to study termination | 15 | 15 | 15 | 15
Percent probability of survival at end of study^a^ | 100 | 100 | 100 | 100
Mean survival (days)^b^ | 183 | 183 | 183 | 183
Survival analysis^c^ | —^d^ | — | — | —
Female
Animals initially in study | 15 | 15 | 15 | 15
Accidental death^e^ | 0 | 0 | 1 | 0
Moribund | 0 | 1 | 0 | 1
Animals surviving to study termination | 15 | 14 | 14 | 14
Percent probability of survival at end of study | 100 | 93 | 100 | 93
Mean survival (days) | 184 | 178 | 172 | 176
Survival analysis | P=0.794 | P=1.000 | — | P=1.000

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice).

c The result of the life table trend test (Tarone, 1975) is in the vehicle control column, and the results of the life table pairwise comparisons (Cox, 1972) with the vehicle controls are in the dosed group columns.

d No deaths occurred in this group; value of statistic cannot be calculated.

e Censored from survival analyses

TABLE 30 Mean Body Weights and Survival of Male p53 Haploinsufficient Mice in the 26-Week Gavage Study of Bromodichloromethane

Weeks on Study | Vehicle Control | | 25 mg/kg | | | 50 mg/kg | | | 100 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 23.5 | 15 | 23.7 | 101 | 15 | 21.6 | 92 | 15 | 22.8 | 97 | 15
2 | 24.3 | 15 | 24.4 | 100 | 15 | 23.5 | 97 | 15 | 22.7 | 93 | 15
3 | 25.5 | 15 | 25.6 | 100 | 15 | 24.3 | 95 | 15 | 23.8 | 93 | 15
4 | 26.3 | 15 | 26.4 | 100 | 15 | 25.1 | 95 | 15 | 24.2 | 92 | 15
5 | 26.6 | 15 | 26.3 | 99 | 15 | 25.3 | 95 | 15 | 24.2 | 91 | 15
6 | 28.4 | 15 | 28.0 | 99 | 15 | 26.6 | 94 | 15 | 24.9 | 88 | 15
7 | 28.5 | 15 | 28.6 | 100 | 15 | 26.5 | 93 | 15 | 25.2 | 88 | 15
8 | 29.8 | 15 | 29.9 | 100 | 15 | 27.3 | 92 | 15 | 25.5 | 86 | 15
9 | 30.1 | 15 | 30.8 | 102 | 15 | 27.4 | 91 | 15 | 25.6 | 85 | 15
10 | 31.1 | 15 | 32.0 | 103 | 15 | 28.0 | 90 | 15 | 25.8 | 83 | 15
11 | 31.8 | 15 | 32.5 | 102 | 15 | 28.3 | 89 | 15 | 26.5 | 83 | 15
12 | 34.2 | 15 | 34.3 | 100 | 15 | 29.1 | 85 | 15 | 27.1 | 79 | 15
13 | 35.2 | 15 | 34.5 | 98 | 15 | 29.8 | 85 | 15 | 27.2 | 77 | 15
14 | 35.8 | 15 | 35.8 | 100 | 15 | 30.5 | 85 | 15 | 27.1 | 76 | 15
15 | 35.9 | 15 | 35.9 | 100 | 15 | 30.6 | 85 | 15 | 28.2 | 79 | 15
16 | 37.6 | 15 | 37.2 | 99 | 15 | 31.9 | 85 | 15 | 29.0 | 77 | 15
17 | 38.3 | 15 | 38.8 | 101 | 15 | 33.3 | 87 | 15 | 30.2 | 79 | 15
18 | 39.0 | 15 | 39.4 | 101 | 15 | 34.2 | 88 | 15 | 31.1 | 80 | 15
19 | 39.9 | 15 | 39.4 | 99 | 15 | 34.4 | 86 | 15 | 31.0 | 78 | 15
20 | 40.6 | 15 | 38.6 | 95 | 15 | 34.4 | 85 | 15 | 31.4 | 77 | 15
21 | 41.4 | 15 | 40.2 | 97 | 15 | 34.8 | 84 | 15 | 31.4 | 76 | 15
22 | 42.4 | 15 | 41.5 | 98 | 15 | 35.5 | 84 | 15 | 32.4 | 76 | 15
23 | 43.5 | 15 | 42.2 | 97 | 15 | 35.7 | 82 | 15 | 31.5 | 72 | 15
24 | 43.1 | 15 | 43.1 | 100 | 15 | 34.2 | 79 | 15 | 31.7 | 74 | 15
25 | 44.4 | 15 | 43.3 | 98 | 15 | 35.9 | 81 | 15 | 32.6 | 73 | 15
26 | 45.6 | 15 | 44.7 | 98 | 15 | 35.8 | 79 | 15 | 32.7 | 72 | 15
Mean for weeks
1–13 | 28.9 | | 29.0 | 100 | | 26.4 | 92 | | 25.0 | 87
14–26 | 40.6 | | 40.0 | 99 | | 33.9 | 84 | | 30.8 | 76

TABLE 31 Mean Body Weights and Survival of Female p53 Haploinsufficient Mice in the 26-Week Gavage Study of Bromodichloromethane

Weeks on Study | Vehicle Control | | 25 mg/kg | | | 50 mg/kg | | | 100 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 19.4 | 15 | 18.8 | 97 | 15 | 19.2 | 99 | 15 | 19.4 | 100 | 15
2 | 20.0 | 15 | 19.6 | 98 | 15 | 19.6 | 98 | 15 | 19.7 | 99 | 15
3 | 21.0 | 15 | 20.7 | 99 | 15 | 21.0 | 100 | 14 | 21.2 | 101 | 15
4 | 21.7 | 15 | 21.4 | 99 | 15 | 21.4 | 99 | 14 | 21.8 | 101 | 15
5 | 22.5 | 15 | 21.9 | 97 | 15 | 21.5 | 96 | 14 | 22.1 | 98 | 15
6 | 23.0 | 15 | 22.1 | 96 | 15 | 22.7 | 99 | 14 | 22.8 | 99 | 15
7 | 23.2 | 15 | 22.4 | 97 | 15 | 22.5 | 97 | 14 | 22.8 | 98 | 15
8 | 23.7 | 15 | 22.9 | 97 | 15 | 22.8 | 96 | 14 | 23.2 | 98 | 15
9 | 23.8 | 15 | 23.3 | 98 | 15 | 22.9 | 96 | 14 | 23.5 | 99 | 15
10 | 24.6 | 15 | 23.9 | 97 | 15 | 23.4 | 95 | 14 | 23.5 | 96 | 14
11 | 24.6 | 15 | 24.0 | 98 | 15 | 23.2 | 94 | 14 | 23.7 | 96 | 14
12 | 25.1 | 15 | 24.6 | 98 | 15 | 24.3 | 97 | 14 | 24.3 | 97 | 14
13 | 26.1 | 15 | 24.8 | 95 | 15 | 23.9 | 92 | 14 | 24.4 | 94 | 14
14 | 25.6 | 15 | 25.5 | 100 | 15 | 24.0 | 94 | 14 | 24.5 | 96 | 14
15 | 25.8 | 15 | 25.0 | 97 | 14 | 24.0 | 93 | 14 | 24.9 | 97 | 14
16 | 26.9 | 15 | 25.7 | 96 | 14 | 24.8 | 92 | 14 | 25.6 | 95 | 14
17 | 28.2 | 15 | 27.0 | 96 | 14 | 26.2 | 93 | 14 | 26.7 | 95 | 14
18 | 28.5 | 15 | 27.3 | 96 | 14 | 26.5 | 93 | 14 | 26.9 | 94 | 14
19 | 28.9 | 15 | 27.5 | 95 | 14 | 26.9 | 93 | 14 | 27.3 | 95 | 14
20 | 29.6 | 15 | 27.9 | 94 | 14 | 27.1 | 92 | 14 | 27.6 | 93 | 14
21 | 29.3 | 15 | 28.4 | 97 | 14 | 27.4 | 94 | 14 | 28.1 | 96 | 14
22 | 29.7 | 15 | 28.9 | 97 | 14 | 27.6 | 93 | 14 | 28.1 | 95 | 14
23 | 30.0 | 15 | 29.2 | 97 | 14 | 27.5 | 92 | 14 | 29.0 | 97 | 14
24 | 30.2 | 15 | 29.2 | 97 | 14 | 27.8 | 92 | 14 | 28.9 | 96 | 14
25 | 31.3 | 15 | 30.4 | 97 | 14 | 28.7 | 92 | 14 | 29.1 | 93 | 14
26 | 31.3 | 15 | 31.0 | 99 | 14 | 29.3 | 94 | 14 | 29.6 | 95 | 14
Mean for weeks
1–13 | 23.0 | | 22.3 | 97 | | 22.2 | 97 | | 22.5 | 98
13–26 | 28.9 | | 27.9 | 97 | | 26.8 | 93 | | 27.4 | 95

FIGURE 9 Growth Curves for Male and Female p53 Haploinsufficient Mice Administered Bromodichloromethane by Gavage for 26 Weeks

## 41-Week Gavage Study in p53 Haploinsufficient Mice

### Survival

Estimates of 41-week survival probabilities for male and female p53 haploinsufficient mice are shown in Table 32. The survival of dosed males and females was similar to that of the vehicle control groups.

### Body Weights, Clinical Findings, and Organ Weights

Mean body weights of 50 and 100 mg/kg males were less than those of the vehicle controls after week 4; mean body weights of 25, 50, and 100 mg/kg females were less after weeks 9, 14, and 24, respectively (Figure 10 and Tables 33 and 34). There were no clinical findings related to bromodichloromethane administration. The relative liver weights in 100 mg/kg males and females and in 25 and 50 mg/kg females were significantly greater than those of the vehicle controls, as was the relative right testis weight in 100 mg/kg males (Table H10). The absolute liver weight in 100 mg/kg females was increased with respect to the vehicle controls, and the absolute heart and right kidney weights in 100 mg/kg in males were decreased.

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions of the liver and kidney. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables E5, E6, E7, and E8.

Liver: The incidences of hepatocyte fatty change in 100 mg/kg males and females were significantly greater than those in the vehicle controls (males: vehicle control, 6/10; 25 mg/kg, 6/10; 50 mg/kg, 5/10; 100 mg/kg, 10/10; females: 3/10, 3/10, 6/10, 9/10; Tables E6 and E8). These lesions were morphologically similar to those previously described in the 26-week drinking water study in Tg.AC hemizygous mice.

Kidney: The incidences of renal tubule degeneration (0/10, 1/10, 0/10, 10/10) and nephropathy (4/10, 3/10, 4/10, 9/10) in 100 mg/kg males were significantly greater than those in the vehicle control group (Table E6). These lesions were morphologically similar to those previously described in the 26-week drinking water study in Tg.AC hemizygous mice.

TABLE 32 Survival of p53 Haploinsufficient Mice in the 41-Week Gavage Study of Bromodichloromethane

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Male
Animals initially in study | 10 | 10 | 10 | 10
Moribund | 0 | 1 | 0 | 0
Animals surviving to study termination | 10 | 9 | 10 | 10
Percent probability of survival at end of study^a^ | 100 | 90 | 100 | 100
Mean survival (days)^b^ | 288 | 267 | 288 | 288
Survival analysis^c^ | P=1.000N | P=1.000 | —^d^ | —
Female
Animals initially in study | 10 | 10 | 10 | 10
Accidental death^e^ | 0 | 0 | 1 | 0
Moribund | 0 | 1 | 1 | 1
Natural death | 1 | 0 | 0 | 0
Animals surviving to study termination | 9 | 9 | 8 | 9
Percent probability of survival at end of study | 90 | 90 | 89 | 90
Mean survival (days) | 286 | 288 | 257 | 286
Survival analysis | P=1.000 | P=1.000N | P=1.000 | P=1.000N

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice)

c The result of the life table trend test (Tarone, 1975) is in the vehicle control column, and the results of the life table pairwise comparisons (Cox, 1972) with the vehicle controls are in the dosed group columns. A negative trend or lower mortality in a dose group is indicated by N.

d No deaths occurred in this group; value of statistic cannot be calculated.

e Censored from survival analyses

FIGURE 10 Growth Curves for Male and Female p53 Haploinsufficient Mice Administered Bromodichloromethane by Gavage for 41 Weeks

TABLE 33 Mean Body Weights and Survival of Male p53 Haploinsufficient Mice in the 41-Week Gavage Study of Bromodichloromethane

Weeks on Study | Vehicle Control | | 25 mg/kg | | | 50 mg/kg | | | 100 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 23.7 | 10 | 23.4 | 99 | 10 | 23.4 | 99 | 10 | 23.5 | 99 | 10
2 | 25.0 | 10 | 24.1 | 96 | 10 | 23.6 | 94 | 10 | 23.9 | 96 | 10
3 | 25.7 | 10 | 24.8 | 97 | 10 | 24.6 | 96 | 10 | 24.8 | 97 | 10
4 | 26.7 | 10 | 25.8 | 97 | 10 | 25.2 | 94 | 10 | 25.3 | 95 | 10
5 | 27.3 | 10 | 26.0 | 95 | 10 | 25.1 | 92 | 10 | 25.0 | 92 | 10
6 | 28.5 | 10 | 26.7 | 94 | 10 | 26.4 | 93 | 10 | 25.9 | 91 | 10
7 | 29.0 | 10 | 27.3 | 94 | 10 | 26.3 | 91 | 10 | 26.2 | 90 | 10
8 | 30.5 | 10 | 28.6 | 94 | 10 | 27.1 | 89 | 10 | 26.4 | 87 | 10
9 | 31.0 | 10 | 29.1 | 94 | 10 | 27.7 | 89 | 10 | 26.0 | 84 | 10
10 | 31.7 | 10 | 30.6 | 97 | 10 | 28.7 | 91 | 10 | 26.8 | 85 | 10
11 | 31.9 | 10 | 31.0 | 97 | 10 | 29.0 | 91 | 10 | 27.2 | 85 | 10
12 | 33.9 | 10 | 33.1 | 98 | 9 | 29.9 | 88 | 10 | 28.4 | 84 | 10
13 | 33.8 | 10 | 32.8 | 97 | 9 | 30.7 | 91 | 10 | 28.5 | 84 | 10
14 | 34.1 | 10 | 33.1 | 97 | 9 | 31.6 | 93 | 10 | 29.0 | 85 | 10
15 | 35.8 | 10 | 34.2 | 96 | 9 | 31.8 | 89 | 10 | 29.4 | 82 | 10
16 | 37.7 | 10 | 35.6 | 94 | 9 | 33.2 | 88 | 10 | 30.5 | 81 | 10
17 | 38.1 | 10 | 37.1 | 97 | 9 | 34.4 | 90 | 10 | 31.2 | 82 | 10
18 | 39.5 | 10 | 38.5 | 98 | 9 | 35.4 | 90 | 10 | 32.0 | 81 | 10
19 | 40.3 | 10 | 37.9 | 94 | 9 | 35.6 | 88 | 10 | 32.5 | 81 | 10
20 | 41.8 | 10 | 39.3 | 94 | 9 | 36.7 | 88 | 10 | 33.0 | 79 | 10
21 | 41.4 | 10 | 39.6 | 96 | 9 | 35.6 | 86 | 10 | 32.6 | 79 | 10
22 | 41.7 | 10 | 39.2 | 94 | 9 | 34.5 | 83 | 10 | 32.9 | 79 | 10
23 | 42.3 | 10 | 38.6 | 91 | 9 | 35.9 | 85 | 10 | 33.5 | 79 | 10
24 | 42.3 | 10 | 39.9 | 94 | 9 | 36.7 | 87 | 10 | 33.4 | 79 | 10
25 | 42.4 | 10 | 40.1 | 95 | 9 | 37.7 | 89 | 10 | 33.7 | 80 | 10
26 | 42.2 | 10 | 40.6 | 96 | 9 | 37.3 | 88 | 10 | 34.1 | 81 | 10
27 | 43.4 | 10 | 40.7 | 94 | 9 | 37.7 | 87 | 10 | 34.9 | 80 | 10
28 | 43.3 | 10 | 42.3 | 98 | 9 | 38.7 | 89 | 10 | 35.4 | 82 | 10
29 | 45.1 | 10 | 42.5 | 94 | 9 | 39.0 | 87 | 10 | 35.6 | 79 | 10
30 | 44.6 | 10 | 42.6 | 96 | 9 | 39.5 | 89 | 10 | 35.6 | 80 | 10
31 | 45.7 | 10 | 43.0 | 94 | 9 | 39.6 | 87 | 10 | 35.8 | 78 | 10
32 | 47.0 | 10 | 44.1 | 94 | 9 | 39.0 | 83 | 10 | 36.9 | 79 | 10
33 | 47.1 | 10 | 44.5 | 95 | 9 | 39.7 | 84 | 10 | 37.1 | 79 | 10
34 | 46.6 | 10 | 44.8 | 96 | 9 | 41.2 | 88 | 10 | 37.8 | 81 | 10
35 | 47.4 | 10 | 45.3 | 96 | 9 | 41.4 | 87 | 10 | 37.7 | 80 | 10
36 | 48.1 | 10 | 45.8 | 95 | 9 | 41.0 | 85 | 10 | 38.4 | 80 | 10
37 | 47.7 | 10 | 45.4 | 95 | 9 | 41.7 | 87 | 10 | 38.7 | 81 | 10
38 | 47.6 | 10 | 44.4 | 93 | 9 | 41.6 | 87 | 10 | 39.0 | 82 | 10
39 | 48.7 | 10 | 46.5 | 96 | 9 | 42.4 | 87 | 10 | 40.1 | 82 | 10
40 | 49.8 | 10 | 46.1 | 93 | 9 | 43.0 | 86 | 10 | 40.3 | 81 | 10
41 | 50.5 | 10 | 46.6 | 92 | 9 | 43.8 | 87 | 10 | 40.2 | 80 | 10
Mean for weeks
1–13 | 29.1 | | 27.9 | 96 | | 26.7 | 92 | | 26.0 | 90
14–41 | 43.7 | | 41.4 | 95 | | 38.1 | 87 | | 35.0 | 80

TABLE 34 Mean Body Weights and Survival of Female p53 Haploinsufficient Mice in the 41-Week Gavage Study of Bromodichloromethane

Weeks on Study | Vehicle Control | | 25 mg/kg | | | 50 mg/kg | | | 100 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 19.3 | 10 | 18.9 | 98 | 10 | 19.4 | 101 | 10 | 19.3 | 100 | 10
2 | 20.1 | 10 | 19.9 | 99 | 10 | 20.2 | 101 | 10 | 19.8 | 99 | 10
3 | 20.9 | 10 | 20.5 | 98 | 10 | 21.5 | 103 | 9 | 20.3 | 97 | 10
4 | 22.2 | 10 | 22.0 | 99 | 10 | 22.1 | 100 | 9 | 21.6 | 97 | 10
5 | 22.9 | 10 | 22.5 | 98 | 10 | 22.5 | 98 | 9 | 20.6 | 90 | 10
6 | 23.4 | 10 | 22.9 | 98 | 10 | 23.0 | 98 | 9 | 22.0 | 94 | 10
7 | 23.0 | 10 | 22.5 | 98 | 10 | 23.0 | 100 | 9 | 21.6 | 94 | 10
8 | 23.5 | 10 | 23.1 | 98 | 10 | 23.5 | 100 | 9 | 22.5 | 96 | 10
9 | 24.0 | 10 | 23.4 | 98 | 10 | 23.4 | 98 | 9 | 23.0 | 96 | 10
10 | 25.0 | 10 | 23.6 | 94 | 10 | 24.3 | 97 | 9 | 23.5 | 94 | 10
11 | 25.3 | 10 | 23.5 | 93 | 10 | 23.9 | 95 | 9 | 23.4 | 93 | 10
12 | 25.8 | 10 | 24.5 | 95 | 10 | 25.2 | 98 | 9 | 24.4 | 95 | 10
13 | 25.8 | 10 | 24.1 | 93 | 10 | 23.9 | 93 | 9 | 24.7 | 96 | 10
14 | 25.9 | 10 | 23.5 | 91 | 10 | 25.0 | 97 | 9 | 24.9 | 96 | 10
15 | 26.4 | 10 | 24.6 | 93 | 10 | 24.8 | 94 | 9 | 25.0 | 95 | 10
16 | 27.6 | 10 | 25.1 | 91 | 10 | 25.5 | 92 | 9 | 25.9 | 94 | 10
17 | 28.5 | 10 | 26.6 | 93 | 10 | 26.8 | 94 | 9 | 27.0 | 95 | 10
18 | 28.9 | 10 | 26.9 | 93 | 10 | 27.0 | 93 | 9 | 27.5 | 95 | 10
19 | 28.9 | 10 | 26.3 | 91 | 10 | 26.8 | 93 | 9 | 27.5 | 95 | 10
20 | 29.6 | 10 | 27.5 | 93 | 10 | 27.7 | 94 | 9 | 28.7 | 97 | 10
21 | 30.2 | 10 | 27.3 | 90 | 10 | 27.7 | 92 | 9 | 28.0 | 93 | 10
22 | 30.0 | 10 | 27.5 | 92 | 10 | 27.0 | 90 | 9 | 27.9 | 93 | 10
23 | 31.0 | 10 | 28.1 | 91 | 10 | 28.2 | 91 | 9 | 28.9 | 93 | 10
24 | 29.9 | 10 | 28.0 | 94 | 10 | 28.6 | 96 | 9 | 28.9 | 97 | 10
25 | 32.0 | 10 | 29.1 | 91 | 10 | 29.5 | 92 | 9 | 29.8 | 93 | 10
26 | 33.1 | 10 | 28.7 | 87 | 10 | 29.7 | 90 | 9 | 30.4 | 92 | 10
27 | 32.9 | 10 | 29.1 | 88 | 10 | 30.0 | 91 | 9 | 30.0 | 91 | 10
28 | 34.2 | 10 | 30.2 | 88 | 10 | 30.5 | 89 | 9 | 30.4 | 89 | 10
29 | 33.6 | 10 | 29.5 | 88 | 10 | 30.9 | 92 | 9 | 30.6 | 91 | 10
30 | 34.0 | 10 | 29.5 | 87 | 10 | 30.7 | 90 | 9 | 30.9 | 91 | 10
31 | 34.8 | 10 | 29.9 | 86 | 10 | 30.7 | 88 | 9 | 30.1 | 87 | 10
32 | 35.4 | 10 | 30.2 | 85 | 10 | 31.1 | 88 | 9 | 30.3 | 86 | 10
33 | 35.3 | 10 | 30.2 | 86 | 10 | 31.4 | 89 | 9 | 30.6 | 87 | 10
34 | 34.8 | 10 | 30.4 | 87 | 10 | 32.7 | 94 | 9 | 31.2 | 90 | 10
35 | 35.5 | 10 | 31.7 | 89 | 10 | 32.8 | 92 | 9 | 31.5 | 89 | 10
36 | 35.0 | 10 | 31.5 | 90 | 10 | 33.0 | 94 | 9 | 30.5 | 87 | 10
37 | 35.2 | 10 | 31.3 | 89 | 10 | 33.8 | 96 | 8 | 31.2 | 89 | 10
38 | 35.0 | 9 | 31.6 | 90 | 10 | 34.7 | 99 | 8 | 32.6 | 93 | 10
39 | 37.1 | 9 | 32.1 | 87 | 10 | 35.3 | 95 | 8 | 34.6 | 93 | 9
40 | 37.8 | 9 | 32.4 | 86 | 10 | 35.5 | 94 | 8 | 35.0 | 93 | 9
41 | 38.8 | 9 | 34.5 | 89 | 9 | 36.4 | 94 | 8 | 35.2 | 91 | 9
Mean for weeks
1–13 | 23.2 | | 22.4 | 97 | | 22.8 | 99 | | 22.1 | 95
14–41 | 32.6 | | 29.0 | 89 | | 30.1 | 93 | | 29.8 | 92

## Genetic Toxicology

Five independent peripheral blood micronucleus tests were conducted with combinations of two transgenic mouse strains and three routes of administration to assess the ability of bromodichloromethane to induce chromosomal damage in erythrocytes after 26 weeks of exposure. No consistent pattern of effects or clearly positive responses emerged from these studies. Equivocal responses were obtained in tests with male and female Tg.AC hemizygous mice exposed to concentrations of 175, 350, or 700 mg/L in drinking water (Table F1) and male Tg.AC hemizygous mice dermally exposed to 64, 128, or 256 mg/kg (Table F2). Results of the dermal study in female Tg.AC hemizygous mice were judged to be negative (Table F2). The equivocal responses in these tests were the result of either a significant increase in micronucleated normochromatic erythrocytes (NCEs) at a single exposed or dosed group only, in the absence of a significant trend, or a significant trend in the absence of a significant increase in micronucleated NCEs for any one exposed or dosed group. Results of the micronucleus tests in male and female Tg.AC hemizygous mice administered 25, 50, or 100 mg/kg by gavage were negative (Table F3).

In p53 haploinsufficient mice, concentrations of 175, 350, or 700 mg/L in drinking water yielded equivocal results in male mice, based on a significant increase in micronucleated NCEs only at 350 mg/L; the trend test was not significant (P=0.057; Table F4). Female p53 haploinsufficient mice exposed to bromodichloromethane via drinking water showed no increase in micronucleated NCEs (Table F4). Results of peripheral blood micronucleus tests in male and female p53 haploinsufficient mice administered 25, 50, or 100 mg/kg by gavage were negative (Table F5).