# MATERIALS AND METHODS

## Procurement and Characterization

### Bromodichloromethane

A single lot of bromodichloromethane (14522LS) was obtained from Aldrich Chemical Co. (Milwaukee, WI) for use in the 26-, 39-, 41-, and 42-week studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory, Battelle Memorial Institute (Columbus, OH), and the study laboratory, Battelle Columbus Operations (Columbus, OH). Reports on analyses performed in support of the bromodichloromethane studies are on file at the National Institute of Environmental Health Sciences.

Lot 14522LS, a clear, colorless liquid, was identified as bromodichloromethane using infrared (IR) spectroscopy. The purity of lot 14522LS was determined using gas chromatography (GC). GC by one system indicated one major peak and three impurity peaks with a combined peak area of 1.9% relative to the major peak area. GC by a second system indicated a purity of 98.4% relative to a frozen reference standard of the same lot. The overall purity of lot 14522LS was determined to be 98% or greater.

Stability studies of another lot of bulk chemical (02107TG) were performed using GC. These studies indicated that bromodichloromethane was stable as a bulk chemical for at least 15 days when stored protected from light at temperatures up to 60° C. To ensure stability, the bulk chemical was stored at or below −20° C, protected from light, in heat-sealed glass ampules with potassium carbonate stabilizer. Stability of lot 14522LS was monitored during the studies using GC. No degradation of the bulk chemical was detected.

### 12-O-Tetradecanoylphorbol-13-acetate (TPA)

12-O-tetradecanoylphorbol-13-acetate was obtained from Sigma-Aldrich Chemical Company (St. Louis, MO) in one lot (48H1178) that was used in the 26-week studies in Tg.AC hemizygous mice. Identity and purity analyses were performed by Research Triangle Institute (Research Triangle Park, NC).

Lot 48H1178, a white crystalline powder, was identified as 12-O-tetradecanoylphorbol-13-acetate using IR and proton nuclear magnetic resonance (NMR) spectrometry. All spectra were consistent with the structure of 12-O-tetradecanoylphorbol-13-acetate. The purity of lot 48H1178 was determined using high performance liquid chromatography. This analysis indicated one major peak and one impurity peak with an area equal to approximately 0.11% of the total integrated peak area. The overall purity of lot 48H1178 was determined to be greater than 99%.

### Acetone

USP-grade acetone was obtained from Spectrum Chemicals and Laboratory Products (Gardena, CA) in three lots (NV0163, OG0513, OX0312) that were used during the 26- and 39-week dermal studies. Identity and purity analyses were performed by the study laboratory.

The identity of each lot was determined by IR spectroscopy. The purity of all lots was determined using GC. These analyses did not indicate any impurities with relative peak areas greater than 0.1% of the major peak. The overall purity of all lots used was determined to be greater than 99%. No degradation of the acetone was detected.

### Corn Oil

USP-grade corn oil was obtained from Spectrum Chemicals and Laboratory Products in six lots (OT0213, OU0101, OV0137, OH0409, PN0012, PO0173) that were used during the 26- and 41-week gavage studies. The study laboratory analyzed peroxide levels in bulk corn oil; potentiometric titration demonstrated peroxide concentrations below the acceptable limit of 3 mEq/kg.

## Preparation and Analysis of Dose Formulations

### Dermal Studies

The dose formulations were prepared approximately every 4 weeks by mixing bromodichloromethane with USP-grade acetone to give the required concentration (Table I2). The dose formulations were stored at room temperature in amber glass bottles with Teflon^®^-lined lids for up to 39 days. A positive control dose formulation of TPA was prepared twice during the studies by adding the appropriate amount of TPA to acetone; the formulations were stored at approximately 5° C in amber glass bottles for up to 6 months.

Stability studies of 0.4, 0.8, 1.6, 3.2, 6.4, and 12.8 µg/mL dose formulations were performed by the study laboratory using GC. Stability was confirmed for dose formulations stored in amber glass bottles with Teflon^®^-lined lids for up to 39 days at room temperature.

Periodic analyses of the dose formulations of bromodichloromethane were conducted by the study laboratory using GC. During the 26- and 39-week studies, dose formulations were analyzed four times (Table I3). All 12 dose formulations for Tg.AC hemizygous mice were within 10% of the target concentration. Animal room samples of these dose formulations were also analyzed; all nine animal room samples were within 10% of the target concentration.

### Drinking Water Studies

The dose formulations were prepared every 1 to 3 weeks by mixing bromodichloromethane with tap water (Table I2). Formulations were stored in glass bottles with Teflon^®^-lined lids at 5° C for up to 35 days. Positive control dose formulations of TPA were prepared and stored as described for the dermal studies.

Stability studies of 0.75, 0.9, 0.8, 1.0, 1.05, and 1.2 µg/mL dose formulations were performed by the study laboratory using GC. Stability was confirmed for at least 35 days for dose formulations stored in amber glass bottles at 5° C.

Periodic analyses of the dose formulations of bromodichloromethane were conducted by the study laboratory using GC. During the 26- and 42-week studies, dose formulations were analyzed four times. All 12 dose formulations for Tg.AC hemizygous and p53 haploinsufficient mice were within 10% of the target concentration (Table I4). Animal room samples of these dose formulations were also analyzed; three of nine Tg.AC hemizygous mouse animal room samples and none of the nine p53 haploinsufficient mouse animal room samples were within 10% of the target concentration. These low results were attributed to the volatility and hydrophobic nature of bromodichloromethane.

### Gavage Studies

The dose formulations were prepared approximately every 4 weeks by mixing bromodichloromethane with USP-grade corn oil to give the required concentrations (Table I2). Dose formulations were stored in amber glass bottles with Teflon^®^-lined lids and refrigerated for up to 35 days. The positive control dose formulations of TPA were prepared and stored as described for the dermal studies.

Stability studies of 0.4, 0.8, 1.6, 3.2, 6.4, and 12.8 µg/mL dose formulations were performed by the study laboratory using GC. Stability was confirmed for at least 21 days for dose formulations stored in glass bottles protected from light at room temperature.

Periodic analyses of the dose formulations of bromodichloromethane were conducted by the study laboratory using GC. During the 26- and 41-week studies, dose formulations were analyzed five times. All 12 dose formulations used in the studies for Tg.AC hemizygous and p53 haploinsufficient mice were within 10% of the target concentration (Table I5). Animal room samples of these dose formulations were also analyzed; eight of nine animal room samples were within 10% of the target concentration.

## Study Designs

### Dermal Studies

Groups of 15 male and 15 female Tg.AC hemizygous mice were administered 0, 64, 128, or 256 mg bromodichloromethane/kg body weight in 3.3 mL acetone/kg body weight 5 days per week for 26 weeks. Groups of 10 male and 10 female Tg.AC hemizygous mice were administered the same doses for 39 weeks. Vehicle control mice were administered acetone only. Doses were applied to the clipped dorsal skin from the mid-back to the interscapular area.

### Drinking Water Studies

Groups of 15 male and 15 female Tg.AC hemizygous and p53 haploinsufficient mice were exposed to 0, 175, 350, or 700 mg bromodichloromethane/L drinking water for 26 weeks. Groups of 10 male and 10 female Tg.AC hemizygous and p53 haploinsufficient mice were exposed to the same concentrations for 42 weeks.

### Gavage Studies

Groups of 15 male and 15 female Tg.AC hemizygous and p53 haploinsufficient mice were administered 0, 25, 50, or 100 mg bromodichloromethane/kg body weight in corn oil by gavage, 5 days per week for 26 weeks. Groups of 10 male and 10 female Tg.AC hemizygous and p53 haploinsufficient mice were administered the same doses for 41 weeks. Vehicle control mice were administered corn oil only.

### Positive Control Mice

For each route of administration, positive control groups of 15 male and 15 female Tg.AC hemizygous mice were administered 1.25 µg TPA in 100 µL acetone (12.5 µg TPA/L solution), three times per week for 26 weeks. The positive TPA controls are included because it has been shown that a subset of Tg.AC mice may revert and become non-responsive to tumor promoters (Honchel et al., 2001). The TPA solution was applied to the clipped dorsal skin from the mid-back to the interscapular area. Positive control mice were removed from study after the appearance of 20 or more skin papillomas and discarded.

### Source and Specification of Animals

Male and female FVB/N-TgN(v-Ha-ras)Led (Tg.AC) hemizygous and B6.129-Trp53^tm1Brd^ (N5) haploinsufficient mice were obtained from Taconic Laboratory Animals and Services (Germantown, NY) for use in the 26-, 39-, 41-, and 42-week studies. Mice were quarantined for 11 to 14 days before the beginning of the studies. Five male and five female mice per strain were randomly selected for parasite evaluation and gross observation of disease. Mice were approximately 6 weeks old at the beginning of the studies. Blood samples were collected from five male and five female sentinel mice from each study at 4 and 26 weeks, from five male and five female mice from the highest-surviving groups from each study at study termination, and from moribund mice from the dermal and drinking water studies after June 5, 2000. The sera were analyzed for antibody titers to rodent viruses (Boorman et al., 1986; Rao et al., 1989a,b). All results were negative.

### Animal Maintenance

Mice were housed individually. Feed and water were available ad libitum. Water consumption was measured weekly by cage (drinking water studies only). Cages and racks were rotated every 2 weeks. Further details of animal maintenance are given in Table 1.

### Clinical Examinations and Pathology

All animals were observed twice daily. Clinical findings and body weights were recorded initially, weekly, and at the end of the studies. Clinical findings for dermal and gavage study mice were recorded postdosing.

In-life observations of papilloma formation on the skin were recorded weekly using the Toxicology Data Management System (TDMS). A papilloma was initially recorded as a mass. The observation “papilloma” was not entered into TDMS for a given animal until the first-observed mass was documented for 3 consecutive weeks. At the third observation, a mass (wart-like in appearance) was entered as a papilloma. Any new mass(es) appearing after the 3-week confirmation period for a given animal at a different site was entered into TDMS first as a mass until the third week, when it was entered as a papilloma. In a few instances, a papilloma that had been previously observed was missing, and therefore not recorded. Reappearance of a mass at a later time was entered into TDMS as a mass until the third observation week, when it was called a papilloma.

At the end of the 26-week studies, blood for hematology analysis was collected from the retroorbital sinus of all mice (except positive controls) under carbon dioxide anesthesia. Samples for hematology analysis were placed in microcollection tubes (Sarstedt, Inc., Nümbrecht, Germany) coated with potassium EDTA. Hematocrit; erythrocyte, platelet, and leukocyte counts; mean cell hemoglobin; and mean cell hemoglobin concentration were determined with a Cell-Dyn^®^ hematology analyzer (Abbott Diagnostics, Santa Clara, CA). Hemoglobin concentrations were determined photometrically using a cyanmethemoglobin procedure. Differential leukocyte counts were determined microscopically from blood smears stained with a modified Wright-Giemsa stain. A Miller Disc was used to determine reticulocyte counts from smears prepared with blood stained with new methylene blue. Mean cell volumes were determined from average red blood cell impedance pulse heights. The parameters measured are listed in Table 1.

Necropsies and microscopic examinations were performed on all mice except positive controls. The heart, right kidney, liver, lung, right testis, and thymus were weighed. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 5 µm, and stained with hematoxylin and eosin for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Tissues examined microscopically are listed in Table 1.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The slides, paraffin blocks, and residual wet tissues were sent to the NTP Archives for inventory, slide/block match, and wet tissue audit. The slides, individual animal data records, and pathology tables were evaluated by an independent quality assessment laboratory. The individual animal records and tables were compared for accuracy; the slide and tissue counts were verified, and the histotechnique was evaluated. The quality assessment pathologist examined all tumors and all slides from potential target organs, which included the kidney and liver of Tg.AC hemizygous and p53 haploinsufficient mice in the 39-week dermal, 42-week drinking water, and 41-week gavage studies. The forestomach of Tg.AC hemizygous mice in the 41-week gavage study was also examined.

The quality assessment report and the reviewed slides were submitted to the NTP Pathology Working Group (PWG) chairperson, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and quality assessment pathologists.

Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and quality assessment pathologists, or lesions of general interest were presented by the chairperson to the PWG for review. The PWG consisted of the quality assessment pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups or previously rendered diagnoses. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman (1982) and Boorman et al. (1985). For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al. (1986).

The 26-week studies had not undergone a quality assessment review prior to completion of the pathology review for the 39-, 41-, and 42-week studies. For the 26-week studies, a quality assessment pathologist evaluated all tumor diagnoses from all animals and all potential target organs (both genders, both strains, all routes of administration), which included the liver, kidney, forestomach, and skin, using terminology and diagnostic criteria defined by the Pathology Working Group for the 39-, 41-, and 42-week studies in order to maintain diagnostic consistency between the studies. The quality assessment pathologist and two NTP pathologists met to review selected examples of lesions related to chemical administration and to address any disagreements in the diagnoses made by the laboratory and quality assessment pathologists. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, the quality assessment pathologist, and the NTP pathologists.

TABLE 1 Experimental Design and Materials and Methods in the Dermal, Drinking Water, and Gavage Studies of Bromodichloromethane

Dermal Studies | Drinking Water Studies | Gavage Studies
Study Laboratory
Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH)
Strain and Species
FVB/N-TgN(v-Ha-ras)Led (Tg.AC) hemizygous mice | FVB/N-TgN(v-Ha-ras)Led (Tg.AC) hemizygous mice and | FVB/N-TgN(v-Ha-ras)Led (Tg.AC) hemizygous mice and
| B6.129-Trp53^tm1Brd^ (N5) haploinsufficient mice | B6.129-Trp53^tm1Brd^ (N5) haploinsufficient mice
Animal Source
Taconic Laboratory Animals and Services, (Germantown, NY) | Taconic Laboratory Animals and Services, (Germantown, NY) | Taconic Laboratory Animals and Services, (Germantown, NY)
Time Held Before Studies
14 days | Tg.AC mice: 11 days | Tg.AC mice: 13 days
| p53 mice: 12 days | p53 mice: 14 days
Average Age When Studies Began
6 weeks | Tg.AC mice: 5 weeks | Tg.AC mice: 5 weeks
| p53 mice: 6 (males) or 7 (females) weeks | p53 mice: 6 (males) or 7 (females) weeks
Date of First Dose or Exposure
August 19, 1999 | Tg.AC mice: August 30, 1999 | Tg.AC mice: September 15, 1999
| p53 mice: August 31, 1999 | p53 mice: September 16, 1999
Duration of Dosing or Exposure
26 or 39 weeks | 26 or 42 weeks | 26 or 41 weeks
Date of Last Dose or Exposure
26-Week Studies | 26-Week Studies | 26-Week Studies
February 16, 2000 (males) | Tg.AC mice: February 28, 2000 (males) | Tg.AC mice: March 13, 2000 (males)
February 17, 2000 (females) | February 29, 2000 (females) | March 14, 2000 (females)
| p53 mice: March 1, 2000 (males) | p53 mice: March 15, 2000 (males)
| March 2, 2000 (females) | March 16, 2000 (females)
39-Week Studies | 42-Week Studies | 41-Week Studies
May 17, 2000 | Tg.AC mice: June 20, 2000 (males and females) | Tg.AC mice: June 27, 2000 (males and females)
| p53 mice: June 21, 2000 (males) | p53 mice: June 28, 2000 (males)
| June 22, 2000 (females) | June 29, 2000 (females)
Necropsy Dates
26-Week Studies | 26-Week Studies | 26-Week Studies
February 17, 2000 (males) | Tg.AC mice: February 28, 2000 (males) | Tg.AC mice: March 14, 2000 (males)
February 18, 2000 (females) | February 29, 2000 (females) | March 15, 2000 (females)
| p53 mice: March 1, 2000 (males) | p53 mice: March 16, 2000 (males)
| March 2, 2000 (females) | March 17, 2000 (females)
39-Week Studies | 42-Week Studies | 41-Week Studies
May 18, 2000 | Tg.AC mice: June 20, 2000 | Tg.AC mice: June 28, 2000
| p53 mice: June 21, 2000 (males) | p53 mice: June 29, 2000 (males)
| June 22, 2000 (females) | June 30, 2000 (females)
Average Age at Necropsy
26-Week Studies | 26-Week Studies | 26-Week Studies
32 weeks | Tg.AC mice: 31 weeks (males) | Tg.AC mice: 31 weeks (males)
| 32 weeks (females) | 32 weeks (females)
| p53 mice: 32 weeks (males) | p53 mice: 33 weeks
| 33 weeks (females)
39-Week Studies | 42-Week Studies | 41-Week Studies
45 weeks | Tg.AC mice: 48 weeks | Tg.AC mice: 46 weeks
| p53 mice: 48 weeks (males) | p53 mice: 48 weeks
| 49 weeks (females)
Size of Study Groups
26-Week Studies | 26-Week Studies | 26-Week Studies
15 males and 15 females | 15 males and 15 females | 15 males and 15 females
39-Week Studies | 42-Week Studies | 41-Week Studies
10 males and 10 females | 10 males and 10 females | 10 males and 10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as dermal studies | Same as dermal studies
Animals per Cage
1 | 1 | 1
Method of Animal Identification
Tail tattoo | Same as dermal studies | Same as dermal studies
Diet
Irradiated NTP-2000 open formula pelleted diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed weekly | Same as dermal studies | Same as dermal studies
Water
Tap water (Columbus, OH municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum | Tap water (Columbus, OH, municipal supply) via amber glass bottles (Supelco, Bellefonte, PA) with stainless steel double ball bearing sipper tubes (Ancare, Bellmore, NY) and Teflon^®^-coated septa, available ad libitum, changed twice weekly | Same as dermal studies
Cages
Polycarbonate (Lab Products Corp., Maywood, NJ), changed once weekly | Same as dermal studies | Same as dermal studies
Bedding
Irradiated Sani-Chips^®^ hardwood chips (P.J. Murphy Forest Products Corp., Maywood, NJ), changed weekly | Same as dermal studies | Same as dermal studies
Rack Filters
Dupont spun-bonded polyester (Snow Filtration Co., Cincinnati, OH), changed once every 2 weeks | Same as dermal studies | Same as dermal studies
Racks
Stainless steel racks (Lab Products Corp., Maywood, NJ), changed once every 2 weeks | Same as dermal studies | Same as dermal studies
Animal Room Environment
Temperature: 72° ± 3° F | Temperature: 72° ± 3° F | Temperature: 72° ± 3° F
Relative humidity: 50% ± 15% | Relative humidity: 50% ± 15% | Relative humidity: 50% ± 15%
Room fluorescent light: 12 hours/day | Room fluorescent light: 12 hours/day | Room fluorescent light: 12 hours/day
Room air changes: 10/hour | Room air changes: 10/hour | Room air changes: 10/hour
Doses or Exposure Concentrations
0, 64, 128, or 256 mg/kg bromodichloromethane dermally in acetone at a volume of 3.3 mL/kg body weight for 5 days per week or 1.25 μg TPA three times/week | 0, 175, 350, or 700 mg/L bromodichloromethane per day or 1.25 μg TPA applied dermally three times/week | 0, 25, 50, or 100 mg/kg bromodichloromethane in corn oil by gavage in a volume of 10 mL/kg body weight 5 days per week or 1.25 μg TPA applied dermally three times/week
Type and Frequency of Observation
Observed twice daily; animals were weighed and clinical findings were recorded initially, weekly, and at the end of the studies. Clinical findings were recorded after dosing. | Observed twice daily; animals were weighed and clinical findings were recorded initially, weekly, and at the end of the studies. Water consumption was recorded weekly. | Same as dermal studies
Method of Sacrifice
CO_2_ asphyxiation | Same as dermal studies | Same as dermal studies
Necropsy
Necropsies were performed on all animals (except positive controls). Organs weighed were heart, right kidney, liver, lung, right testis, and thymus. | Same as dermal studies | Same as dermal studies
Clinical Pathology
Blood was collected from the retroorbital sinus of all mice (except positive controls) at the end of the 26-week study for hematology.; Hematology: hematocrit; hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; erythrocyte and platelet morphology; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials | Same as dermal studies | Same as dermal studies
Histopathology
Histopathology was performed on all animals (except positive controls). In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, large intestine (colon and cecum), small intestine (duodenum, ileum, jejunum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, ovary, pituitary gland, skin, spleen, stomach (forestomach), testis with epididymis, thymus, thyroid gland, and uterus. | Histopathology was performed on all animals (except positive controls). In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, large intestine (colon and cecum), small intestine (duodenum, ileum, jejunum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), ovary, pituitary gland, spleen, stomach (forestomach), testis with epididymis, thymus, thyroid gland, and uterus. | Same as drinking water studies

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier (1958) and is presented in the form of graphs. Animals found dead of other than natural causes or missing were censored from the survival analyses; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s (1972) method for testing two groups for equality and Tarone’s (1975) life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented in Appendixes A, B, C, D, and E as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test (Gart et al., 1979), a procedure based on the overall proportion of affected animals, was used to determine significance.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed or exposed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett (1955) and Williams (1971, 1972). Hematology data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley (1977) (as modified by Williams, 1986) and Dunn (1964). Jonckheere’s test (Jonckheere, 1954) was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey (1957) were examined by NTP personnel, and implausible values were eliminated from the analysis. Average severity values were analyzed for significance with the Mann-Whitney U test (Hollander and Wolfe, 1973).

## Quality Assurance Methods

The 26-, 39-, 41-, and 42-week studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations (21 CFR, Part 58). In addition, as records from the these studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent quality assurance contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Report.

## Genetic Toxicology

### Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al. (1990). At the termination of the 26-week studies, peripheral blood samples were obtained from male and female Tg.AC hemizygous and p53 haploinsufficient mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic erythrocytes (NCEs) in each of up to 15 mice per dose or exposure group. In addition, the percentage of polychromatic erythrocytes (PCEs) in a population of 1,000 erythrocytes was determined as a measure of bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group, plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over dose or exposure groups with a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each dosed or exposed group and the control group (ILS, 1990). In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single dosed or exposed group is less than or equal to 0.025 divided by the number of dosed or exposed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed, and the magnitudes of those effects. Because these studies were not repeated, the results of the single micronucleus trials in these mice were accepted without replication.

### Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple aliquots of a chemical were tested in the same assay, and different results were obtained among aliquots and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary tables in the Abstract of this Report present a result that represents a scientific judgement of the overall evidence for activity of the chemical in an assay.