# INTRODUCTION

BROMODICHLOROMETHANE

CAS No. 75-27-4

Chemical Formula: CHBrCl_2_ Molecular Weight: 163.83

Synonyms: Dichlorobromomethane, monobromodichloromethane

## Chemical and Physical Properties

Bromodichloromethane, a clear, colorless liquid with a density of 1.980 g/mL at 20° C, is one of several trihalomethanes formed when organic substances in water react with chlorine or bromine (Stevens et al., 1976; Hoehn et al., 1978; Rook, 1980). Bromodichloromethane as a halogenated organic molecule is included in the trihalomethane class of chemicals formed as a by-product when drinking water supplies are disinfected by chlorination (Rook, 1974).

## Production, Use, and Human Exposure

The U.S. Environmental Protection Agency has established a maximum contaminant level of 0.080 mg/L for total trihalomethanes in community water systems serving more than 10,000 persons (40 CFR § 141.64). The presence of trihalomethanes in drinking water is believed to pose a risk to humans because chloroform, another trihalomethane found in drinking water, is carcinogenic in rats and mice (IARC, 1999a). Bromodichloromethane when administered in corn oil by oral gavage is carcinogenic for rats and mice (NTP, 1987). Trihalomethanes are widespread in the environment, not only in water supplies but also in swimming pools, soft drinks, and dump sites (NTP, 1987). The mean concentration of bromodichloromethane in chlorinated water supplies in the United States is 0.017 mg/L (range: 0 to 0.125 mg/L; Fed. Regist., 1979). Assuming that the average daily water consumption for an adult human male weighing 70 kg is 2 L per day, intake of bromodichloromethane could reach a maximum daily consumption of 4.0 pg/kg per day.

## Absorption, Distribution, and Excretion

Bromodichloromethane was administered in corn oil by gavage to male Sprague-Dawley rats at 100 mg/kg (16 pCi/kg) and to male B6C3F_1_ mice at 150 mg/kg (32 pCi/kg; Mink et al., 1986). Urine and expired gas were monitored for radioactivity, and tissue distribution was determined. Eight hours after administration of bromodichloromethane, the percentage of radioactivity recovered as expired carbon dioxide was 14% in rats and 81% in mice; the percentage of unmetabolized compound in expired air was 41% in rats and 7% in mice. The percentage of recovered label at 8 hours in expired air, urine, and tissues was 63% for rats and 93% for mice. Radioactivity was found in the liver, kidney, and stomach. These studies indicate that mice metabolize bromodichloromethane at a faster rate than do rats. Similar studies with chloroform, chlorodibromomethane, and bromoform indicated that mice also metabolize these trihalomethanes at a faster rate than do rats (Mink et al., 1986). In another series of experiments, bromodichloromethane, chloroform, chlorodibromomethane, bromoform, and iodoform were administered intraperitoneally in corn oil to male Sprague-Dawley rats at 1 mmol/kg body weight; blood samples were collected from the tail vein, and the amount of total carbon monoxide was measured. The highest blood carbon monoxide levels were observed after iodoform and bromoform administration; chlorodibromomethane, bromodichloromethane, and chloroform were metabolized at slower rates (Anders et al., 1978). Bromodichloromethane given in corn oil shows a complex blood profile that may reflect discontinuous stomach emptying into the small intestine (Lilly et al., 1998). While several P450 enzymes can metabolize bromodichloromethane, CYP2E1 appears to be the dominant hepatic CYP isoenzyme for metabolism of bromodichloromethane in both rats and humans at concentrations found in the drinking water (Allis and Zhao, 2002; Zhao and Allis, 2002).

## Toxicity

### Experimental Animals

The following oral LD_50_ values have been reported for bromodichloromethane: 450 mg/kg, male ICR mice; 900 mg/kg, female ICR mice; 916 mg/kg, male Sprague-Dawley rats; 969 mg/kg, female Sprague-Dawley rats; 450 mg/kg, male CD-1 mice; and 900 mg/kg, female CD-1 mice (Bowman et al., 1978; Chu et al., 1982). Clinical signs associated with bromodichloromethane administration at LD_50_ or higher doses included piloerection, sedation, flaccid muscle tone, ataxia, prostration, and enlargement and congestion of the liver and kidneys. Bromodichloromethane administered in corn oil by gavage for 14 consecutive days to 10 male CD-1 mice at 148 mg/kg per day caused focal inflammation of the liver and intratubular mineralization and epithelial hyperplasia of the kidney; however, no effect on body weight gain was seen (Condie et al., 1983). Kidney function was judged to be impaired because uptake of p-aminohippurate in renal cortical slices was decreased. No dose-related changes were seen in blood urea nitrogen or serum creatinine levels; serum glutamic-pyruvic transaminase activity (SGPT) was elevated. Munson et al. (1982) conducted a 14-day study in male and female CD-1 mice in which bromodichloromethane was administered by gavage in a solution of 10% emulphor at levels of 50 to 250 mg/kg per day. At the highest dose, liver weight, serum glutamic-oxaloacetic transaminase and SGPT activities, and blood urea nitrogen levels increased; body weight gain, serum glucose levels, and spleen weight decreased. Four days before sacrifice, a separate group of mice was immunized with sheep erythrocytes. The mice were sacrificed, and spleen cell suspensions were prepared and assayed for antibody-forming cells; at 250 mg/kg, antibody-forming cells were decreased, suggesting impairment of the immune system. Histopathologic evaluation of tissues was not reported. Bromodichloromethane administered to male and female Sprague-Dawley rats for 90 days in drinking water at levels up to 2,500 ppm (resulting in doses of approximately 100 mg/kg body weight and 135 mg/kg body weight) produced mild toxicity in the liver and decreased body weight gain (Chu et al., 1982). The vacuolar changes observed in the liver, interpreted as fatty infiltration, were reversed after a 90-day recovery period.

### Humans

There is no information on the acute toxicity of bromodichloromethane for humans.

## Reproductive Toxicity

### Experimental Animals

Bromodichloromethane was given to pregnant Sprague-Dawley rats in corn oil by gavage on days 6 through 15 of gestation at doses of 0, 50, 100, or 200 mg/kg per day (Ruddick et al., 1983). At the highest doses, maternal body weight gain was decreased, but no teratogenic effects were observed. A mixture of trihalomethanes and 15 other organic substances concentrated from water was given in dimethyl sulfoxide by gavage to pregnant CD-1 mice at 51, 170, or 510 mg/kg per day on days 7 through 14 of gestation; no indication of fetal toxicity was observed (Kavlock et al., 1979). By weight, the mixture contained 69% chloroform, 16% bromodichloromethane, 10% chlorodibromomethane, and 4% bromoform. Bromodichloromethane appears to have greater reproductive toxicity when administered in corn oil than when administered in an aqueous vehicle (Narotsky et al., 1997). However, even in a two-generation study, the oral exposure required to produce toxicity in rats is several orders of magnitude greater than human drinking water exposure (Christian et al., 2002).

### Humans

There have been a series of studies evaluating the potential for trihalomethanes in the drinking water to adversely affect pregnancy outcomes. A study in Sweden evaluating different chlorination methods did not find an effect on delivery outcomes (Källén and Robert, 2000), but the study was not based on the amount of by-products in the drinking water. Other studies have found a weak association between low birth weights and the levels of trihalomethanes in the drinking water (Källén and Robert, 2000; Bove et al., 2002; Aggazzotti et al., 2004). Other studies have shown increased adverse birth outcomes in municipalities that chlorinate their drinking water compared with those that do not chlorinate (Yang, 2004).

## Carcinogenicity

### Experimental Animals

There have been several rodent studies evaluating the potential carcinogenicity of bromodichloromethane. Bromodichloromethane or chloroform was administered in drinking water to male and female Wistar rats for up to 180 weeks (Tumasonis et al., 1985). During the first 72 weeks of the study, bromodichloromethane was administered at concentrations of 0 or 1.2 mL (2.4 g) per liter of drinking water; at week 72, the concentration was halved because of a gradual increase in water intake. The dose of bromodichloromethane was estimated at 150 mg/kg per day in female rats and 200 mg/kg per day in male rats. The liver and grossly observable lesions were examined. An increased incidence of hepatic neoplastic nodules was found in females (but not in males) when bromodichloromethane was administered throughout the lifespan [males: control, 5/22 (23%); dosed, 6/47 (13%); females: control, 0/18; dosed 17/53 (32%)].

NTP studies showed increased kidney cancer in F344/N rats and male B6C3F_1_ mice plus increased incidences of liver cancer in female mice following bromodichloromethane exposure by oral gavage in corn oil (NTP, 1987). However, most attention was on the increased incidences of adenocarcinoma of the large intestine in male and female rats following oral gavage exposure to bromodichloromethane (males: vehicle control, 0/50; 50 mg/kg, 11/50; 100 mg/kg, 38/50; females: 0/46, 0/50, 6/47) because colon and rectal neoplasms have been associated with trihalomethane exposure in drinking water in humans (Gottlieb and Carr 1982; NTP, 1987; King et al., 2000). In another study, bromodichloromethane in the drinking water did not cause colon cancer in male rats or male mice (George et al., 2002). Exposure-related cancers were not found at any site in the male mice, but the authors report a marginal increase in benign liver cancer but only at the lowest dose. The NTP (2006) conducted toxicology and carcinogenesis studies of bromodichloromethane at concentrations of 0, 175, 350, or 700 mg/L in drinking water for 2 years in male F344/N rats and female B6C3F_1_ mice. There was no evidence of increased incidences of neoplasms in the exposed rats or mice compared to the control groups.

Male and female Long-Evans rats from a mutant Tsc2 (Eker rats) exposed to 70 and 700 mg/L of bromodichloromethane in the drinking water failed to show an increase in hyperplasia in either the urinary bladder (another potential human cancer associated with chlorinated water) or colon epithelium (McDorman et al., 2003). However, these rats did show a nonstatistical increase in aberrant crypt foci in the colon. Bromodichloromethane both in the drinking water and by oral gavage in corn oil produced a marginal increase in aberrant crypt foci that was significant only for the drinking water group (Geter et al., 2004).

Bromodichloromethane was administered as a microencapsulated preparation in feed to Wistar rats at concentrations of 0, 140, 550, or 2,200 ppm (w/w) bromodichloromethane for 24 months (Aida et al., 1992). Histologic findings included cholangiofibrosis and/or fibrosis in the liver of males and females in the 2,200 ppm group at 6, 12, 18, and 24 months. Tumors of the liver were not increased in dosed rats.

### Humans

Exposure to chlorinated drinking water and trihalomethanes has been associated with increased rates of various cancers in humans. Several studies have noted an increase in colon or rectal cancers with exposure to chlorination by-products (Young et al., 1987; Hildesheim et al., 1998). Modeling human exposure to drinking water disinfection by-products is difficult at best, and the epidemiology results are often not consistent across sexes (usually only males) or cancer sites (increase in rectal cancer and not colon cancer in one study, increase in colon but not rectal cancer in a second study), while other studies fail to show a cancer effect (Young et al., 1987).

More human studies have evaluated the effect of chlorinated water on bladder cancer. Some studies have shown an association (Villanueva et al., 2003; Chevrier et al., 2004); however, reconstructing accurate and specific disinfection by-product exposure histories over long periods of time is difficult. Generally the studies suggest an association between increasing rates of bladder cancer and increasing chlorinated water exposure (McGeehin et al., 1993) but no association between total trihalomethane exposure and bladder cancer risk.

## Genetic Toxicity

The mutagenicity data for bromodichloromethane were reviewed by IARC (1999b). The data from a large number of tests show mixed results that may, in some cases, be directly related to inadequate exposures to this volatile chemical. A summary of the most significant observations follows.

Bromodichloromethane was mutagenic in Salmonella typhimurium strains sensitive to base substitution mutations, such as TA100 and TA1535, when tested with protocols that controlled for volatility (Simmon et al., 1977; Pegram et al., 1997; DeMarini et al., 1997). Bromodichloromethane was not mutagenic at the tk locus in mouse lymphoma L5178Y cells treated without exogenous liver activation enzymes (S9), but with induced rat liver S9, a highly significant dose-related induction of mutant colonies was seen (McGregor et al., 1988).

Bromodichloromethane (maximum dose, 1 mmol/kg) induced chromosome aberrations in bone marrow cells of Long-Evans rats 12 hours after a single intraperitoneal injection, but not after 5 days of oral administration (Fujie et al., 1990). Male ICR/SJ mice treated by oral gavage once daily for 4 days with doses of 25, 50, or 100 mg/kg bromodichloromethane showed elevated frequencies of sister chromatid exchanges in bone marrow samples (Fujie et al., 1993). Bromodichloromethane did not induce micronuclei in bone marrow cells of male ddy mice given one or four daily intraperitoneal injections of up to 500 mg/kg or 200 mg/kg for single or multiple injections, respectively (Hayashi et al., 1988). However, bromodichloromethane did induce a small but significant increase in micronucleated erythrocytes in peripheral blood of C57BL/6 and FVB/N p53 heterozygous mice exposed by inhalation to 15 ppm for 13 weeks (Torti et al., 2002). In vitro, bromodichloromethane induced chromosomal aberrations in cultured Chinese hamster lung fibroblasts incubated for 48 hours, in tightly capped flasks, in the presence or absence of rat liver S9 (Matsuoka et al., 1996); tests with bromodichloromethane for chromosomal aberration induction in Chinese hamster ovary cells incubated with loose caps were negative (Anderson et al., 1990).

Bromodichloromethane administered by gavage did not induce unscheduled DNA synthesis, a measure of DNA damage, in the livers of Sprague-Dawley rats after single doses of 135 or 450 mg/kg (Stocker et al., 1997). Furthermore, no induction of DNA strand breaks was noted in kidney cells of F344 rats after 7 days of exposure to 0.75 or 1.5 mmol/kg (Potter et al., 1996). In vitro, bromodichloromethane induced a dose-related increase in DNA damage in Escherichia coli in the absence of exogenous metabolic activation; the response was enhanced markedly in experiments conducted with rat liver S9 (Le Curieux et al., 1995). Bromodichloromethane was more potent than other trihalomethanes and methylene chloride at inducing DNA strand breaks in cultured human lung epithelial cells (Landi et al., 2003).

## Background on Genetically Altered Mice

Mutation and/or deletions of tumor suppressor genes or activation of protooncogenes can disrupt cell function and predispose an animal to cancer. In the current studies, two genetically altered mouse models with either a loss of heterozygosity in a critical cancer gene (Trp53) or a gain of oncogene function (Ha-ras) were used to determine how these animals would respond to bromodichloromethane exposure. The Tg.AC hemizygous and p53 haploinsufficient mice have been shown to be susceptible to the rapid development of cancer and are being evaluated by the National Institute of Environmental Health Sciences (NIEHS) and the NTP as models for identifying chemical toxicity and/or chemical carcinogenic processes (Tennant et al., 1996; Pritchard et al., 2003).

### FVB/N-TgN (v-Ha-ras)Led (Tg.AC) Hemizygous Mouse Model

The Tg.AC hemizygous transgenic mouse model has been evaluated as a reporter phenotype (skin papillomas) in response to either genotoxic or nongenotoxic carcinogens, including tumor promoters (Spalding et al., 1993, 1999; Tennant et al., 1999). The Tg.AC strain of mice are hemizygous for a mutant v-Ha-ras transgene. The model was developed by Leder et al. (1990) with an inducible zeta-globin promoter driving the expression of a mutated (point mutation in codons 12 and 59) v-Ha-ras oncogene and is regarded as a genetically initiated model. With the exception of bone marrow, constitutive expression of the transgene cannot be detected in adult tissues. The transgene is usually transcriptionally silent until activated by certain treatments including full-thickness wounding, ultraviolet irradiation, or exposure to some chemicals (Cannon et al., 1997; Trempus et al., 1998). Point mutations in the Ha-ras gene are believed to be early events in the induction of skin papillomas and malignancies. Topical application of carcinogens to the shaved dorsal surface of Tg.AC hemizygous mice induces epidermal squamous cell papillomas or carcinomas, a reporter phenotype that defines the activity of the chemical. 12-O-tetradecanoylphorbol-13-acetate (TPA) has been used as a positive control in NIEHS Tg.AC mouse studies to confirm the mice are responsive to carcinogens because it has been found that a subset of Tg.AC mice may revert and become nonresponsive to a tumor promoter (Honchel et al., 2001). The oral route of administration can also generate tumor responses in the skin of Tg.AC hemizygous mice and lead to squamous cell papillomas and/or carcinomas of the forestomach. To date, the appearance of either spontaneous or induced tumors has been shown to involve transgene expression. However, the mechanism of response by the Tg.AC hemizygous mouse model to chemical carcinogens is not yet understood.

In NIEHS studies, mice are exposed beginning at 2 months of age for a total of 6 to 9 months. Cutaneous papillomas at various sites have been reported at 3.7% and 3.8% incidence in 33-week-old control male and female Tg.AC hemizygous mice, respectively (Mahler et al.,1998). Cutaneous papillomas occurring at sites such as the lip, pinnae, prepuce, and vulva suggest a possible relationship to grooming and chronic irritation. Up to 32% of Tg.AC homozygous and heterozygous male or female mice can develop odontogenic tumors as early as 33 weeks (Wright et al., 1995; Mahler et al., 1998). A number of different tumor types occur in untreated Tg.AC hemizygous mice at an incidence of greater than 3% including odontogenic tumors, forestomach papillomas, cutaneous papillomas, alveolar/bronchiolar adenomas, salivary gland duct carcinomas, and erythroleukemia (Mahler et al.,1998). In the FVB mouse (the background strain for the Tg.AC hemizygous mouse), alveolar/bronchiolar neoplasms occur at 14 months of age (Mahler et al., 1996).

The Tg.AC hemizygous mouse model was used in the current Report for the studies of bromodichloromethane because this model has been reported to detect both nongenotoxic and genotoxic carcinogens (Spalding et al., 1993; Tennant et al., 1995, 1996; Pritchard, 2003). Tg.AC mice may spontaneously lose a portion of the zeta-globlin promoter sequence making them unresponsive to TPA-initated tumors (Thompson et al., 1998). Therefore, TPA positive controls were included for Tg.AC studies.

### B6.129-Trp53^tm1Brd^ (N5) Mouse Model

The heterozygous B6.129-Trp53 (N12)^tmlBrd(+/−)^ mouse (on a B6.129S7 background) was developed by Donehower et al. (1992). A null mutation was introduced into one p53 allele by homologous recombination in murine embryonic stem cells. Insertion of a neo cassette resulted in deletion of a 450-base pair gene fragment containing 106 nucleotides of exon 5 and approximately 350 nucleotides of intron 4.

Trp53, a nuclear protein, plays an essential role in the regulation of the cell cycle, specifically in the transition from G_0_ to G_1_, as well as G_2_ to M, and the spindle apparatus. The p53 protein is labile and exists at very low concentrations in normal cells; mutants of p53 are expressed in high amount in DNA damaged cells or a variety of transformed cell lines and are believed to contribute to transformation and malignancy. The p53 protein is a DNA-binding protein containing DNA-binding, oligomerization, and transcription activation domains. Many amino acid residues may be phosphorylated or acetylated, which may determine p53 function. It is postulated to bind as a tetramer to a p53-binding site and activate expression of downstream genes that inhibit growth and/or invasion or promote apoptosis, functioning as a tumor suppressor. This protein is critical to tumor suppression in humans and rodents. Mutants of p53 that fail to bind the consensus DNA binding site frequently occur in human cancers, and are unable to function as tumor suppressors. Alterations of the Trp53 gene occur not only as somatic mutations in human malignancies, but also as germline mutations in some cancer-prone families with Li-Fraumeni syndrome.

The mouse heterozygous for a p53 null allele (+/−) has only a single functional wild-type p53 allele which provides a target for mutagens. The p53 tumor suppressor gene is one of the most common sites for mutations and gene alterations in human cancer (Harris, 1996a,b,c).

Heterozygous p53^(+/−)^ mice develop normally and like humans and other mammals, develop cancer (primarily lymphomas or sarcomas) with age, but often with decreased latency.

## Study Rationale

The purpose of this study was twofold. Given the hundreds of potentially hazardous disinfection by-products (Bull et al., 1995), usually at very low concentrations and occurring as mixtures, a more efficient process for determining safety of chemicals and chemical mixtures found in finished drinking water is needed (Boorman et al., 1999). One objective of this study was to help determine whether the use of genetically modified mice could reduce study length and increase sensitivity for determining potential hazards of drinking water disinfection by-products compared to traditional rodent bioassays. This study was one of three studies to investigate the Tg.AC hemizygous and p53 haploinsufficient mouse models using disinfection by-products that had been extensively studied using traditional rodent models. The results of dichloroacetic acid (NTP, 2007a) and sodium bromate (NTP, 2007b) are being reported separately. The second objective was to determine whether the use of genetically modified mice could provide more insight on the apparent discrepancy in carcinogenicity results between studies where bromodichloromethane is given in the drinking water and where it is given by oral gavage.

This Report focuses on Tg.AC hemizygous and p53 haploinsufficient strains that were exposed to bromodichloromethane in the drinking water and also in corn oil by gavage for up to 42 weeks. The Tg.AC hemizygous mouse strain was also exposed to bromodichloromethane by the dermal route, which if predictive, could prove to be the most efficient screening procedure for drinking water mixtures.