# APPENDIX J WATER AND COMPOUND CONSUMPTION IN THE DRINKING WATER STUDIES OF BROMODICHLOROMETHANE

TABLE J1 Water and Compound Consumption by Male Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Bromodichloromethane

Week | 0 mg/L | | 175 mg/L | | | 350 mg/L | | | 700 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg) | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg)
1 | 7.7 | 23.1 | 2.1 | 22.6 | 16 | 1.4 | 22.6 | 21 | 1.1 | 22.7 | 34
2 | 4.6 | 24.6 | 2.7 | 24.1 | 20 | 2.6 | 23.2 | 39 | 1.7 | 20.8 | 57
3 | 5.9 | 26.1 | 3.1 | 25.7 | 21 | 2.8 | 25.0 | 40 | 2.1 | 23.9 | 61
4 | 4.4 | 26.8 | 3.1 | 26.7 | 20 | 2.9 | 25.8 | 39 | 2.4 | 25.9 | 65
5 | 4.8 | 27.8 | 3.2 | 27.7 | 20 | 2.8 | 27.3 | 36 | 2.4 | 26.5 | 63
6 | 5.3 | 29.4 | 3.2 | 28.9 | 19 | 2.8 | 28.1 | 35 | 2.4 | 27.3 | 61
7 | 4.8 | 30.0 | 3.6 | 29.4 | 22 | 3.0 | 28.6 | 36 | 2.9 | 27.4 | 74
8 | 5.0 | 30.2 | 3.8 | 29.9 | 22 | 3.4 | 28.9 | 41 | 2.6 | 28.1 | 65
9 | 4.7 | 31.0 | 4.0 | 30.5 | 23 | 3.4 | 29.5 | 40 | 2.7 | 28.7 | 65
10 | 4.9 | 32.0 | 3.7 | 31.1 | 21 | 3.0 | 30.1 | 35 | 2.7 | 29.3 | 65
11 | 5.2 | 32.8 | 3.8 | 31.4 | 21 | 3.2 | 30.0 | 37 | 2.6 | 30.2 | 61
12 | 6.0 | 32.6 | 4.3 | 32.2 | 23 | 3.2 | 30.6 | 36 | 2.6 | 30.7 | 60
13 | 4.7 | 34.2 | 4.2 | 33.1 | 22 | 3.3 | 31.4 | 37 | 2.7 | 31.8 | 60
14 | 5.3 | 34.9 | 4.0 | 33.5 | 21 | 3.1 | 31.6 | 34 | 2.7 | 32.1 | 59
15 | 5.2 | 35.2 | 4.1 | 33.6 | 21 | 3.6 | 31.3 | 41 | 2.8 | 32.1 | 62
16 | 4.6 | 35.7 | 3.7 | 34.5 | 19 | 3.1 | 31.9 | 34 | 2.8 | 33.1 | 59
17 | 4.6 | 35.8 | 4.1 | 34.7 | 21 | 3.5 | 32.0 | 39 | 3.1 | 32.8 | 66
18 | 5.3 | 35.9 | 4.3 | 35.0 | 22 | 3.6 | 32.1 | 39 | 3.2 | 33.1 | 68
19 | 5.0 | 35.6 | 4.0 | 34.6 | 20 | 3.6 | 32.7 | 38 | 2.8 | 32.9 | 60
20 | 5.0 | 36.9 | 3.9 | 35.4 | 19 | 3.4 | 33.5 | 35 | 3.1 | 32.7 | 65
21 | 5.3 | 37.6 | 4.1 | 36.4 | 20 | 3.7 | 34.7 | 38 | 3.1 | 32.6 | 66
22 | 4.9 | 38.4 | 3.9 | 37.9 | 18 | 3.4 | 34.9 | 34 | 3.0 | 33.2 | 64
23 | 4.3 | 39.2 | 3.8 | 38.7 | 17 | 3.5 | 35.6 | 34 | 2.9 | 34.9 | 59
24 | 4.6 | 39.6 | 4.1 | 39.9 | 18 | 3.6 | 35.9 | 35 | 2.9 | 36.2 | 55
25 | 4.8 | 40.2 | 3.9 | 40.2 | 17 | 3.6 | 37.3 | 34 | 2.9 | 35.9 | 56
26 | 4.1 | 41.0 | 3.7 | 40.4 | 16 | 3.6 | 38.3 | 33 | 2.9 | 36.5 | 55
Mean for Weeks
1–13 | 5.2 | 29.3 | 3.4 | 28.7 | 21 | 2.9 | 27.8 | 36 | 2.4 | 27.2 | 61
14–26 | 4.8 | 37.4 | 4.0 | 36.5 | 19 | 3.5 | 34.0 | 36 | 2.9 | 33.7 | 61

a Grams of water consumed per animal per day

b Milligrams of bromodichloromethane consumed per kilogram body weight per day

TABLE J2 Water and Compound Consumption by Female Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Bromodichloromethane

Week | 0 mg/L | | 175 mg/L | | | 350 mg/L | | | 700 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg) | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg)
1 | | | 2.7 | 19.1 | 24 | 1.5 | 19.0 | 28 | 1.5 | 18.9 | 55
2 | 6.0 | 20.0 | 3.4 | 20.3 | 29 | 3.1 | 20.2 | 54 | 3.6 | 20.2 | 126
3 | 6.6 | 21.2 | 4.1 | 21.4 | 33 | 4.3 | 21.3 | 70 | 5.0 | 21.4 | 163
4 | 6.o | 22.3 | 4.0 | 22.3 | 32 | 4.6 | 22.3 | 72 | 4.3 | 22.3 | 135
5 | 4.9 | 23.2 | 4.2 | 23.1 | 32 | 4.1 | 22.7 | 64 | 4.1 | 22.7 | 128
6 | 6.6 | 24.2 | 4.3 | 24.1 | 31 | 4.6 | 23.6 | 68 | 4.8 | 23.8 | 140
7 | 6.6 | 24.6 | 4.6 | 24.3 | 33 | 4.8 | 23.9 | 71 | 4.6 | 23.8 | 135
8 | | | 4.8 | 24.7 | 34 | 5.0 | 24.4 | 71 | 4.9 | 24.0 | 142
9 | 5.8 | 24.8 | 5.1 | 25.8 | 35 | 4.9 | 24.8 | 70 | 4.8 | 25.0 | 136
10 | 5.8 | 25.4 | 5.3 | 25.6 | 36 | 5.0 | 25.1 | 69 | 5.2 | 25.3 | 145
11 | 5.1 | 24.5 | 4.9 | 27.1 | 32 | 4.8 | 25.5 | 65 | 5.3 | 25.8 | 144
12 | 6.3 | 25.3 | 4.9 | 27.2 | 32 | 4.9 | 26.2 | 65 | 5.4 | 26.2 | 145
13 | 4.8 | 26.3 | 5.1 | 28.2 | 32 | 4.7 | 26.7 | 62 | 5.3 | 26.8 | 138
14 | 6.4 | 26.4 | 5.2 | 28.5 | 32 | 4.8 | 26.9 | 62 | 5.0 | 26.8 | 131
15 | 5.6 | 26.6 | 5.5 | 29.0 | 33 | 4.9 | 27.8 | 61 | 5.4 | 27.9 | 136
16 | 4.9 | 27.6 | 5.9 | 29.5 | 35 | 4.9 | 28.0 | 61 | 5.8 | 28.1 | 144
17 | 5.3 | 27.0 | 5.6 | 29.1 | 34 | 4.8 | 27.8 | 61 | 5.4 | 28.2 | 135
18 | 6.2 | 27.5 | 6.0 | 30.4 | 34 | 4.7 | 27.8 | 60 | 5.5 | 28.4 | 137
19 | 5.5 | 27.9 | 5.5 | 30.5 | 32 | 4.9 | 29.0 | 59 | 5.5 | 28.6 | 135
20 | 5.3 | 29.3 | 5.0 | 31.0 | 28 | 4.7 | 29.8 | 55 | 5.1 | 29.5 | 120
21 | 5.7 | 29.2 | 4.8 | 31.6 | 26 | 5.1 | 29.9 | 60 | 5.3 | 30.1 | 124
22 | 4.8 | 29.5 | 5.0 | 31.9 | 27 | 4.8 | 30.7 | 54 | 5.0 | 30.7 | 115
23 | 4.8 | 29.9 | 5.1 | 33.1 | 27 | 4.4 | 31.8 | 49 | 5.4 | 31.2 | 120
24 | 4.8 | 30.2 | 5.3 | 33.9 | 28 | 5.1 | 32.1 | 55 | 5.2 | 32.5 | 112
25 | 5.0 | 28.5 | 5.0 | 34.6 | 25 | 4.9 | 33.5 | 51 | 5.3 | 32.9 | 113
26 | 4.9 | 29.9 | 5.2 | 34.9 | 26 | 5.0 | 33.9 | 52 | 5.2 | 33.2 | 109
Mean for Weeks
1–13 | 5.9 | 23.8 | 4.4 | 24.1 | 32 | 4.3 | 23.5 | 64 | 4.5 | 23.6 | 133
14–26 | 5.3 | 28.4 | 5.3 | 31.4 | 30 | 4.8 | 29.9 | 57 | 5.3 | 29.8 | 126

a Grams of water consumed per animal per day

b Milligrams of bromodichloromethane consumed per kilogram body weight per day

TABLE J3 Water and Compound Consumption by Male Tg.AC Hemizygous Mice in the 42-Week Drinking Water Study of Bromodichloromethane

Week | 0 mg/L | | 175 mg/L | | | 350 mg/L | | | 700 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg) | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg)
1 | 8.7 | 22.4 | 2.4 | 22.7 | 18 | 1.0 | 23.2 | 15 | 0.8 | 22.8 | 24
2 | 5.5 | 23.7 | 2.9 | 24.0 | 21 | 2.5 | 23.3 | 37 | 1.9 | 20.6 | 66
3 | 7.4 | 25.0 | 2.9 | 26.1 | 19 | 2.8 | 25.0 | 39 | 2.0 | 23.8 | 60
4 | 5.7 | 25.6 | 3.3 | 27.5 | 21 | 2.9 | 26.5 | 38 | 2.6 | 25.6 | 71
5 | 5.0 | 27.2 | 3.1 | 28.6 | 19 | 2.7 | 27.6 | 35 | 2.5 | 26.3 | 68
6 | 4.7 | 27.9 | 3.1 | 29.1 | 19 | 2.8 | 28.5 | 34 | 2.6 | 27.0 | 67
7 | 4.2 | 28.5 | 3.2 | 29.4 | 19 | 2.9 | 28.7 | 36 | 2.4 | 27.6 | 61
8 | 4.1 | 28.1 | 3.6 | 30.6 | 20 | 3.1 | 29.5 | 37 | 2.7 | 27.4 | 69
9 | 3.0 | 28.7 | 3.9 | 32.0 | 21 | 3.1 | 30.8 | 35 | 3.0 | 28.7 | 72
10 | 4.6 | 29.4 | 3.4 | 33.1 | 18 | 3.1 | 31.8 | 34 | 2.9 | 29.5 | 68
11 | 4.3 | 30.8 | 3.6 | 33.5 | 19 | 3.1 | 32.5 | 34 | 2.7 | 30.5 | 63
12 | 4.2 | 31.2 | 3.4 | 34.0 | 18 | 3.3 | 33.0 | 35 | 3.1 | 31.3 | 70
13 | 4.3 | 31.4 | 3.4 | 33.9 | 17 | 3.3 | 33.1 | 35 | 3.0 | 30.4 | 68
14 | 3.4 | 31.7 | 3.8 | 34.7 | 19 | 3.1 | 33.1 | 33 | 3.2 | 30.7 | 74
15 | 4.0 | 31.6 | 4.2 | 34.6 | 21 | 3.5 | 33.6 | 37 | 3.1 | 31.0 | 70
16 | 4.8 | 32.4 | 4.0 | 35.2 | 20 | 3.2 | 34.3 | 33 | 3.3 | 31.9 | 72
17 | 4.7 | 32.2 | 4.2 | 35.5 | 20 | 3.3 | 34.5 | 33 | 3.6 | 32.5 | 78
18 | 5.1 | 32.5 | 3.8 | 36.0 | 19 | 3.6 | 35.2 | 35 | 3.4 | 32.3 | 73
19 | 4.5 | 33.4 | 3.3 | 36.3 | 16 | 3.3 | 35.6 | 32 | 3.3 | 33.2 | 69
20 | 5.4 | 34.2 | 3.5 | 39.1 | 16 | 3.3 | 37.0 | 31 | 2.9 | 34.3 | 60
21 | 4.3 | 35.1 | 3.5 | 39.2 | 16 | 3.4 | 36.8 | 32 | 2.8 | 33.0 | 60
22 | 4.9 | 35.3 | 3.8 | 40.2 | 16 | 3.7 | 37.5 | 34 | 3.1 | 35.1 | 62
23 | 5.5 | 36.3 | 3.8 | 40.5 | 16 | 3.8 | 37.2 | 35 | 3.0 | 35.2 | 59
24 | 5.2 | 36.6 | 3.7 | 41.6 | 16 | 3.5 | 37.9 | 32 | 2.9 | 36.0 | 56
25 | 3.7 | 36.7 | 3.5 | 42.0 | 15 | 3.5 | 37.0 | 33 | 3.2 | 36.2 | 61
26 | 5.0 | 36.9 | 3.8 | 42.2 | 16 | 3.2 | 38.6 | 29 | 3.1 | 36.7 | 58
27 | 4.1 | 36.9 | 3.6 | 42.2 | 15 | 3.5 | 39.4 | 31 | 3.2 | 35.4 | 63
28 | 4.4 | 37.6 | 3.8 | 42.4 | 16 | 3.4 | 40.2 | 30 | 3.5 | 35.0 | 70
29 | 5.4 | 37.5 | 3.7 | 42.9 | 15 | 3.6 | 39.8 | 31 | 3.5 | 35.1 | 69
30 | 5.0 | 37.5 | 4.1 | 42.6 | 17 | 4.0 | 40.2 | 35 | 3.6 | 36.3 | 69
31 | 5.2 | 37.6 | 4.0 | 42.8 | 16 | 3.7 | 40.6 | 32 | 3.0 | 36.6 | 57
32 | 3.7 | 37.0 | 3.9 | 43.1 | 16 | 3.6 | 40.4 | 31 | 3.2 | 37.1 | 61
33 | 5.0 | 38.9 | 4.0 | 42.8 | 16 | 3.5 | 40.0 | 30 | 3.2 | 37.5 | 59
34 | 3.9 | 37.6 | 3.6 | 42.2 | 15 | 3.2 | 40.5 | 28 | 3.1 | 37.1 | 58
35 | 4.2 | 37.2 | 3.9 | 40.7 | 17 | 3.4 | 40.3 | 29 | 3.2 | 36.8 | 61
36 | 4.0 | 35.8 | 3.9 | 40.5 | 17 | 3.3 | 39.5 | 29 | 3.6 | 37.3 | 67
37 | 4.5 | 37.2 | 3.8 | 41.3 | 16 | 3.6 | 38.8 | 32 | 3.4 | 37.5 | 63
38 | 4.7 | 38.2 | 3.9 | 41.6 | 16 | 3.2 | 39.1 | 28 | 3.4 | 37.9 | 62
39 | 4.1 | 38.9 | 3.8 | 41.8 | 16 | 3.1 | 39.3 | 27 | 3.0 | 38.3 | 56
40 | 4.2 | 39.9 | 3.8 | 42.0 | 16 | 3.4 | 39.1 | 30 | 2.9 | 38.1 | 53
41 | 4.1 | 41.7 | 4.0 | 40.8 | 17 | 3.4 | 38.5 | 31 | 3.4 | 37.8 | 63
42 | 4.0 | 42.4 | 4.1 | 41.8 | 17 | 3.2 | 39.1 | 29 | 3.2 | 38.3 | 58
Mean for Weeks
1–13 | 5.0 | 27.7 | 3.2 | 29.6 | 19 | 2.8 | 28.7 | 34 | 2.5 | 27.0 | 64
14–42 | 4.5 | 36.4 | 3.8 | 40.3 | 17 | 3.4 | 38.0 | 32 | 3.2 | 35.5 | 64

a Grams of water consumed per animal per day

b Milligrams of bromodichloromethane consumed per kilogram body weight per day

TABLE J4 Water and Compound Consumption by Female Tg.AC Hemizygous Mice in the 42-Week Drinking Water Study of Bromodichloromethane

Week | 0 mg/L | | 175 mg/L | | | 350 mg/L | | | 700 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg) | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg)
1 | | | 2.3 | 19.1 | 21 | 1.4 | 18.9 | 26 | 0.9 | 19.3 | 32
2 | 6.6 | 20.0 | 3.8 | 20.6 | 32 | 3.3 | 20.0 | 58 | 2.6 | 18.8 | 98
3 | 8.9 | 21.2 | 4.5 | 22.2 | 35 | 4.5 | 21.6 | 73 | 3.6 | 20.8 | 121
4 | 6.0 | 22.0 | 4.5 | 22.9 | 34 | 4.1 | 22.4 | 64 | 4.3 | 21.9 | 137
5 | 4.5 | 23.3 | 4.4 | 23.7 | 33 | 4.2 | 23.1 | 64 | 4.0 | 23.2 | 122
6 | | | 4.3 | 24.0 | 32 | 4.6 | 23.8 | 67 | 4.7 | 23.1 | 142
7 | 6.2 | 24.2 | 4.6 | 23.8 | 34 | 4.5 | 23.4 | 68 | 4.4 | 23.3 | 132
8 | 6.8 | 24.8 | 5.0 | 25.1 | 35 | 5.0 | 24.1 | 72 | 5.2 | 24.5 | 149
9 | 5.4 | 25.2 | 5.4 | 25.9 | 37 | 4.0 | 24.7 | 57 | 5.2 | 24.8 | 147
10 | 5.3 | 26.4 | 5.4 | 26.1 | 36 | 5.0 | 25.4 | 69 | 5.1 | 24.8 | 143
11 | 6.8 | 26.9 | 5.0 | 27.0 | 33 | 4.8 | 26.5 | 63 | 6.1 | 25.8 | 166
12 | 6.0 | 26.7 | 5.5 | 26.2 | 36 | 4.6 | 26.2 | 61 | 5.7 | 26.5 | 152
13 | 5.0 | 27.3 | 5.1 | 26.7 | 34 | 4.1 | 26.2 | 55 | 5.2 | 26.8 | 136
14 | 4.8 | 27.8 | 4.7 | 27.1 | 30 | 4.4 | 27.1 | 57 | 5.1 | 26.7 | 134
15 | 5.1 | 28.1 | 4.7 | 27.3 | 30 | 4.9 | 27.9 | 61 | 5.1 | 27.4 | 130
16 | 4.1 | 28.9 | 4.6 | 27.6 | 29 | 4.3 | 28.4 | 54 | 4.8 | 27.6 | 122
17 | 5.7 | 28.5 | 4.9 | 27.9 | 30 | 4.8 | 29.2 | 57 | 4.8 | 27.4 | 123
18 | 5.1 | 28.2 | 5.0 | 28.6 | 30 | 5.0 | 29.4 | 60 | 5.1 | 27.8 | 128
19 | 4.3 | 29.3 | 4.8 | 29.0 | 29 | 5.1 | 30.4 | 58 | 4.4 | 29.2 | 105
20 | 4.8 | 29.9 | 4.7 | 29.8 | 28 | 4.1 | 31.4 | 45 | 4.6 | 29.6 | 109
21 | 5.2 | 30.3 | 4.8 | 29.5 | 29 | 4.9 | 30.6 | 56 | 4.8 | 30.5 | 111
22 | 5.5 | 30.2 | 4.9 | 30.3 | 28 | 4.9 | 32.0 | 54 | 4.6 | 31.7 | 102
23 | 5.8 | 31.3 | 4.6 | 30.2 | 27 | 4.7 | 33.1 | 49 | 4.2 | 32.6 | 91
24 | 6.2 | 30.4 | 4.3 | 30.9 | 24 | 4.3 | 33.9 | 45 | 4.8 | 33.4 | 101
25 | 5.1 | 31.5 | 4.8 | 32.7 | 26 | 4.5 | 35.0 | 45 | 4.1 | 33.7 | 86
26 | 5.6 | 31.8 | 4.5 | 33.6 | 24 | 4.4 | 35.8 | 43 | 4.5 | 33.9 | 93
27 | 4.9 | 31.5 | 4.7 | 33.9 | 24 | 4.0 | 37.2 | 38 | 4.6 | 35.0 | 93
28 | 5.3 | 31.3 | 4.3 | 34.0 | 22 | 3.5 | 37.5 | 33 | 4.6 | 34.8 | 93
29 | 5.4 | 32.7 | 4.6 | 34.2 | 24 | 3.6 | 37.9 | 34 | 4.8 | 35.1 | 95
30 | 5.5 | 32.9 | 4.3 | 34.6 | 22 | 4.1 | 38.1 | 38 | 4.2 | 33.2 | 89
31 | 5.2 | 32.6 | 4.6 | 34.0 | 23 | 4.0 | 38.3 | 37 | 3.9 | 33.1 | 83
32 | 4.5 | 32.9 | 4.7 | 32.2 | 26 | 3.6 | 36.6 | 34 | 4.9 | 32.9 | 105
33 | 4.5 | 32.9 | 5.3 | 32.0 | 29 | 3.7 | 37.7 | 34 | 4.4 | 32.9 | 93
34 | 5.9 | 33.2 | 4.9 | 33.3 | 26 | 3.8 | 36.6 | 37 | 4.4 | 33.3 | 93
35 | 4.9 | 33.5 | 4.8 | 33.7 | 25 | 4.2 | 38.3 | 39 | 5.4 | 32.3 | 117
36 | 5.5 | 32.7 | 5.3 | 34.0 | 27 | 4.6 | 39.2 | 41 | 5.1 | 33.0 | 108
37 | 5.0 | 33.3 | 5.2 | 32.8 | 28 | 4.5 | 41.0 | 38 | 4.8 | 33.2 | 101
38 | 5.6 | 34.8 | 5.3 | 33.5 | 28 | 4.5 | 42.3 | 38 | 5.0 | 32.8 | 107
39 | 6.1 | 35.3 | 5.1 | 34.2 | 26 | 4.9 | 42.7 | 40 | 4.4 | 33.2 | 93
40 | 5.6 | 35.7 | 5.0 | 34.8 | 25 | 4.7 | 41.9 | 39 | 4.1 | 36.5 | 79
41 | 6.1 | 36.6 | 5.0 | 34.9 | 25 | 4.9 | 41.2 | 42 | 4.5 | 35.8 | 88
42 | 6.4 | 35.7 | 4.8 | 35.8 | 24 | 4.7 | 42.8 | 38 | 5.4 | 34.9 | 108
Mean for Weeks
1–13 | 6.1 | 24.4 | 4.6 | 24.1 | 33 | 4.2 | 23.6 | 61 | 4.4 | 23.3 | 129
14–42 | 5.3 | 31.8 | 4.8 | 31.9 | 26 | 4.4 | 35.6 | 44 | 4.7 | 32.2 | 103

a Grams of water consumed per animal per day

b Milligrams of bromodichloromethane consumed per kilogram body weight per day

TABLE J5 Water and Compound Consumption by Male p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Bromodichloromethane

Week | 0 mg/L | | 175 mg/L | | | 350 mg/L | | | 700 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg) | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg)
1 | 3.7 | 22.8 | 2.2 | 23.0 | 17 | 1.4 | 22.9 | 21 | 1.2 | 22.5 | 37
2 | 3.7 | 24.2 | 2.9 | 23.7 | 21 | 2.5 | 21.8 | 41 | 2.2 | 20.1 | 76
3 | 3.6 | 25.6 | 3.1 | 25.0 | 22 | 2.5 | 24.2 | 36 | 2.5 | 22.0 | 81
4 | 3.4 | 26.7 | 2.9 | 26.2 | 20 | 2.5 | 25.2 | 35 | 2.3 | 24.1 | 68
5 | 3.6 | 27.9 | 3.0 | 26.9 | 20 | 2.7 | 26.4 | 36 | 2.4 | 24.8 | 69
6 | 3.3 | 28.3 | 2.9 | 28.1 | 18 | 2.7 | 26.9 | 35 | 2.4 | 24.8 | 69
7 | 3.7 | 30.2 | 3.1 | 28.5 | 19 | 2.8 | 27.4 | 35 | 2.7 | 25.2 | 74
8 | 4.0 | 31.1 | 3.3 | 30.3 | 19 | 2.9 | 28.3 | 36 | 2.6 | 26.0 | 71
9 | 3.7 | 33.0 | 3.1 | 32.1 | 17 | 2.8 | 29.7 | 33 | 2.6 | 27.2 | 67
10 | 4.0 | 34.7 | 3.2 | 33.5 | 17 | 3.0 | 30.7 | 34 | 2.8 | 27.9 | 70
11 | 3.7 | 36.1 | 3.2 | 35.2 | 16 | 2.9 | 32.1 | 32 | 3.1 | 27.9 | 77
12 | 3.7 | 37.0 | 3.1 | 36.3 | 15 | 2.7 | 33.1 | 28 | 2.9 | 29.0 | 70
13 | 3.9 | 38.4 | 3.2 | 37.3 | 15 | 2.9 | 33.3 | 30 | 2.9 | 29.6 | 68
14 | 4.0 | 38.9 | 3.2 | 38.3 | 15 | 2.9 | 34.2 | 30 | 2.8 | 30.1 | 65
15 | 4.0 | 39.8 | 3.2 | 38.9 | 14 | 2.9 | 35.2 | 29 | 2.8 | 30.8 | 64
16 | 3.8 | 40.8 | 3.2 | 39.2 | 14 | 2.7 | 36.1 | 27 | 2.8 | 31.2 | 62
17 | 4.1 | 42.0 | 3.3 | 40.6 | 14 | 3.0 | 37.1 | 28 | 2.8 | 32.1 | 62
18 | 4.0 | 42.9 | 3.4 | 40.8 | 15 | 3.1 | 37.5 | 29 | 2.9 | 33.0 | 62
19 | 3.9 | 43.4 | 3.1 | 42.0 | 13 | 3.0 | 37.6 | 28 | 2.9 | 33.3 | 61
20 | 3.9 | 43.8 | 3.2 | 43.0 | 13 | 3.1 | 38.8 | 28 | 2.8 | 33.9 | 58
21 | 4.1 | 45.1 | 3.2 | 43.7 | 13 | 3.1 | 39.4 | 28 | 3.0 | 34.7 | 61
22 | 4.0 | 45.9 | 3.4 | 44.2 | 13 | 3.6 | 39.6 | 31 | 3.0 | 34.8 | 61
23 | 4.0 | 46.4 | 3.2 | 45.0 | 12 | 3.0 | 41.0 | 26 | 3.0 | 35.1 | 61
24 | 4.0 | 47.1 | 2.9 | 45.6 | 11 | 2.9 | 41.1 | 25 | 2.8 | 36.9 | 53
25 | 3.9 | 47.4 | 3.3 | 45.2 | 13 | 3.0 | 41.5 | 26 | 3.1 | 36.0 | 61
26 | 4.1 | 47.8 | 3.3 | 46.3 | 12 | 3.1 | 42.7 | 26 | 3.1 | 36.5 | 59
Mean for Weeks
1–13 | 3.7 | 30.5 | 3.0 | 29.7 | 18 | 2.6 | 27.9 | 33 | 2.5 | 25.5 | 69
14–26 | 4.0 | 43.9 | 3.2 | 42.5 | 13 | 3.0 | 38.6 | 28 | 2.9 | 33.7 | 61

a Grams of water consumed per animal per day

b Milligrams of bromodichloromethane consumed per kilogram body weight per day

TABLE J6 Water and Compound Consumption by Female p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Bromodichloromethane

Week | 0 mg/L | | 175 mg/L | | | 350 mg/L | | | 700 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg) | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg)
1 | 4.1 | 18.9 | 2.3 | 18.9 | 22 | 1.6 | 18.8 | 30 | 1.4 | 18.6 | 54
2 | 4.1 | 19.6 | 2.9 | 19.6 | 26 | 2.8 | 19.3 | 51 | 2.7 | 19.1 | 98
3 | 4.3 | 20.8 | 3.6 | 20.2 | 31 | 3.2 | 20.0 | 56 | 3.1 | 20.0 | 107
4 | 3.8 | 21.8 | 3.5 | 21.4 | 28 | 3.6 | 21.4 | 59 | 3.3 | 21.1 | 110
5 | 4.1 | 22.1 | 3.5 | 21.9 | 28 | 3.7 | 21.9 | 59 | 3.8 | 22.0 | 120
6 | 4.1 | 22.0 | 3.6 | 21.9 | 29 | 3.7 | 22.4 | 58 | 3.7 | 22.3 | 117
7 | 4.2 | 22.3 | 4.0 | 22.1 | 31 | 4.0 | 21.8 | 65 | 3.9 | 21.9 | 126
8 | 4.1 | 23.3 | 3.8 | 22.5 | 29 | 3.9 | 23.2 | 59 | 3.6 | 22.7 | 112
9 | 4.2 | 23.6 | 3.7 | 23.0 | 28 | 3.7 | 23.5 | 55 | 3.9 | 22.4 | 121
10 | 4.1 | 24.6 | 3.8 | 23.7 | 28 | 3.8 | 24.3 | 55 | 3.8 | 24.1 | 112
11 | 4.1 | 24.7 | 3.8 | 24.4 | 27 | 3.8 | 24.6 | 54 | 3.6 | 24.1 | 105
12 | 4.2 | 25.3 | 3.8 | 24.5 | 27 | 3.9 | 25.2 | 54 | 3.7 | 24.6 | 104
13 | 3.9 | 26.5 | 3.7 | 25.2 | 26 | 3.7 | 25.8 | 50 | 3.6 | 24.9 | 101
14 | 4.1 | 27.1 | 3.8 | 26.0 | 25 | 3.8 | 27.0 | 50 | 3.5 | 25.9 | 96
15 | 4.1 | 27.9 | 3.8 | 26.4 | 25 | 3.8 | 27.3 | 48 | 3.7 | 26.3 | 98
16 | 4.2 | 29.0 | 4.0 | 26.4 | 27 | 3.9 | 27.8 | 50 | 3.7 | 26.9 | 97
17 | 4.3 | 28.7 | 4.0 | 26.8 | 26 | 4.1 | 28.3 | 51 | 3.9 | 28.4 | 96
18 | 4.4 | 29.1 | 4.2 | 27.6 | 27 | 4.1 | 28.7 | 50 | 4.0 | 27.6 | 100
19 | 4.3 | 29.8 | 4.0 | 28.1 | 25 | 4.0 | 29.2 | 48 | 3.9 | 27.5 | 99
20 | 4.3 | 30.6 | 4.1 | 29.1 | 25 | 3.9 | 29.4 | 46 | 4.0 | 28.3 | 98
21 | 4.3 | 31.5 | 3.9 | 29.7 | 23 | 4.0 | 30.4 | 46 | 3.9 | 29.2 | 95
22 | 4.4 | 32.7 | 4.2 | 30.8 | 24 | 4.3 | 30.9 | 49 | 4.0 | 30.0 | 92
23 | 4.3 | 34.0 | 3.9 | 32.2 | 21 | 3.8 | 32.9 | 41 | 4.0 | 30.4 | 92
24 | 4.1 | 35.3 | 3.5 | 32.1 | 19 | 3.4 | 33.2 | 36 | 3.7 | 30.8 | 83
25 | 4.3 | 35.6 | 4.3 | 32.1 | 23 | 4.1 | 32.6 | 44 | 3.9 | 31.3 | 88
26 | 4.3 | 36.4 | 4.1 | 33.2 | 21 | 3.9 | 34.0 | 40 | 3.9 | 31.7 | 85
Mean for Weeks
1–13 | 4.1 | 22.7 | 3.5 | 22.2 | 28 | 3.5 | 22.5 | 54 | 3.4 | 22.1 | 107
14–26 | 4.3 | 31.4 | 4.0 | 29.3 | 24 | 3.9 | 30.1 | 46 | 3.8 | 28.8 | 94

a Grams of water consumed per animal per day

b Milligrams of bromodichloromethane consumed per kilogram body weight per day

TABLE J7 Water and Compound Consumption by Male p53 Haploinsufficient Mice in the 42-Week Drinking Water Study of Bromodichloromethane

Week | 0 mg/L | | 175 mg/L | | | 350 mg/L | | | 700 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg) | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg)
1 | 3.5 | 23.0 | 1.8 | 22.5 | 14 | 2.2 | 23.0 | 34 | 0.9 | 22.8 | 28
2 | 3.5 | 23.8 | 2.8 | 23.3 | 21 | 2.7 | 23.0 | 40 | 2.2 | 20.3 | 74
3 | 3.2 | 24.8 | 2.7 | 24.2 | 20 | 2.6 | 24.1 | 38 | 2.2 | 22.8 | 67
4 | 3.3 | 25.5 | 2.8 | 25.4 | 20 | 2.7 | 25.5 | 38 | 2.3 | 24.3 | 66
5 | 3.3 | 26.3 | 2.9 | 26.5 | 19 | 2.7 | 26.0 | 36 | 2.2 | 24.6 | 64
6 | 2.3 | 27.2 | 2.1 | 27.5 | 14 | 2.0 | 26.4 | 26 | 1.7 | 25.0 | 48
7 | 3.4 | 29.1 | 3.0 | 28.9 | 18 | 2.8 | 27.4 | 35 | 2.6 | 25.7 | 72
8 | 3.7 | 29.4 | 3.2 | 29.8 | 19 | 3.2 | 28.2 | 39 | 2.7 | 27.1 | 70
9 | 3.6 | 31.7 | 3.0 | 31.0 | 17 | 3.0 | 28.9 | 37 | 2.5 | 28.2 | 63
10 | 3.7 | 33.5 | 3.2 | 32.3 | 17 | 3.1 | 30.8 | 35 | 2.8 | 29.5 | 66
11 | 3.7 | 34.6 | 3.1 | 32.7 | 17 | 3.1 | 30.9 | 35 | 2.6 | 30.3 | 59
12 | 3.6 | 35.7 | 2.9 | 34.8 | 15 | 3.1 | 32.4 | 33 | 2.6 | 31.7 | 57
13 | 3.6 | 36.8 | 3.3 | 35.1 | 16 | 3.0 | 33.5 | 32 | 2.7 | 31.3 | 60
14 | 3.7 | 37.4 | 3.0 | 36.2 | 15 | 3.0 | 33.9 | 31 | 2.7 | 31.8 | 59
15 | 3.9 | 38.2 | 3.0 | 37.0 | 14 | 3.1 | 34.8 | 31 | 2.6 | 32.9 | 56
16 | 4.0 | 39.3 | 3.0 | 38.0 | 14 | 3.2 | 35.6 | 31 | 2.7 | 33.5 | 57
17 | 4.0 | 40.5 | 3.3 | 39.8 | 15 | 3.3 | 37.0 | 31 | 3.0 | 34.4 | 61
18 | 4.0 | 41.5 | 3.1 | 40.2 | 13 | 3.3 | 38.0 | 31 | 3.3 | 34.5 | 67
19 | 4.0 | 41.3 | 3.2 | 41.3 | 14 | 3.2 | 38.3 | 30 | 2.8 | 35.7 | 56
20 | 4.3 | 41.5 | 3.2 | 41.8 | 13 | 3.2 | 38.9 | 28 | 2.9 | 36.6 | 56
21 | 4.0 | 43.0 | 3.1 | 42.3 | 13 | 3.2 | 39.1 | 29 | 2.7 | 37.2 | 51
22 | 4.4 | 43.7 | 3.1 | 43.5 | 13 | 3.3 | 40.2 | 29 | 2.9 | 36.6 | 56
23 | 4.3 | 44.9 | 3.1 | 43.9 | 12 | 3.1 | 41.5 | 26 | 3.1 | 37.1 | 58
24 | 4.1 | 45.8 | 2.8 | 44.5 | 11 | 3.1 | 41.6 | 26 | 2.6 | 37.6 | 49
25 | 4.0 | 46.0 | 3.1 | 44.6 | 12 | 3.4 | 40.7 | 29 | 2.9 | 36.4 | 56
26 | 4.1 | 46.8 | 3.2 | 44.3 | 13 | 3.2 | 41.1 | 27 | 2.8 | 39.7 | 50
27 | 4.4 | 47.4 | 3.2 | 45.4 | 12 | 3.4 | 41.5 | 29 | 3.0 | 40.4 | 53
28 | 4.2 | 47.9 | 3.2 | 45.8 | 12 | 3.4 | 42.5 | 28 | 3.2 | 39.6 | 57
29 | 4.3 | 48.2 | 3.1 | 46.3 | 12 | 3.4 | 42.9 | 28 | 3.4 | 41.0 | 58
30 | 3.9 | 48.3 | 3.0 | 46.4 | 11 | 3.2 | 41.6 | 26 | 2.8 | 41.4 | 47
31 | 4.7 | 47.2 | 3.4 | 46.2 | 13 | 3.4 | 42.6 | 28 | 3.1 | 40.9 | 52
32 | 4.4 | 47.0 | 3.2 | 46.7 | 12 | 3.4 | 44.3 | 26 | 2.9 | 42.4 | 47
33 | 5.0 | 49.1 | 3.4 | 47.5 | 12 | 3.4 | 44.1 | 27 | 2.9 | 43.0 | 48
34 | 4.6 | 49.8 | 3.4 | 47.7 | 13 | 3.4 | 44.9 | 27 | 3.2 | 44.1 | 50
35 | 4.6 | 50.1 | 3.3 | 47.7 | 12 | 3.5 | 45.3 | 27 | 3.0 | 43.4 | 49
36 | 4.8 | 49.9 | 3.5 | 48.3 | 13 | 3.7 | 45.4 | 29 | 2.9 | 43.0 | 48
37 | 4.9 | 49.7 | 3.2 | 47.2 | 12 | 3.5 | 45.5 | 27 | 2.9 | 44.5 | 45
38 | 4.9 | 50.3 | 3.5 | 48.7 | 12 | 3.7 | 46.5 | 28 | 3.1 | 45.0 | 48
39 | 4.7 | 50.9 | 3.6 | 48.2 | 13 | 3.6 | 46.7 | 27 | 3.4 | 44.5 | 53
40 | 4.6 | 51.0 | 3.3 | 48.5 | 12 | 3.5 | 45.8 | 27 | 3.4 | 44.3 | 53
41 | 4.7 | 51.3 | 3.5 | 48.8 | 12 | 3.5 | 46.1 | 27 | 3.5 | 44.3 | 55
42 | 4.6 | 51.6 | 3.3 | 49.1 | 12 | 3.6 | 45.6 | 28 | 3.4 | 43.7 | 54
Mean for Weeks
1–13 | 3.4 | 29.3 | 2.8 | 28.8 | 17 | 2.8 | 27.7 | 35 | 2.3 | 26.4 | 61
14–42 | 4.4 | 46.2 | 3.2 | 44.7 | 13 | 3.3 | 41.8 | 28 | 3.0 | 39.6 | 53

a Grams of water consumed per animal per day

b Milligrams of bromodichloromethane consumed per kilogram body weight per day

TABLE J8 Water and Compound Consumption by Female p53 Haploinsufficient Mice in the 42-Week Drinking Water Study of Bromodichloromethane

Week | 0 mg/L | | 175 mg/L | | | 350 mg/L | | | 700 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg) | Water (g/day) | Body Weight (g) | Dose/Day (mg/kg)
1 | 3.6 | 18.8 | 1.9 | 18.7 | 18 | 1.4 | 18.4 | 26 | 1.8 | 19.1 | 66
2 | 3.7 | 19.5 | 2.8 | 19.6 | 25 | 3.2 | 18.7 | 59 | 3.0 | 19.4 | 108
3 | 3.7 | 20.0 | 3.1 | 20.5 | 26 | 3.1 | 19.5 | 55 | 3.1 | 19.6 | 109
4 | 3.6 | 21.0 | 3.2 | 21.4 | 26 | 3.4 | 20.7 | 57 | 3.3 | 21.5 | 108
5 | 4.0 | 21.3 | 3.6 | 21.5 | 29 | 3.8 | 21.0 | 63 | 3.7 | 21.7 | 120
6 | 2.9 | 22.2 | 2.3 | 22.4 | 18 | 2.7 | 22.0 | 43 | 2.9 | 22.7 | 89
7 | 4.1 | 22.5 | 3.7 | 22.8 | 29 | 3.8 | 21.8 | 61 | 4.3 | 23.1 | 130
8 | 4.2 | 23.0 | 3.8 | 23.5 | 28 | 3.8 | 22.8 | 58 | 4.0 | 23.5 | 118
9 | 3.8 | 23.7 | 3.9 | 23.6 | 29 | 3.7 | 23.3 | 56 | 4.1 | 23.9 | 121
10 | 4.0 | 24.2 | 4.0 | 24.4 | 28 | 3.7 | 23.9 | 54 | 4.1 | 24.9 | 116
11 | 4.2 | 24.0 | 3.7 | 25.1 | 26 | 3.5 | 24.0 | 52 | 4.0 | 24.6 | 113
12 | 4.4 | 23.9 | 3.7 | 25.9 | 25 | 3.7 | 24.3 | 54 | 4.3 | 24.8 | 123
13 | 4.3 | 24.9 | 3.7 | 26.5 | 25 | 3.6 | 25.3 | 50 | 4.2 | 25.3 | 115
14 | 5.0 | 25.6 | 3.8 | 26.9 | 25 | 3.8 | 25.6 | 52 | 4.3 | 26.1 | 116
15 | 4.3 | 25.6 | 3.8 | 27.1 | 24 | 3.7 | 25.6 | 51 | 4.1 | 26.1 | 111
16 | 4.6 | 25.8 | 3.8 | 27.2 | 24 | 3.8 | 26.5 | 50 | 4.3 | 26.4 | 114
17 | 4.7 | 27.0 | 4.2 | 28.4 | 26 | 3.8 | 27.4 | 48 | 4.5 | 27.3 | 116
18 | 4.7 | 27.6 | 3.8 | 29.0 | 23 | 3.8 | 27.8 | 48 | 4.4 | 28.3 | 109
19 | 4.9 | 27.9 | 4.1 | 29.4 | 24 | 3.7 | 28.0 | 46 | 4.4 | 28.9 | 107
20 | 4.5 | 28.7 | 4.1 | 30.6 | 23 | 3.7 | 28.7 | 45 | 4.4 | 28.7 | 107
21 | 4.4 | 28.7 | 4.0 | 30.0 | 23 | 3.8 | 28.4 | 47 | 4.5 | 28.3 | 112
22 | 4.4 | 29.5 | 4.2 | 31.0 | 24 | 3.9 | 29.6 | 46 | 4.4 | 30.0 | 104
23 | 4.5 | 30.4 | 3.9 | 32.1 | 21 | 3.7 | 30.8 | 42 | 4.4 | 31.0 | 100
24 | 4.0 | 30.8 | 3.4 | 32.5 | 18 | 3.7 | 31.2 | 42 | 4.1 | 32.1 | 90
25 | 4.3 | 31.5 | 4.0 | 32.0 | 22 | 3.8 | 30.9 | 43 | 4.5 | 32.0 | 99
26 | 4.3 | 32.1 | 3.8 | 31.9 | 21 | 3.6 | 32.3 | 39 | 4.2 | 32.3 | 91
27 | 4.8 | 32.9 | 4.0 | 31.6 | 22 | 3.7 | 32.8 | 40 | 4.4 | 33.6 | 92
28 | 4.5 | 34.0 | 3.9 | 34.3 | 20 | 3.7 | 33.8 | 38 | 4.3 | 35.3 | 85
29 | 4.6 | 35.3 | 4.1 | 35.3 | 20 | 3.7 | 35.3 | 37 | 4.3 | 35.2 | 86
30 | 4.5 | 36.3 | 3.8 | 36.3 | 18 | 3.5 | 36.5 | 34 | 3.8 | 36.9 | 72
31 | 4.5 | 35.4 | 4.1 | 36.1 | 20 | 3.7 | 36.4 | 36 | 4.2 | 34.5 | 86
32 | 4.8 | 37.0 | 4.0 | 37.3 | 19 | 3.5 | 36.6 | 33 | 4.6 | 34.4 | 95
33 | 4.8 | 37.8 | 4.0 | 37.8 | 18 | 3.7 | 37.4 | 35 | 5.0 | 36.0 | 96
34 | 5.1 | 38.3 | 4.1 | 39.3 | 18 | 3.7 | 39.1 | 33 | 4.5 | 38.6 | 82
35 | 5.3 | 39.0 | 4.0 | 39.7 | 18 | 3.7 | 38.9 | 33 | 4.4 | 39.3 | 78
36 | 5.0 | 39.7 | 3.9 | 40.4 | 17 | 3.8 | 38.9 | 34 | 4.3 | 39.9 | 76
37 | 5.3 | 39.4 | 4.0 | 40.8 | 17 | 3.7 | 38.9 | 34 | 4.2 | 39.5 | 74
38 | 5.6 | 40.8 | 4.1 | 41.4 | 17 | 3.7 | 40.2 | 32 | 4.2 | 39.4 | 75
39 | 5.0 | 41.5 | 3.8 | 42.3 | 16 | 3.8 | 41.2 | 32 | 4.2 | 40.0 | 73
40 | 4.8 | 42.4 | 3.6 | 43.5 | 15 | 3.6 | 41.2 | 30 | 4.2 | 39.7 | 73
41 | 5.1 | 43.6 | 3.9 | 44.2 | 16 | 3.9 | 42.5 | 32 | 4.6 | 39.9 | 80
42 | 4.4 | 44.5 | 3.6 | 43.6 | 15 | 3.7 | 43.9 | 29 | 4.3 | 40.4 | 74
Mean for Weeks
1–13 | 3.9 | 22.2 | 3.3 | 22.8 | 25 | 3.3 | 22.0 | 53 | 3.6 | 22.6 | 110
14–42 | 4.7 | 34.1 | 3.9 | 34.9 | 20 | 3.7 | 34.0 | 39 | 4.4 | 33.8 | 92

a Grams of water consumed per animal per day

b Milligrams of bromodichloromethane consumed per kilogram body weight per day