# APPENDIX I CHEMICAL CHARACTERIZATION AND DOSE FORMULATION STUDIES

## Procurement and Characterization

### Bromodichloromethane

A single lot of bromodichloromethane (14522LS) was obtained from Aldrich Chemical Co. (Milwaukee, WI) for use in the 26-, 39-, 41-, and 42-week studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory, Battelle Memorial Institute (Columbus, OH), and the study laboratory, Battelle Columbus Operations (Columbus, OH). Reports on analyses performed in support of the bromodichloromethane studies are on file at the National Institute of Environmental Health Sciences.

Lot 14522LS, a clear, colorless liquid, was identified as bromodichloromethane by the analytical chemistry laboratory and the study laboratory using infrared (IR) spectroscopy. All spectra were consistent with the structure of bromodichloromethane, a literature spectra (Aldrich, 1985) of bromodichloromethane, and with the spectrum of a previously analyzed lot of bromodichloromethane. The infrared spectrum is presented in Figure I1.

The purity of lot 14522LS was determined by the analytical chemistry laboratory using gas chromatography (GC) by system A (Table I1) and by the study laboratory using GC by system B. GC by system A indicated one major peak and three impurity peaks with a combined peak area of 1.9% relative to the major peak area. GC by system B indicated a purity of 98.4% relative to a frozen reference standard of the same lot. The overall purity of lot 14522LS was determined to be 98% or greater.

Stability studies of another lot of bulk chemical (02107TG) were performed by the analytical chemistry laboratory using GC by system C. GC by system C indicated that bromodichloromethane was stable as a bulk chemical for 15 days when stored protected from light at temperatures up to 60° C. To ensure stability, the bulk chemical was stored at less than or equal to −20° C, protected from light, in heat-sealed glass ampules with potassium carbonate stabilizer. Stability of lot 14522LS was monitored by the study laboratory during the studies using GC by system B. No degradation of the bulk chemical was detected.

### 12-O-Tetradecanoylphorbol-13-acetate (TPA)

12-O-tetradecanoylphorbol-13-acetate was obtained from Sigma-Aldrich Chemical Company (St. Louis, MO) in one lot (48H1178) that was used in the 26-week studies in Tg.AC hemizygous mice. Identity and purity analyses were performed by Research Triangle Institute (RTI; Research Triangle Park, NC).

Lot 48H1178, a white crystalline powder, was identified as 12-O-tetradecanoylphorbol-13-acetate using IR and proton nuclear magnetic resonance (NMR) spectrometry. All spectra were consistent with the structure of 12-O-tetradecanoylphorbol-13-acetate.

The purity of lot 48H1178 was determined by RTI using high performance liquid chromatography (HPLC). HPLC analysis was performed with a Dupont Zorbax Rx C8 column (25 cm × 4.6 mm; Agilent Technologies, Palo Alto, CA), photodiode array detection monitored at 232 nm, and an isocratic mobile phase of water:acetonitrile (10:90) with a flow rate of 1.0 mL/minute. Analysis indicated one major peak and one impurity peak with an area equal to approximately 0.11% of the total integrated peak area. The overall purity of lot 48H1178 was determined to be greater than 99%.

### Acetone

USP-grade acetone was obtained from Spectrum Chemicals and Laboratory Products (Gardena, CA) in three lots (NV0163, OG0513, OX0312) that were used during the 26- and 39-week dermal studies. Identity and purity analyses were performed by the study laboratory.

The identity of each lot was determined by IR spectroscopy; all spectra were consistent with a literature spectrum (Aldrich, 1985). The purity of all lots was determined using GC by system D. These analyses did not indicate any impurities with relative peak areas greater than 0.1% of the major peak area. The overall purity of all lots used was determined to be greater than 99%. No degradation of the acetone was detected.

### Corn Oil

USP-grade corn oil was obtained from Spectrum Chemicals and Laboratory Products in six lots (OT0213, OU0101, OV0137, OH0409, PN0012, PO0173) that were used during the 26- and 41-week gavage studies. The study laboratory analyzed peroxide levels in bulk corn oil upon receipt and at least monthly thereafter using potentiometric titration. Potentiometric titration monitored via a double platinum sheet electrode demonstrated peroxide concentrations below the acceptable limit of 3 mEq/kg.

## Preparation and Analysis of Dose Formulations

### Dermal Studies

The dose formulations were prepared approximately every 4 weeks by mixing bromodichloromethane with USP-grade acetone to give the required concentration (Table I2). The dose formulations were stored at room temperature in amber glass bottles with Teflon^®^-lined lids for up to 39 days. A positive control dose formulation of TPA was prepared twice during the studies by adding the appropriate amount of TPA to acetone; the formulations were stored at approximately 5° C in amber glass bottles for up to 6 months.

Stability studies of 0.4, 0.8, 1.6, 3.2, 6.4, and 12.8 µg/mL dose formulations were performed by the study laboratory using GC by systems similar to system B (Table I1). Stability was confirmed for dose formulations stored in amber glass bottles with Teflon^®^-lined lids for up to 39 days at room temperature.

Periodic analyses of the dose formulations of bromodichloromethane were conducted by the study laboratory using GC by systems similar to system B. During the 26- and 39-week studies, dose formulations were analyzed four times (Table I3). All 12 dose formulations for Tg.AC hemizygous mice were within 10% of the target concentration. Animal room samples of these dose formulations were also analyzed; all nine animal room samples were within 10% of the target concentration.

### Drinking Water Studies

The dose formulations were prepared every 1 to 3 weeks by mixing bromodichloromethane with tap water (Table I2). Formulations were stored in glass bottles with Teflon^®^-lined lids at 5° C for up to 35 days. Positive control dose formulations of TPA were prepared and stored as described for the dermal studies.

Stability studies of 0.75, 0.9, 0.8, 1.0, 1.05, and 1.2 µg/mL dose formulations were performed by the study laboratory using GC by system E (Table I1). Stability was confirmed for at least 35 days for dose formulations stored in amber glass bottles at 5° C.

Periodic analyses of the dose formulations of bromodichloromethane were conducted by the study laboratory using GC by system E (Table I1). During the 26- and 42-week studies, dose formulations were analyzed four times. All 12 of the dose formulations for Tg.AC hemizygous and p53 haploinsufficient mice were within 10% of the target concentration (Table I4). Animal room samples of these dose formulations were also analyzed; three of nine Tg.AC hemizygous mouse animal room samples and none of the nine p53 haploinsufficient mouse animal room samples were within 10% of the target concentration. These low results were attributed to the volatility and hydrophobic nature of bromodichloromethane.

### Gavage Studies

The dose formulations were prepared approximately every 4 weeks by mixing bromodichloromethane with USP-grade corn oil to give the required concentrations (Table I2). Dose formulations were stored in amber glass bottles with Teflon^®^-lined lids and refrigerated for up to 35 days. The positive control dose formulations of TPA were prepared and stored as described for the dermal studies.

Stability studies of 0.4, 0.8, 1.6, 3.2, 6.4, and 12.8 µg/mL dose formulations were performed by the study laboratory using GC by systems similar to system B (Table I1). Stability was confirmed for at least 21 days for dose formulations stored in glass bottles protected from light at room temperature.

Periodic analyses of the dose formulations of bromodichloromethane were conducted by the study laboratory using GC by systems similar to system B. During the 26- and 41-week studies dose formulations were analyzed five times. All 12 dose formulations used in the studies for Tg.AC hemizygous and p53 haploinsufficient mice were within 10% of the target concentration (Table I5). Animal room samples of these dose formulations were also analyzed; eight of nine animal room samples were within 10% of the target concentration.

FIGURE I1 Infrared Absorption Spectrum of Bromodichloromethane

TABLE I1 Gas Chromatography Systems Used in the Dermal, Drinking Water, and Gavage Studies of Bromodichloromethane

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization | Supelco Vocol 30 m × 0.25 mm, 1.5-μm film thickness (Supelco, Inc., Bellefonte, PA) | Helium at 3.5 mL/minute | 40° C for 4 minutes, then 6° C/minute to 210° C, held for 2 minutes
System B
Electron capture | Supelco Vocol 30 m × 0.25 mm, 1.5-μm film thickness (Supelco, Inc.) | Helium at 4 mL/minute | 55° C for 7 minutes, then 5° C/minute to 100° C, then 30° C/minute to 150° C, held for 3 minutes
System C
Electron capture | Supelco Vocol 30 m × 0.25 mm, 3.0-μm film thickness (Supelco, Inc.) | Helium at 8 mL/minute | 40° C to 120° C at 10° C/minute, then 49° C/minute to 169° C, held for 1 minute
System D
Flame ionization | 20% SP-2401/0.1% Carbowax 1500 on 100/120 Supelcoport, 2.4 m × 2 mm (Supelco, Inc.) | Helium at 30 mL/minute | 40° C for 4 minutes, then 10° C/minute to 170° C
System E
Flame ionization | 1% SP-1000.on 60/80 Carbopack B, 2.4 m × 2.0 mm (Supelco, Inc.) | Helium at 10 mL/minute | 150° C isothermal

TABLE I2 Preparation and Storage of Dose Formulations in the Dermal, Drinking Water, and Gavage Studies of Bromodichloromethane

Dermal Studies | Drinking Water Studies | Gavage Studies
Preparation
Bromodichloromethane: The required amount of bromodichloromethane was added to a specified initial volume of USP-grade acetone in a graduated mixing cylinder. The cylinder was sealed, shaken vigorously, and inverted at least 10 times then diluted to volume with USP-grade acetone and mixed as before. Dose formulations were prepared approximately every 4 weeks. | Bromodichloromethane: A specified amount of bromodichloromethane was added to 16 L of tap water in a 20 L glass mixing bottle and sealed with a Teflon^®^-lined screw cap. The bottle was sealed, shaken vigorously, and rolled on a bottle roller until the chemical was dissolved. Dose formulations were prepared every 1 to 3 weeks. | Bromodichloromethane: The required amount of bromodichloromethane was added to 600 mL of USP-grade corn oil in a calibrated glass mixing bottle, diluted to volume with USP-grade corn oil, sealed, shaken, and inverted at least 10 times. A stir bar was added and the formulation was stirred for at least 2 hours. Dose formulations were prepared approximately every 4 weeks.
TPA: A 12.5 μg/mL formulation was prepared by diluting the appropriate amount of TPA in acetone. Formulations were prepared twice during the studies. | TPA: A 12.5 μg/mL formulation was prepared by diluting the appropriate amount of TPA in acetone. Formulations were prepared twice during the studies. | TPA: A 12.5 μg/mL formulation was prepared by diluting the appropriate amount of TPA in acetone. Formulations were prepared twice during the studies.
Chemical Lot Number
Bromodichloromethane: 14522LS TPA: 48H1178 | Bromodichloromethane: 14522LS TPA: 48H1178 | Bromodichloromethane: 14522LS TPA: 48H1178
Maximum Storage Time
Bromodichloromethane: 39 days TPA: 6 months | Bromodichloromethane: 35 days TPA: 6 months | Bromodichloromethane: 35 days TPA: 6 months
Storage Conditions
Bromodichloromethane: Formulations were transferred to 15-mL amber glass bottles, sealed with Teflon^®^-lined lids, and stored at room temperature. | Bromodichloromethane: Formulations remained in the glass containers in which they were prepared; the lids were sealed with Teflon^®^-lined screw caps and the containers were stored refrigerated at approximately 5° C. | Bromodichloromethane: Formulations were transferred to 15-mL amber glass bottles, sealed with Teflon^®^-lined lids, and stored refrigerated at approximately 5° C.
TPA: Stored in amber glass bottles sealed with Teflon^®^-lined lids and refrigerated at approximately 5° C. | TPA: Stored in amber glass bottles, sealed with Teflon^®^-lined lids, and refrigerated at approximately 5° C. | TPA: Stored in amber glass bottles sealed with Teflon^®^-lined lids and refrigerated at approximately 5° C.
Study Laboratory
Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH)

TABLE I3 Results of Analyses of Dose Formulations Administered to Tg.AC Hemizygous Mice in the 26- and 39-Week Dermal Studies of Bromodichloromethane

Date Prepared | Date Analyzed | Target Concentration (mg/L) | Determined Concentration^a^ (mg/L) | Difference from Target (%)
August 11, 1999 | August 11, 1999 | 19.4 | 19.15 | −1
August 11, 1999 | August 11, 1999 | 38.8 | 39.38 | +1
August 11, 1999 | August 11, 1999 | 77.6 | 77.03 | −1
August 11, 1999 | September 16, 1999^b^ | 19.4 | 20.55 | +6
August 11, 1999 | September 16, 1999^b^ | 38.8 | 41.27 | +6
August 11, 1999 | September 16, 1999^b^ | 77.6 | 82.46 | +6
November 2, 1999 | November 3–4, 1999 | 19.4 | 19.30 | −1
November 2, 1999 | November 3–4, 1999 | 38.8 | 39.48 | +2
November 2, 1999 | November 3–4, 1999 | 77.6 | 77.50 | 0
November 2, 1999 | December 10, 1999^b^ | 19.4 | 19.48 | 0
November 2, 1999 | December 10, 1999^b^ | 38.8 | 41.11 | +6
November 2, 1999 | December 10, 1999^b^ | 77.6 | 80.79 | +4
January 25, 2000 | January 26, 2000 | 19.4 | 20.26 | +4
January 25, 2000 | January 26, 2000 | 38.8 | 38.49 | −1
January 25, 2000 | January 26, 2000 | 77.6 | 75.98 | −2
April 18, 2000 | April 19, 2000 | 19.4 | 19.23 | −1
April 18, 2000 | April 19, 2000 | 38.8 | 38.00 | −2
April 18, 2000 | April 19, 2000 | 77.6 | 73.77 | −5
April 18, 2000 | May 23–24, 2000^b^ | 19.4 | 20.40 | +5
April 18, 2000 | May 23–24, 2000^b^ | 38.8 | 40.18 | +4
April 18, 2000 | May 23–24, 2000^b^ | 77.6 | 79.10 | +2

a Results of duplicate analyses

b Animal room samples

TABLE I4 Results of Analyses of Dose Formulations Administered to Tg.AC Hemizygous and p53 Haploinsufficient Mice in the 26- and 42-Week Drinking Water Studies of Bromodichloromethane

Date Prepared | Date Analyzed | Target Concentration (mg/L) | Determined Concentration^a^ (mg/L) | Difference from Target (%)
August 23, 1999 | August 26, 1999 | 175 | 174.6 | 0
August 23, 1999 | August 26, 1999 | 175 | 171.7 | −2
August 23, 1999 | August 26, 1999 | 175 | 174.4 | 0
August 23, 1999 | August 26, 1999 | 350 | 339.7 | −3
August 23, 1999 | August 26, 1999 | 350 | 353.1 | +1
August 23, 1999 | August 26, 1999 | 350 | 336.3 | −4
August 23, 1999 | August 26, 1999 | 700 | 639.1 | −9
August 23, 1999 | August 26, 1999 | 700 | 668.1 | −5
August 23, 1999 | August 26, 1999 | 700 | 704.3 | +1
November 9, 1999 | November 10–11, 1999 | 175 | 170.3 | −3
November 9, 1999 | November 10–11, 1999 | 175 | 166.3 | −5
November 9, 1999 | November 10–11, 1999 | 350 | 327.7 | −6
November 9, 1999 | November 10–11, 1999 | 350 | 329.2 | −6
November 9, 1999 | November 10–11, 1999 | 700 | 686.3 | −2
November 9, 1999 | November 10–11, 1999 | 700 | 631.4 | −10
February 1, 2000 | February 2–3, 2000 | 175 | 170.8 | −2
February 1, 2000 | February 2–3, 2000 | 350 | 354.0 | +1
February 1, 2000 | February 2–3, 2000 | 700 | 649.7 | −7
May 3, 2000 | May 8, 2000 | 175 | 188.2 | +8
May 3, 2000 | May 8, 2000 | 350 | 378.2 | +8
May 3, 2000 | May 8, 2000 | 700 | 751.8 | +7
Animal Room Samples for Tg.AC Hemizygous Mice
August 23, 1999 | September 20–21, 1999 | 175 | 121.0 | −31
August 23, 1999 | September 20–21, 1999 | 350 | 264.8 | −24
August 23, 1999 | September 20–21, 1999 | 700 | 637.5 | −9
November 9, 1999 | December 6–7, 1999 | 175 | 136.6 | −22
November 9, 1999 | December 6–7, 1999 | 350 | 372.3 | +6
November 9, 1999 | December 6–7, 1999 | 700 | 662.7 | −5
April 11, 2000 | May 31, 2000 | 175 | 145.9 | −17
April 11, 2000 | May 31, 2000 | 350 | 239.7 | −32
April 11, 2000 | May 31, 2000 | 700 | 465.7 | −33
Animal Room Samples for p53 Haploinsufficient Mice
August 23, 1999 | September 20, 1999 | 175 | 133.3 | −24
August 23, 1999 | September 20, 1999 | 350 | 252.6 | −28
August 23, 1999 | September 20, 1999 | 700 | 575.4 | −18
November 9, 1999 | December 6–7, 1999 | 175 | 139.9 | −20
November 9, 1999 | December 6–7, 1999 | 350 | 247.3 | −29
November 9, 1999 | December 6–7, 1999 | 700 | 619.7 | −11
April 11, 2000 | May 31, 2000 | 175 | 144.4 | −17
April 11, 2000 | May 31, 2000 | 350 | 254.2 | −27
April 11, 2000 | May 31, 2000 | 700 | 534.5 | −24

a Results of duplicate analyses

TABLE I5 Results of Analyses of Dose Formulations Administered to Tg.AC Hemizygous and p53 Haploinsufficient Mice in the 26- and 41-Week Gavage Studies of Bromodichloromethane

Date Prepared | Date Analyzed | Target Concentration (mg/L) | Determined Concentration^a^ (mg/L) | Difference from Target (%)
September 8, 1999 | September 9, 1999 | 2.5 | 2.418 | −3
September 8, 1999 | September 9, 1999 | 5.0 | 4.977 | 0
September 8, 1999 | September 9, 1999 | 10.0 | 10.17 | +2
September 8, 1999 | October 14–15, 1999 | 2.5 | 2.461 | −2
September 8, 1999 | October 14–15, 1999 | 5.0 | 4.829 | −3
September 8, 1999 | October 14–15, 1999 | 10.0 | 9.492 | −5
December 1, 1999 | December 3, 1999 | 2.5 | 2.374 | −5
December 1, 1999 | December 3, 1999 | 5.0 | 4.851 | −3
December 1, 1999 | December 3, 1999 | 10.0 | 9.420 | −6
December 1, 1999 | January 5, 2000 | 2.5 | 2.259 | −10
December 1, 1999 | January 5, 2000 | 5.0 | 4.684 | −6
December 1, 1999 | January 5, 2000 | 10.0 | 9.280 | −7
February 22, 2000 | February 23, 2000 | 2.5 | 2.362 | −6
February 22, 2000 | February 23, 2000 | 5.0 | 4.806 | −4
February 22, 2000 | February 23, 2000 | 10.0 | 8.855 | −11^b^
February 24, 2000 | February 25, 2000 | 10.0 | 9.835 | −2
May 16, 2000 | May 16–17, 2000 | 2.5 | 2.390 | −4
May 16, 2000 | May 16–17, 2000 | 5.0 | 4.777 | −4
May 16, 2000 | May 16–17, 2000 | 10.0 | 9.444 | −6
May 16, 2000 | June 22, 2000 | 2.5 | 2.372 | −5
May 16, 2000 | June 22, 2000 | 5.0 | 4.682 | −6
May 16, 2000 | June 22, 2000 | 10.0 | 8.845 | −12

a Results of duplicate analyses.

b Not used in study.