# APPENDIX H ORGAN WEIGHTS AND ORGAN-WEIGHT-TO-BODY-WEIGHT RATIOS

TABLE H1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Bromodichloromethane^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Male
n | 13 | 14 | 15 | 13
Necropsy body wt. | 35.0 ± 1.4 | 34.6 ± 1.0 | 36.1 ± 0.9 | 33.8 ± 0.8
Heart
Absolute | 0.181 ± 0.005 | 0.185 ± 0.004 | 0.180 ± 0.005 | 0.173 ± 0.004
Relative | 5.232 ± 0.159 | 5.388 ± 0.165 | 5.006 ± 0.128 | 5.143 ± 0.126
R. Kidney
Absolute | 0.294 ± 0.005 | 0.313 ± 0.008 | 0.305 ± 0.008 | 0.288 ± 0.009
Relative | 8.555 ± 0.320 | 9.070 ± 0.185 | 8.542 ± 0.328 | 8.533 ± 0.211
Liver
Absolute | 1.630 ± 0.053 | 1.654 ± 0.052 | 1.722 ± 0.044 | 1.674 ± 0.057
Relative | 46.914 ± 0.955 | 47.877 ± 1.004 | 47.791 ± 0.639 | 49.579 ± 1.318
Lung
Absolute | 0.283 ± 0.013 | 0.286 ± 0.014 | 0.297 ± 0.010 | 0.261 ± 0.014
Relative | 8.234 ± 0.476 | 8.281 ± 0.346 | 8.286 ± 0.354 | 7.786 ± 0.467
R. Testis
Absolute | 0.084 ± 0.003 | 0.089 ± 0.002 | 0.087 ± 0.002 | 0.087 ± 0.002
Relative | 2.455 ± 0.140 | 2.589 ± 0.096 | 2.433 ± 0.081 | 2.579 ± 0.085
Thymus
Absolute | 0.034 ± 0.003 | 0.038 ± 0.003 | 0.043 ± 0.004 | 0.034 ± 0.003
Relative | 0.954 ± 0.068 | 1.095 ± 0.071 | 1.173 ± 0.078 | 1.004 ± 0.077
Female
n | 11 | 10 | 12 | 10
Necropsy body wt. | 28.6 ± 0.9 | 28.8 ± 1.4 | 29.2 ± 1.0 | 29.3 ± 1.0
Heart
Absolute | 0.150 ± 0.004 | 0.152 ± 0.005 | 0.149 ± 0.004 | 0.148 ± 0.007
Relative | 5.263 ± 0.107 | 5.334 ± 0.152 | 5.142 ± 0.153 | 5.043 ± 0.188
R. Kidney
Absolute | 0.218 ± 0.007 | 0.221 ± 0.008 | 0.219 ± 0.007 | 0.213 ± 0.006
Relative | 7.649 ± 0.207 | 7.730 ± 0.144 | 7.527 ± 0.220 | 7.292 ± 0.190
Liver
Absolute | 1.460 ± 0.052 | 1.495 ± 0.058 | 1.509 ± 0.048 | 1.486 ± 0.030
Relative | 51.084 ± 0.923 | 52.269 ± 1.205 | 51.858 ± 1.101 | 50.946 ± 0.938
Lung
Absolute | 0.266 ± 0.014 | 0.233 ± 0.007 | 0.262 ± 0.012 | 0.258 ± 0.017
Relative | 9.334 ± 0.471 | 8.283 ± 0.454 | 9.108 ± 0.565 | 8.835 ± 0.503
Thymus
Absolute | 0.036 ± 0.002 | 0.039 ± 0.003 | 0.037 ± 0.003 | 0.035 ± 0.002
Relative | 1.242 ± 0.057 | 1.341 ± 0.071 | 1.271 ± 0.071 | 1.179 ± 0.064

a Organ weights (absolute weights) and body weights are given as grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

TABLE H2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Bromodichloromethane^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Male
n | 6 | 8 | 9 | 8
Necropsy body wt. | 38.3 ± 2.5 | 38.8 ± 2.4 | 37.6 ± 1.9 | 36.9 ± 2.0
Heart
Absolute | 0.208 ± 0.011 | 0.201 ± 0.009 | 0.202 ± 0.009 | 0.223 ± 0.025
Relative | 5.527 ± 0.376 | 5.223 ± 0.179 | 5.443 ± 0.254 | 6.008 ± 0.510
R. Kidney
Absolute | 0.356 ± 0.014 | 0.350 ± 0.016 | 0.346 ± 0.014 | 0.316 ± 0.007
Relative | 9.421 ± 0.461 | 9.159 ± 0.454 | 9.251 ± 0.251 | 8.697 ± 0.381
Liver
Absolute | 2.065 ± 0.104 | 1.998 ± 0.114 | 1.987 ± 0.122 | 1.982 ± 0.126
Relative | 54.519 ± 2.390 | 51.657 ± 0.965 | 52.660 ± 1.965 | 53.636 ± 1.006
Lung
Absolute | 0.245 ± 0.007 | 0.239 ± 0.011 | 0.254 ± 0.010 | 0.295 ± 0.027
Relative | 6.543 ± 0.437 | 6.283 ± 0.389 | 6.822 ± 0.268 | 8.104 ± 0.795
R. Testis
Absolute | 0.082 ± 0.004 | 0.090 ± 0.003 | 0.092 ± 0.002 | 0.084 ± 0.005
Relative | 2.175 ± 0.153 | 2.380 ± 0.178 | 2.511 ± 0.162 | 2.312 ± 0.181
Thymus
Absolute | 0.037 ± 0.007 | 0.035 ± 0.004 | 0.034 ± 0.006 | 0.039 ± 0.005
Relative | 0.925 ± 0.121 | 0.912 ± 0.080 | 0.907 ± 0.159 | 1.071 ± 0.127
Female
n | 5 | 4 | 7 | 5
Necropsy body wt. | 28.7 ± 1.8 | 28.1 ± 1.7 | 33.5 ± 3.0 | 28.9 ± 0.7
Heart
Absolute | 0.143 ± 0.006 | 0.146 ± 0.005 | 0.168 ± 0.008^*^ | 0.171 ± 0.009^*^
Relative | 5.010 ± 0.100 | 5.230 ± 0.288 | 5.168 ± 0.365 | 5.926 ± 0.287
R. Kidney
Absolute | 0.259 ± 0.014 | 0.247 ± 0.010 | 0.249 ± 0.011 | 0.222 ± 0.007
Relative | 9.075 ± 0.441 | 8.865 ± 0.502 | 7.674 ± 0.518^*^ | 7.691 ± 0.160
Liver
Absolute | 1.706 ± 0.138 | 1.613 ± 0.029 | 1.833 ± 0.133 | 1.604 ± 0.043
Relative | 59.551 ± 3.727 | 58.115 ± 3.602 | 55.566 ± 2.783 | 55.541 ± 1.445
Lung
Absolute | 0.220 ± 0.008 | 0.233 ± 0.010 | 0.226 ± 0.006 | 0.281 ± 0.025^*^
Relative | 7.794 ± 0.590 | 8.346 ± 0.187 | 7.124 ± 0.715 | 9.787 ± 0.965
Thymus
Absolute | 0.025 ± 0.003 | 0.039 ± 0.007 | 0.042 ± 0.005^*^ | 0.031 ± 0.002
Relative | 0.857 ± 0.080 | 1.359 ± 0.194^*^ | 1.233 ± 0.082^*^ | 1.078 ± 0.083

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

a Organ weights (absolute weights) and body weights are given as grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

TABLE H3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Male
n | 13 | 12 | 12 | 14
Necropsy body wt. | 41.3 ± 1.3 | 40.3 ± 1.6 | 38.4 ± 0.9 | 36.9 ± 1.0^*^
Heart
Absolute | 0.188 ± 0.004 | 0.175 ± 0.005^*^ | 0.171 ± 0.004^**^ | 0.162 ± 0.004^**^
Relative | 4.588 ± 0.155 | 4.373 ± 0.110 | 4.458 ± 0.076 | 4.403 ± 0.102
R. Kidney
Absolute | 0.322 ± 0.009 | 0.293 ± 0.008^**^ | 0.281 ± 0.007^**^ | 0.280 ± 0.005^**^
Relative | 7.822 ± 0.158 | 7.318 ± 0.160 | 7.317 ± 0.126 | 7.676 ± 0.295
Liver
Absolute | 1.904 ± 0.080 | 1.869 ± 0.090 | 1.800 ± 0.053 | 1.726 ± 0.055
Relative | 45.942 ± 1.006 | 46.259 ± 0.790 | 46.829 ± 0.895 | 46.817 ± 0.739
Lung
Absolute | 0.236 ± 0.007 | 0.226 ± 0.008 | 0.250 ± 0.015 | 0.226 ± 0.009
Relative | 5.773 ± 0.246 | 5.687 ± 0.246 | 6.555 ± 0.437 | 6.212 ± 0.316
R. Testis
Absolute | 0.094 ± 0.002 | 0.085 ± 0.003 | 0.090 ± 0.004 | 0.084 ± 0.004
Relative | 2.286 ± 0.066 | 2.155 ± 0.149 | 2.353 ± 0.114 | 2.311 ± 0.130
Thymus
Absolute | 0.045 ± 0.003 | 0.053 ± 0.007 | 0.053 ± 0.005 | 0.046 ± 0.004
Relative | 1.088 ± 0.053 | 1.298 ± 0.142 | 1.357 ± 0.105 | 1.244 ± 0.112
Female
n | 10 | 13 | 11 | 13
Necropsy body wt. | 30.0 ± 1.4 | 35.0 ± 1.5 | 33.6 ± 2.4 | 33.2 ± 1.8
Heart
Absolute | 0.151 ± 0.006 | 0.159 ± 0.005 | 0.160 ± 0.006 | 0.150 ± 0.005
Relative | 5.111 ± 0.226 | 4.605 ± 0.165 | 4.900 ± 0.219 | 4.595 ± 0.163
R. Kidney
Absolute | 0.223 ± 0.009 | 0.244 ± 0.011 | 0.232 ± 0.007 | 0.229 ± 0.007
Relative | 7.505 ± 0.311 | 7.228 ± 0.678 | 7.149 ± 0.399 | 7.020 ± 0.272
Liver
Absolute | 1.506 ± 0.049 | 1.775 ± 0.041 | 1.760 ± 0.145 | 1.824 ± 0.116
Relative | 50.533 ± 0.925 | 51.695 ± 2.470 | 52.343 ± 1.508 | 54.879 ± 1.933
Lung
Absolute | 0.241 ± 0.014 | 0.232 ± 0.009 | 0.250 ± 0.013 | 0.236 ± 0.006
Relative | 8.168 ± 0.557 | 6.756 ± 0.355 | 7.840 ± 0.692 | 7.326 ± 0.427
Thymus
Absolute | 0.035 ± 0.003 | 0.039 ± 0.003 | 0.041 ± 0.004 | 0.040 ± 0.003
Relative | 1.162 ± 0.066 | 1.114 ± 0.058 | 1.217 ± 0.081 | 1.216 ± 0.072

* Significantly different (P≤0.05) from the control group by Williams’ test

** P≤0.01

a Organ weights (absolute weights) and body weights are given as grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

TABLE H4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Tg.AC Hemizygous Mice in the 42-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Male
n | 6 | 9 | 8 | 9
Necropsy body wt. | 43.0 ± 1.5 | 42.0 ± 2.2 | 38.9 ± 1.4 | 38.9 ± 2.2
Heart
Absolute | 0.189 ± 0.007 | 0.179 ± 0.007 | 0.189 ± 0.008 | 0.184 ± 0.006
Relative | 4.393 ± 0.106 | 4.299 ± 0.157 | 4.907 ± 0.268 | 4.817 ± 0.256
R. Kidney
Absolute | 0.364 ± 0.012 | 0.330 ± 0.014 | 0.308 ± 0.010^**^ | 0.285 ± 0.008^**^
Relative | 8.507 ± 0.428 | 7.922 ± 0.268 | 7.995 ± 0.432 | 7.480 ± 0.375
Liver
Absolute | 2.112 ± 0.112 | 2.049 ± 0.110 | 2.011 ± 0.079 | 1.991 ± 0.136
Relative | 49.019 ± 1.501 | 48.869 ± 1.258 | 51.928 ± 1.920 | 51.252 ± 2.147
Lung
Absolute | 0.227 ± 0.005 | 0.240 ± 0.013 | 0.267 ± 0.025 | 0.238 ± 0.013
Relative | 5.310 ± 0.252 | 5.788 ± 0.291 | 6.983 ± 0.770 | 6.273 ± 0.499
R. Testis
Absolute | 0.082 ± 0.005 | 0.089 ± 0.003 | 0.090 ± 0.003 | 0.089 ± 0.003
Relative | 1.916 ± 0.145 | 2.159 ± 0.142 | 2.331 ± 0.123 | 2.351 ± 0.196
Thymus
Absolute | 0.036 ± 0.006 | 0.040 ± 0.005 | 0.040 ± 0.005 | 0.040 ± 0.005
Relative | 0.853 ± 0.150 | 0.965 ± 0.112 | 1.017 ± 0.105 | 1.028 ± 0.113
Female
n | 5 | 8 | 4 | 4
Necropsy body wt. | 35.7 ± 1.7 | 36.3 ± 3.2 | 42.6 ± 4.6 | 39.8 ± 3.6
Heart
Absolute | 0.168 ± 0.001 | 0.171 ± 0.015 | 0.170 ± 0.012 | 0.178 ± 0.011
Relative | 4.763 ± 0.239 | 4.800 ± 0.322 | 4.020 ± 0.154 | 4.568 ± 0.477
R. Kidney
Absolute | 0.260 ± 0.016 | 0.252 ± 0.008 | 0.262 ± 0.031 | 0.242 ± 0.011
Relative | 7.300 ± 0.332 | 7.264 ± 0.572 | 6.149 ± 0.361 | 6.189 ± 0.514
Liver
Absolute | 1.882 ± 0.057 | 1.915 ± 0.113 | 2.390 ± 0.266 | 2.274 ± 0.106
Relative | 53.151 ± 2.437 | 54.010 ± 2.515 | 56.105 ± 1.791 | 58.085 ± 3.803
Lung
Absolute | 0.229 ± 0.013 | 0.251 ± 0.031 | 0.233 ± 0.015 | 0.239 ± 0.016
Relative | 6.549 ± 0.710 | 7.121 ± 0.826 | 5.563 ± 0.404 | 6.276 ± 1.058
Thymus
Absolute | 0.034 ± 0.004 | 0.037 ± 0.004 | 0.045 ± 0.009 | 0.041 ± 0.008
Relative | 0.982 ± 0.139 | 1.008 ± 0.064 | 1.040 ± 0.097 | 1.006 ± 0.162

** Significantly different (P≤0.01) from the control group by Williams’ test

a Organ weights (absolute weights) and body weights are given as grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

TABLE H5 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Tg.AC Hemizygous Mice in the 26-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Male
n | 13 | 14 | 12 | 14
Necropsy body wt. | 35.5 ± 1.5 | 34.8 ± 0.9 | 33.7 ± 1.1 | 33.0 ± 1.0
Heart
Absolute | 0.185 ± 0.008 | 0.185 ± 0.004 | 0.178 ± 0.006 | 0.185 ± 0.006
Relative | 5.258 ± 0.205 | 5.383 ± 0.260 | 5.308 ± 0.168 | 5.659 ± 0.199
R. Kidney
Absolute | 0.295 ± 0.012 | 0.300 ± 0.008 | 0.291 ± 0.009 | 0.287 ± 0.005
Relative | 8.344 ± 0.179 | 8.663 ± 0.281 | 8.682 ± 0.201 | 8.779 ± 0.261
Liver
Absolute | 1.667 ± 0.073 | 1.581 ± 0.038 | 1.626 ± 0.044 | 1.740 ± 0.071
Relative | 47.118 ± 1.314 | 45.579 ± 1.001 | 48.515 ± 1.062 | 52.608 ± 0.955^**^
Lung
Absolute | 0.308 ± 0.019 | 0.331 ± 0.015 | 0.274 ± 0.012 | 0.283 ± 0.015
Relative | 8.782 ± 0.565 | 9.591 ± 0.540 | 8.191 ± 0.390 | 8.605 ± 0.389
R. Testis
Absolute | 0.089 ± 0.002 | 0.083 ± 0.006 | 0.091 ± 0.003 | 0.088 ± 0.003
Relative | 2.556 ± 0.125 | 2.397 ± 0.172 | 2.712 ± 0.099 | 2.690 ± 0.108
Thymus
Absolute | 0.035 ± 0.003 | 0.030 ± 0.003 | 0.031 ± 0.003 | 0.034 ± 0.003
Relative | 0.967 ± 0.076 | 0.838 ± 0.060 | 0.890 ± 0.074 | 1.014 ± 0.069
Female
n | 11 | 14 | 13 | 13
Necropsy body wt. | 27.0 ± 0.4 | 29.8 ± 1.3 | 28.0 ± 1.1 | 28.6 ± 1.2
Heart
Absolute | 0.147 ± 0.004 | 0.143 ± 0.003 | 0.148 ± 0.004 | 0.143 ± 0.003
Relative | 5.464 ± 0.171 | 4.894 ± 0.201 | 5.363 ± 0.221 | 5.083 ± 0.161
R. Kidney
Absolute | 0.205 ± 0.004 | 0.211 ± 0.005 | 0.203 ± 0.006 | 0.216 ± 0.005
Relative | 7.634 ± 0.208 | 7.216 ± 0.292 | 7.316 ± 0.173 | 7.671 ± 0.265
Liver
Absolute | 1.432 ± 0.052 | 1.544 ± 0.053^b^ | 1.490 ± 0.059 | 1.586 ± 0.059
Relative | 53.104 ± 1.706 | 52.597 ± 1.223^b^ | 53.284 ± 0.719 | 55.706 ± 0.944
Lung
Absolute | 0.305 ± 0.012 | 0.294 ± 0.012 | 0.301 ± 0.015 | 0.293 ± 0.011
Relative | 11.366 ± 0.547 | 10.023 ± 0.512 | 10.986 ± 0.765 | 10.414 ± 0.459
Thymus
Absolute | 0.029 ± 0.002 | 0.034 ± 0.002 | 0.037 ± 0.002 | 0.034 ± 0.003
Relative | 1.087 ± 0.076 | 1.160 ± 0.077 | 1.330 ± 0.066 | 1.166 ± 0.078

** Significantly different (P≤0.01) from the vehicle control group by Williams’ test

a Organ weights (absolute weights) and body weights are given as grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

b n=13

TABLE H6 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Tg.AC Hemizygous Mice in the 41-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Male
n | 6 | 6 | 6 | 8
Necropsy body wt. | 34.1 ± 2.1 | 38.7 ± 1.8 | 34.3 ± 2.1 | 33.4 ± 0.8
Heart
Absolute | 0.181 ± 0.016 | 0.185 ± 0.007 | 0.181 ± 0.009 | 0.179 ± 0.009
Relative | 5.293 ± 0.245 | 4.804 ± 0.123 | 5.289 ± 0.109 | 5.418 ± 0.374
R. Kidney
Absolute | 0.295 ± 0.012 | 0.331 ± 0.021 | 0.290 ± 0.013 | 0.291 ± 0.005
Relative | 8.718 ± 0.333 | 8.564 ± 0.455 | 8.498 ± 0.337 | 8.734 ± 0.150
Liver
Absolute | 1.851 ± 0.159 | 1.969 ± 0.099 | 1.993 ± 0.072 | 1.753 ± 0.047
Relative | 53.920 ± 1.792 | 50.887 ± 1.117 | 58.687 ± 2.523 | 52.662 ± 1.567
Lung
Absolute | 0.273 ± 0.026 | 0.225 ± 0.012 | 0.238 ± 0.021 | 0.233 ± 0.014
Relative | 8.041 ± 0.704 | 5.904 ± 0.477 | 7.160 ± 0.977 | 6.998 ± 0.430
R. Testis
Absolute | 0.085 ± 0.005 | 0.085 ± 0.003 | 0.085 ± 0.003 | 0.087 ± 0.003
Relative | 2.545 ± 0.206 | 2.220 ± 0.119 | 2.509 ± 0.161 | 2.617 ± 0.102
Thymus
Absolute | 0.024 ± 0.001 | 0.032 ± 0.006 | 0.025 ± 0.004 | 0.026 ± 0.003
Relative | 0.718 ± 0.061 | 0.799 ± 0.120 | 0.697 ± 0.094 | 0.756 ± 0.071
Female
n | 7 | 9 | 9 | 7
Necropsy body wt. | 28.9 ± 1.3 | 30.5 ± 1.4 | 29.2 ± 0.9 | 33.0 ± 3.0
Heart
Absolute | 0.147 ± 0.007 | 0.136 ± 0.005 | 0.142 ± 0.005 | 0.157 ± 0.012
Relative | 5.127 ± 0.276 | 4.481 ± 0.113 | 4.857 ± 0.116 | 4.843 ± 0.305
R. Kidney
Absolute | 0.229 ± 0.008 | 0.228 ± 0.010 | 0.222 ± 0.005 | 0.227 ± 0.009
Relative | 7.953 ± 0.144 | 7.523 ± 0.275 | 7.665 ± 0.338 | 7.094 ± 0.412
Liver
Absolute | 1.541 ± 0.101 | 1.724 ± 0.140 | 1.696 ± 0.047 | 1.885 ± 0.145
Relative | 53.132 ± 1.712 | 56.274 ± 3.140 | 58.106 ± 0.836 | 57.858 ± 2.881
Lung
Absolute | 0.224 ± 0.015 | 0.253 ± 0.017 | 0.221 ± 0.014 | 0.246 ± 0.023
Relative | 7.875 ± 0.769 | 8.416 ± 0.676 | 7.609 ± 0.496 | 7.707 ± 0.830
Thymus
Absolute | 0.029 ± 0.002 | 0.028 ± 0.003 | 0.028 ± 0.003 | 0.038 ± 0.004
Relative | 1.018 ± 0.055 | 0.927 ± 0.077 | 0.954 ± 0.096 | 1.151 ± 0.085

a Organ weights (absolute weights) and body weights are given as grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

TABLE H7 Organ Weights and Organ-Weight-to-Body-Weight Ratios for p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Male
n | 15 | 15 | 15 | 15
Necropsy body wt. | 48.5 ± 1.1 | 47.2 ± 1.0 | 43.6 ± 0.9^**^ | 37.4 ± 1.0^**^
Heart
Absolute | 0.219 ± 0.013 | 0.204 ± 0.008 | 0.197 ± 0.007 | 0.171 ± 0.004^**^
Relative | 4.503 ± 0.198 | 4.332 ± 0.154 | 4.528 ± 0.132 | 4.593 ± 0.092
R. Kidney
Absolute | 0.302 ± 0.015 | 0.278 ± 0.005 | 0.254 ± 0.007^**^ | 0.225 ± 0.006^**^
Relative | 6.234 ± 0.278 | 5.898 ± 0.102 | 5.839 ± 0.112 | 6.089 ± 0.242
Liver
Absolute | 2.796 ± 0.177 | 2.753 ± 0.165 | 2.277 ± 0.113* | 2.025 ± 0.061^**^
Relative | 57.157 ± 2.619 | 57.815 ± 2.444 | 51.939 ± 1.763 | 54.284 ± 0.907
Lung
Absolute | 0.253 ± 0.013 | 0.245 ± 0.009 | 0.247 ± 0.011 | 0.271 ± 0.011
Relative | 5.238 ± 0.276 | 5.228 ± 0.218 | 5.710 ± 0.282 | 7.264 ± 0.261^**^
R. Testis
Absolute | 0.111 ± 0.002 | 0.111 ± 0.002 | 0.113 ± 0.002 | 0.110 ± 0.002
Relative | 2.299 ± 0.032 | 2.374 ± 0.062 | 2.599 ± 0.040^**^ | 2.977 ± 0.080^**^
Thymus
Absolute | 0.071 ± 0.005 | 0.068 ± 0.002 | 0.068 ± 0.004 | 0.059 ± 0.004
Relative | 1.462 ± 0.087 | 1.442 ± 0.050 | 1.553 ± 0.086 | 1.571 ± 0.090
Female
n | 15 | 15 | 14 | 15
Necropsy body wt. | 36.8 ± 2.3 | 33.8 ± 1.1 | 35.1 ± 2.1 | 32.9 ± 1.7
Heart
Absolute | 0.172 ± 0.007 | 0.159 ± 0.005 | 0.167 ± 0.007 | 0.164 ± 0.007
Relative | 4.825 ± 0.229 | 4.753 ± 0.185 | 4.894 ± 0.218 | 5.076 ± 0.216
R. Kidney
Absolute | 0.193 ± 0.005 | 0.190 ± 0.003 | 0.192 ± 0.006 | 0.193 ± 0.004
Relative | 5.447 ± 0.255 | 5.685 ± 0.159 | 5.611 ± 0.209 | 6.007 ± 0.214
Liver
Absolute | 1.606 ± 0.082 | 1.496 ± 0.038 | 1.624 ± 0.081 | 1.687 ± 0.077
Relative | 44.170 ± 0.966 | 44.590 ± 1.049 | 46.722 ± 0.856 | 51.562 ± 0.874^**^
Lung
Absolute | 0.232 ± 0.010 | 0.233 ± 0.010 | 0.249 ± 0.010 | 0.243 ± 0.007
Relative | 6.603 ± 0.450 | 7.036 ± 0.412 | 7.301 ± 0.352 | 7.659 ± 0.415
Thymus
Absolute | 0.065 ± 0.004 | 0.062 ± 0.004 | 0.068 ± 0.003 | 0.063 ± 0.005
Relative | 1.790 ± 0.094 | 1.853 ± 0.118 | 1.990 ± 0.103 | 1.895 ± 0.082

** Significantly different (P≤0.01) from the control group by Williams’ test

a Organ weights (absolute weights) and body weights are given as grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

TABLE H8 Organ Weights and Organ-Weight-to-Body-Weight Ratios for p53 Haploinsufficient Mice in the 42-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Male
n | 9 | 10 | 9 | 7
Necropsy body wt. | 51.9 ± 0.8 | 48.9 ± 2.0 | 46.8 ± 1.7 | 43.5 ± 2.6^**^
Heart
Absolute | 0.224 ± 0.009 | 0.230 ± 0.008 | 0.214 ± 0.010 | 0.203 ± 0.011
Relative | 4.313 ± 0.164 | 4.727 ± 0.124 | 4.575 ± 0.093 | 4.681 ± 0.082
R. Kidney
Absolute | 0.337 ± 0.013 | 0.330 ± 0.013 | 0.281 ± 0.017^*^ | 0.251 ± 0.017^**^
Relative | 6.500 ± 0.240 | 6.816 ± 0.273 | 5.992 ± 0.257 | 5.833 ± 0.391
Liver
Absolute | 3.380 ± 0.173 | 3.359 ± 0.278 | 2.816 ± 0.197 | 2.670 ± 0.224
Relative | 65.087 ± 2.942 | 67.531 ± 3.669 | 59.640 ± 2.393 | 61.124 ± 2.834
Lung
Absolute | 0.228 ± 0.008 | 0.222 ± 0.006 | 0.226 ± 0.008 | 0.345 ± 0.097
Relative | 4.400 ± 0.186 | 4.619 ± 0.249 | 4.871 ± 0.252 | 8.894 ± 3.386
R. Testis
Absolute | 0.117 ± 0.002 | 0.116 ± 0.003 | 0.116 ± 0.004 | 0.112 ± 0.004
Relative | 2.265 ± 0.038 | 2.915 ± 0.137 | 2.478 ± 0.061 | 2.623 ± 0.165^*^
Thymus
Absolute | 0.051 ± 0.004 | 0.052 ± 0.003 | 0.048 ± 0.006 | 0.049 ± 0.005
Relative | 0.984 ± 0.066 | 1.069 ± 0.060 | 1.008 ± 0.109 | 1.129 ± 0.075
Female
n | 9 | 9 | 10 | 8
Necropsy body wt. | 45.8 ± 2.0 | 42.5 ± 2.1 | 43.0 ± 1.7 | 41.1 ± 2.0
Heart
Absolute | 0.205 ± 0.012 | 0.179 ± 0.006 | 0.203 ± 0.008 | 0.199 ± 0.009
Relative | 4.476 ± 0.185 | 4.274 ± 0.206 | 4.784 ± 0.286 | 4.876 ± 0.168
R. Kidney
Absolute | 0.254 ± 0.006 | 0.235 ± 0.007 | 0.237 ± 0.007 | 0.237 ± 0.006
Relative | 5.610 ± 0.218 | 5.593 ± 0.214 | 5.565 ± 0.201 | 5.851 ± 0.252
Liver
Absolute | 2.021 ± 0.086 | 1.719 ± 0.106 | 1.884 ± 0.064 | 2.104 ± 0.109
Relative | 44.213 ± 1.005 | 40.410 ± 1.539 | 44.190 ± 1.610 | 51.522 ± 2.221^*^
Lung
Absolute | 0.243 ± 0.014 | 0.280 ± 0.051 | 0.235 ± 0.014 | 0.228 ± 0.006
Relative | 5.322 ± 0.202 | 6.686 ± 1.256 | 5.612 ± 0.541 | 5.623 ± 0.274
Thymus
Absolute | 0.050 ± 0.002 | 0.056 ± 0.008 | 0.053 ± 0.004 | 0.047 ± 0.002
Relative | 1.103 ± 0.065 | 1.344 ± 0.200 | 1.244 ± 0.092 | 1.170 ± 0.063

* Significantly different (P≤0.05) from the control group by Williams’ or Dunnett’s test

** Significantly different (P≤0.01) from the control group by Williams’ test

a Organ weights (absolute weights) and body weights are given as grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

TABLE H9 Organ Weights and Organ-Weight-to-Body-Weight Ratios for p53 Haploinsufficient Mice in the 26-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Male
n | 15 | 15 | 15 | 15
Necropsy body wt. | 44.8 ± 1.3 | 44.7 ± 1.6 | 36.8 ± 1.2^**^ | 33.0 ± 1.5^**^
Heart
Absolute | 0.195 ± 0.008 | 0.192 ± 0.007 | 0.188 ± 0.007 | 0.162 ± 0.007^**^
Relative | 4.361 ± 0.136 | 4.356 ± 0.186 | 5.173 ± 0.237^**^ | 4.946 ± 0.148^**^
R. Kidney
Absolute | 0.253 ± 0.010 | 0.250 ± 0.007 | 0.232 ± 0.006 | 0.222 ± 0.011^*^
Relative | 5.654 ± 0.154 | 5.687 ± 0.231 | 6.350 ± 0.104^**^ | 6.745 ± 0.190^**^
Liver
Absolute | 1.923 ± 0.099 | 2.073 ± 0.144 | 1.682 ± 0.057 | 1.738 ± 0.111
Relative | 42.739 ± 1.224 | 45.844 ± 1.987 | 45.957 ± 1.085 | 52.180 ± 0.987^**^
Lung
Absolute | 0.291 ± 0.014 | 0.270 ± 0.011 | 0.270 ± 0.013 | 0.251 ± 0.013
Relative | 6.522 ± 0.299 | 6.225 ± 0.432 | 7.384 ± 0.324 | 7.730 ± 0.413^*^
R. Testis
Absolute | 0.115 ± 0.002 | 0.109 ± 0.002 | 0.110 ± 0.002 | 0.106 ± 0.003^**^
Relative | 2.593 ± 0.066 | 2.471 ± 0.075 | 3.027 ± 0.077^**^ | 3.249 ± 0.098^**^
Thymus
Absolute | 0.059 ± 0.002 | 0.061 ± 0.004 | 0.050 ± 0.002^*^ | 0.046 ± 0.004^**^
Relative | 1.330 ± 0.044 | 1.372 ± 0.069 | 1.355 ± 0.060 | 1.381 ± 0.084
Female
n | 15 | 14 | 14 | 14
Necropsy body wt. | 31.4 ± 1.5 | 30.8 ± 1.2 | 29.2 ± 1.2 | 30.3 ± 1.1
Heart
Absolute | 0.161 ± 0.005 | 0.149 ± 0.004 | 0.161 ± 0.008 | 0.165 ± 0.009
Relative | 5.294 ± 0.291 | 4.906 ± 0.150 | 5.603 ± 0.314 | 5.530 ± 0.343
R. Kidney
Absolute | 0.191 ± 0.005 | 0.185 ± 0.005 | 0.184 ± 0.006 | 0.185 ± 0.007
Relative | 6.209 ± 0.195 | 6.057 ± 0.145 | 6.398 ± 0.293 | 6.158 ± 0.224
Liver
Absolute | 1.390 ± 0.054 | 1.416 ± 0.039 | 1.451 ± 0.069 | 1.755 ± 0.088^**^
Relative | 44.780 ± 1.294 | 46.313 ± 0.869 | 49.536 ± 0.826^**^ | 57.653 ± 1.080^**^
Lung
Absolute | 0.287 ± 0.012 | 0.266 ± 0.013 | 0.259 ± 0.011 | 0.259 ± 0.011
Relative | 9.230 ± 0.316 | 8.720 ± 0.422 | 8.963 ± 0.401 | 8.726 ± 0.519
Thymus
Absolute | 0.057 ± 0.003 | 0.053 ± 0.003 | 0.054 ± 0.003 | 0.048 ± 0.003
Relative | 1.844 ± 0.079 | 1.763 ± 0.110 | 1.871 ± 0.092 | 1.606 ± 0.109

* Significantly different (P≤0.05) from the vehicle control group by Williams’ test

** P≤0.01

a Organ weights (absolute weights) and body weights are given as grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

TABLE H10 Organ Weights and Organ-Weight-to-Body-Weight Ratios for p53 Haploinsufficient Mice in the 41-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Male
n | 10 | 9 | 10 | 10
Necropsy body wt. | 49.8 ± 1.5 | 47.1 ± 1.7 | 44.3 ± 2.4^*^ | 38.2 ± 1.8^**^
Heart
Absolute | 0.197 ± 0.008 | 0.187 ± 0.006 | 0.184 ± 0.006 | 0.174 ± 0.007^*^
Relative | 3.973 ± 0.162 | 3.999 ± 0.126 | 4.256 ± 0.254 | 4.609 ± 0.219
R. Kidney
Absolute | 0.288 ± 0.014 | 0.278 ± 0.012 | 0.266 ± 0.010 | 0.246 ± 0.008^*^
Relative | 5.828 ± 0.324 | 5.912 ± 0.196 | 6.094 ± 0.204 | 6.562 ± 0.403
Liver
Absolute | 2.242 ± 0.171 | 2.183 ± 0.146 | 2.204 ± 0.154 | 2.453 ± 0.279
Relative | 44.629 ± 2.472 | 46.056 ± 1.699 | 49.417 ± 1.265 | 66.126 ± 10.219^**^
Lung
Absolute | 0.228 ± 0.012 | 0.239 ± 0.013 | 0.200 ± 0.015 | 0.226 ± 0.014
Relative | 4.608 ± 0.268 | 5.127 ± 0.348 | 4.674 ± 0.470 | 6.086 ± 0.566
R. Testis
Absolute | 0.112 ± 0.003 | 0.105 ± 0.003 | 0.107 ± 0.004 | 0.103 ± 0.003
Relative | 2.274 ± 0.106 | 2.245 ± 0.106 | 2.463 ± 0.104 | 2.760 ± 0.144^**^
Thymus
Absolute | 0.058 ± 0.005 | 0.056 ± 0.002 | 0.057 ± 0.005 | 0.048 ± 0.004
Relative | 1.163 ± 0.085 | 1.207 ± 0.067 | 1.338 ± 0.156 | 1.282 ± 0.151
Female
n | 9 | 9 | 8 | 9
Necropsy body wt. | 38.8 ± 3.2 | 34.0 ± 2.8 | 35.0 ± 1.9 | 34.9 ± 2.9
Heart
Absolute | 0.162 ± 0.008 | 0.163 ± 0.005 | 0.166 ± 0.005 | 0.161 ± 0.007
Relative | 4.326 ± 0.253 | 4.985 ± 0.354 | 4.828 ± 0.279 | 4.777 ± 0.318
R. Kidney
Absolute | 0.222 ± 0.011 | 0.217 ± 0.005 | 0.213 ± 0.006 | 0.196 ± 0.011
Relative | 5.888 ± 0.308 | 6.641 ± 0.450 | 6.180 ± 0.298 | 5.749 ± 0.331
Liver
Absolute | 1.656 ± 0.088 | 1.644 ± 0.087 | 1.755 ± 0.096 | 2.106 ± 0.170^*^
Relative | 43.721 ± 1.991 | 49.240 ± 1.661^*^ | 50.371 ± 1.614^**^ | 60.433 ± 1.162^**^
Lung
Absolute | 0.217 ± 0.012 | 0.213 ± 0.006 | 0.224 ± 0.011 | 0.217 ± 0.008
Relative | 5.825 ± 0.453 | 6.604 ± 0.540 | 6.568 ± 0.561 | 6.522 ± 0.561
Thymus
Absolute | 0.055 ± 0..005 | 0.048 ± 0.003 | 0.053 ± 0.005 | 0.044 ± 0.003
Relative | 1.442 ± 0.136 | 1.434 ± 0.118 | 1.523 ± 0.155 | 1.311 ± 0.113

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** Significantly different (P≤0.01) from the vehicle control group by Williams’ test

a Organ weights (absolute weights) and body weights are given as grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).