# APPENDIX G HEMATOLOGY RESULTS

TABLE G1 Hematology Data for Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Bromodichloromethane^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Male
n | 13 | 14 | 15 | 13
Automated hematocrit (%) | 44.2 ± 0.6 | 43.7 ± 0.7 | 43.5 ± 0.4 | 43.7 ± 0.4
Hemoglobin (g/dL) | 14.2 ± 0.2 | 14.1 ± 0.2 | 14.0 ± 0.1 | 14.0 ± 0.1
Erythrocytes (10^6^/μL) | 10.20 ± 0.24 | 10.04 ± 0.21 | 9.96 ± 0.12 | 10.01 ± 0.16
Reticulocytes (10^6^/μL) | 0.15 ± 0.01 | 0.14 ± 0.01 | 0.14 ± 0.01 | 0.15 ± 0.01
Nucleated erythrocytes (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.01 ± 0.01 | 0.00 ± 0.00
Mean cell volume (fL) | 43.5 ± 0.6 | 43.6 ± 0.5 | 43.7 ± 0.3 | 43.7 ± 0.5
Mean cell hemoglobin (pg) | 14.0 ± 0.2 | 14.1 ± 0.2 | 14.1 ± 0.1 | 14.0 ± 0.2
Mean cell hemoglobin concentration (g/dL) | 32.2 ± 0.1 | 32.2 ± 0.1 | 32.2 ± 0.1 | 32.0 ± 0.1
Platelets (10^3^/μL) | 1,011.2 ± 28.2 | 1,082.4 ± 83.5 | 984.9 ± 20.7 1 | 1,021.6 ± 37.8
Leukocytes (10^3^/μL) | 4.35 ± 0.61 | 3.89 ± 0.37 | 4.53 ± 0.40 | 4.07 ± 0.34
Segmented neutrophils (10^3^/μL) | 0.93 ± 0.18 | 0.94 ± 0.10 | 0.98 ± 0.13 | 0.75 ± 0.10
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 3.37 ± 0.43 | 2.91 ± 0.32 | 3.51 ± 0.31 | 3.27 ± 0.29
Monocytes (10^3^/μL) | 0.04 ± 0.02 | 0.02 ± 0.01 | 0.01 ± 0.01 | 0.02 ± 0.01
Basophils (10^3^/μL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL) | 0.01 ± 0.00 | 0.02 ± 0.01 | 0.02 ± 0.01 | 0.03 ± 0.01
Female
n | 11 | 10 | 12 | 10
Automated hematocrit (%) | 44.3 ± 0.6 | 43.8 ± 0.3 | 43.8 ± 0.6 | 45.0 ± 0.7
Hemoglobin (g/dL) | 14.6 ± 0.2 | 14.3 ± 0.1 | 14.3 ± 0.3 | 14.6 ± 0.2
Erythrocytes (10^6^/μL) | 9.90 ± 0.19 | 9.73 ± 0.11 | 9.82 ± 0.17 | 10.32 ± 0.24
Reticulocytes (10^6^/μL) | 0.17 ± 0.02 | 0.18 ± 0.02 | 0.20 ± 0.02 | 0.20 ± 0.02
Nucleated erythrocytes (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 44.9 ± 0.4 | 45.0 ± 0.3 | 44.6 ± 0.4 | 43.7 ± 0.6
Mean cell hemoglobin (pg) | 14.8 ± 0.2 | 14.7 ± 0.1 | 14.6 ± 0.2 | 14.2 ± 0.2
Mean cell hemoglobin concentration (g/dL) | 33.0 ± 0.2 | 32.6 ± 0.1 | 32.7 ± 0.2 | 32.4 ± 0.1^*^
Platelets (10^3^/μL) | 896.9 ± 53.5 | 937.3 ± 106.8 | 837.3 ± 34.1 | 924.2 ± 127.7
Leukocytes (10^3^/μL) | 4.29 ± 0.35 | 4.92 ± 0.56 | 4.19 ± 0.26 | 5.46 ± 0.77
Segmented neutrophils (10^3^/μL) | 0.86 ± 0.20 | 1.19 ± 0.32 | 0.89 ± 0.17 | 1.26 ± 0.42
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.05 ± 0.05
Lymphocytes (10^3^/μL) | 3.39 ± 0.20 | 3.66 ± 0.28 | 3.24 ± 0.18 | 4.08 ± 0.37
Monocytes (10^3^/μL) | 0.01 ± 0.01 | 0.04 ± 0.02 | 0.02 ± 0.01 | 0.05 ± 0.02
Basophils (10^3^/μL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL) | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.04 ± 0.02 | 0.03 ± 0.01

* Significantly different (P≤0.05) from the vehicle control group by Dunn’s test

a Mean ± standard error. Statistical tests were performed on unrounded data.

TABLE G2 Hematology Data for Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Male
n | 12 | 12 | 12 | 14
Automated hematocrit (%) | 41.9 ± 0.3 | 42.6 ± 0.8 | 43.0 ± 0.3 | 42.8 ± 0.4
Hemoglobin (g/dL) | 13.6 ± 0.1 | 13.8 ± 0.3 | 14.0 ± 0.1 | 14.0 ± 0.2
Erythrocytes (10^6^/μL) | 9.46 ± 0.12 | 9.60 ± 0.19 | 9.57 ± 0.09 | 9.55 ± 0.14
Reticulocytes (10^6^/μL) | 0.19 ± 0.01 | 0.24 ± 0.02 | 0.023 ± 0.02^*^ | 0.26 ± 0.02^**^
Nucleated erythrocytes (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 44.3 ± 0.4 | 44.4 ± 0.3 | 45.0 ± 0.3 | 44.8 ± 0.2
Mean cell hemoglobin (pg) | 14.4 ± 0.1 | 14.4 ± 0.1 | 14.6 ± 0.1 | 14.7 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 32.6 ± 0.1 | 32.4 ± 0.1 | 32.5 ± 0.1 | 32.8 ± 0.2
Platelets (10^3^/μL) | 1,201.8 ± 26.3 | 1,159.0 ± 55.1 | 1,112.5 ± 33.7^*^ | 1,050.4 ± 24.2^**^
Leukocytes (10^3^/μL) | 5.17 ± 0.28 | 5.29 ± 0.53 | 4.24 ± 0.52 | 4.16 ± 0.37
Segmented neutrophils (10^3^/μL) | 1.38 ± 0.12 | 1.62 ± 0.36 | 0.92 ± 0.19^**^ | 1.16 ± 0.27^*^
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 3.69 ± 0.28 | 3.57 ± 0.26 | 3.26 ± 0.32 | 2.92 ± 0.20
Monocytes (10^3^/μL) | 0.04 ± 0.01 | 0.04 ± 0.02 | 0.04 ± 0.02 | 0.02 ± 0.01
Basophils (10^3^/μL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL) | 0.06 ± 0.01 | 0.07 ± 0.02 | 0.03 ± 0.02^*^ | 0.05 ± 0.02
Female
n | 10 | 13 | 11 | 13
Automated hematocrit (%) | 43.5 ± 0.6 | 42.9 ± 0.6 | 45.2 ± 1.1 | 43.4 ± 0.6
Hemoglobin (g/dL) | 14.3 ± 0.2 | 14.1 ± 0.2 | 14.8 ± 0.4 | 14.2 ± 0.2
Erythrocytes (10^6^/μL) | 9.55 ± 0.18 | 9.31 ± 0.11 | 9.99 ± 0.29 | 9.52 ± 0.16
Reticulocytes (10^6^/μL) | 0.19 ± 0.02 | 0.17 ± 0.01 | 0.22 ± 0.02 | 0.20 ± 0.02
Nucleated erythrocytes (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 45.6 ± 0.4 | 46.1 ± 0.2 | 45.3 ± 0.5 | 45.6 ± 0.4
Mean cell hemoglobin (pg) | 15.0 ± 0.1 | 15.2 ± 0.1 | 14.9 ± 0.2 | 14.9 ± 0.2
Mean cell hemoglobin concentration (g/dL) | 32.8 ± 0.1 | 32.9 ± 0.1 | 32.8 ± 0.1 | 32.7 ± 0.1
Platelets (10^3^/μL) | 906.4 ± 30.3 | 961.4 ± 66.2 | 991.5 ± 95.9 | 961.1 ± 26.8
Leukocytes (10^3^/μL) | 3.69 ± 0.37 | 5.25 ± 0.75 | 4.23 ± 0.41 | 4.30 ± 0.40
Segmented neutrophils (10^3^/μL) | 0.87 ± 0.14 | 1.51 ± 0.74 | 0.83 ± 0.19 | 0.97 ± 0.36
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 2.77 ± 0.30 | 3.66 ± 0.20^*^ | 3.33 ± 0.31 | 3.25 ± 0.20
Monocytes (10^3^/μL) | 0.01 ± 0.01 | 0.05 ± 0.03 | 0.02 ± 0.01 | 0.03 ± 0.03
Basophils (10^3^/μL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL) | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.05 ± 0.01 | 0.05 ± 0.01

* Significantly different (P≤0.05) from the control group by Dunn’s or Shirley’s test

** P≤0.01

a Mean ± standard error. Statistical tests were performed on unrounded data.

TABLE G3 Hematology Data for Tg.AC Hemizygous Mice in the 26-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Male
n | 13 | 14 | 12 | 14
Automated hematocrit (%) | 43.9 ± 0.7 | 45.2 ± 0.6 | 42.9 ± 0.9 | 43.4 ± 0.8
Hemoglobin (g/dL) | 14.1 ± 0.3 | 14.5 ± 0.2 | 13.8 ± 0.3 | 14.0 ± 0.3
Erythrocytes (10^6^/μL) | 9.87 ± 0.22 | 9.95 ± 0.12 | 9.51 ± 0.29 | 9.41 ± 0.19
Reticulocytes (10^6^/μL) | 0.16 ± 0.02 | 0.17 ± 0.01 | 0.15 ± 0.01 | 0.015 ± 0.01
Nucleated erythrocytes (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 44.6 ± 0.4 | 45.4 ± 0.4 | 45.3 ± 0.5 | 46.1 ± 0.3^**^
Mean cell hemoglobin (pg) | 14.4 ± 0.1 | 14.6 ± 0.1 | 14.6 ± 0.2 | 14.9 ± 0.1^**^
Mean cell hemoglobin concentration (g/dL) | 32.2 ± 0.1 | 32.1 ± 0.1 | 32.2 ± 0.1 | 32.3 ± 0.1
Platelets (10^3^/μL) | 1,034.8 ± 35.2 | 990.4 ± 31.7 | 1,011.3 ± 31.4 | 1,053.4 ± 45.7
Leukocytes (10^3^/μL) | 2.43 ± 0.35 | 1.45 ± 0.30^*^ | 1.35 ± 0.90 | 2.56 ± 0.33
Segmented neutrophils (10^3^/μL) | 0.60 ± 0.18 | 0.35 ± 0.17 | 0.21 ± 0.03 | 0.60 ± 0.22
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 1.81 ± 0.27 | 1.09 ± 0.14^*^ | 1.12 ± 0.07 | 1.93 ± 0.22
Monocytes (10^3^/μL) | 0.00 ± 0.00 | 0.01 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Basophils (10^3^/μL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL) | 0.02 ± 0.00 | 0.01 ± 0.00 | 0.01 ± 0.00 | 0.03 ± 0.01
Female
n | 10 | 13 | 12 | 13
Automated hematocrit (%) | 45.4 ± 0.5 | 44.6 ± 1.0 | 44.0 ± 0.5 | 42.9 ± 0.8
Hemoglobin (g/dL) | 14.8 ± 0.2 | 14.6 ± 0.3 | 14.5 ± 0.2 | 14.0 ± 0.3
Erythrocytes (10^6^/μL) | 9.86 ± 0.14 | 9.74 ± 0.28 | 9.57 ± 0.12 | 9.35 ± 0.24
Reticulocytes (10^6^/μL) | 0.13 ± 0.01 | 0.14 ± 0.01 | 0.14 ± 0.01 | 0.15 ± 0.01
Nucleated erythrocytes (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 46.1 ± 0.3 | 46.0 ± 0.3 | 46.0 ± 0.2 | 46.0 ± 0.5
Mean cell hemoglobin (pg) | 15.0 ± 0.1 | 15.1 ± 0.2 | 15.1 ± 0.1 | 15.1 ± 0.2
Mean cell hemoglobin concentration (g/dL) | 32.7 ± 0.1 | 32.8 ± 0.1 | 32.9 ± 0.1 | 32.8 ± 0.1
Platelets (10^3^/μL) | 734.3 ± 58.7 | 859.1 ± 36.9^*^ | 894.7 ± 67.1^*^ | 1,015.8 ± 80.2^**^
Leukocytes (10^3^/μL) | 3.12 ± 0.26 | 3.50 ± 0.27 | 3.74 ± 0.24 | 4.36 ± 0.45
Segmented neutrophils (10^3^/μL) | 0.43 ± 0.13 | 0.35 ± 0.05 | 0.41 ± 0.08 | 0.56 ± 0.13
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 2.66 ± 0.20 | 3.13 ± 0.23 | 3.28 ± 0.23 | 3.75 ± 0.38^*^
Monocytes (10^3^/μL) | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.02 ± 0.01 | 0.03 ± 0.02
Basophils (10^3^/μL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL) | 0.02 ± 0.01 | 0.01 ± 0.01 | 0.03 ± 0.01 | 0.02 ± 0.01

* Significantly different (P≤0.05) from the vehicle control group by Dunn’s or Shirley’s test

** Significantly different (P≤0.01) from the vehicle control group by Shirley’s test

a Mean ± standard error. Statistical tests were performed on unrounded data.

TABLE G4 Hematology Data for p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Male
n | 15 | 14 | 15 | 15
Automated hematocrit (%) | 47.7 ± 0.3 | 47.5 ± 0.3 | 47.5 ± 0.3 | 46.3 ± 0.5^**^
Hemoglobin (g/dL) | 15.5 ± 0.1 | 15.4 ± 0.1 | 15.3 ± 0.1 | 15.0 ± 0.2^**^
Erythrocytes (10^6^/μL) | 10.60 ± 0.09 | 10.49 ± 0.07 | 10.59 ± 0.09 | 10.43 ± 0.08
Reticulocytes (10^6^/μL) | 0.09 ± 0.01 | 0.09 ± 0.013 | 0.10 ± 0.02 | 0.14 ± 0.02
Nucleated erythrocytes (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 45.1 ± 0.2 | 45.3 ± 0.1 | 44.9 ± 0.3 | 44.3 ± 0.2
Mean cell hemoglobin (pg) | 14.6 ± 0.1 | 14.7 ± 0.0 | 14.4 ± 0.1 | 14.3 ± 0.1^**^
Mean cell hemoglobin concentration (g/dL) | 32.5 ± 0.1 | 32.4 ± 0.1 | 32.2 ± 0.1^*^ | 32.4 ± 0.1
Platelets (10^3^/μL) | 911.9 ± 14.6 | 906.6 ± 15.3 | 898.7 ± 19.9 | 998.3 ± 44.1
Leukocytes (10^3^/μL) | 5.23 ± 0.49 | 5.07 ± 0.40 | 5.01 ± 0.33 | 5.03 ± 0.52
Segmented neutrophils (10^3^/μL) | 0.91 ± 0.08 | 0.87 ± 0.08 | 0.81 ± 0.06 | 0.89 ± 0.11
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 4.23 ± 0.42 | 4.10 ± 0.35 | 4.13 ± 0.34 | 4.04 ± 0.43
Monocytes (10^3^/μL) | 0.02 ± 0.01 | 0.02 ± 0.01 | 0.02 ± 0.01 | 0.01 ± 0.01
Basophils (10^3^/μL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL) | 0.06 ± 0.01 | 0.08 ± 0.02 | 0.05 ± 0.01 | 0.09 ± 0.02
Female
n | 15 | 15 | 14 | 15
Automated hematocrit (%) | 46.4 ± 0.4 | 46.6 ± 0.3 | 46.0 ± 0.3 | 45.9 ± 0.3
Hemoglobin (g/dL) | 15.1 ± 0.1 | 15.3 ± 0.1 | 15.1 ± 0.1 | 15.1 ± 0.1
Erythrocytes (10^6^/μL) | 10.30 ± 0.10 | 10.30 ± 0.08 | 10.20 ± 0.08 | 10.07 ± 0.08
Reticulocytes (10^6^/μL) | 0.09 ± 0.01 | 0.12 ± 0.02 | 0.10 ± 0.01 | 0.09 ± 0.01
Nucleated erythrocytes (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 45.1 ± 0.2 | 45.3 ± 0.2 | 45.2 ± 0.1 | 45.6 ± 0.2
Mean cell hemoglobin (pg) | 14.7 ± 0.1 | 14.9 ± 0.1 | 14.8 ± 0.1 | 15.0 ± 0.1^**^
Mean cell hemoglobin concentration (g/dL) | 32.6 ± 0.1 | 32.8 ± 0.1 | 32.8 ± 0.1 | 32.9 ± 0.1
Platelets (10^3^/μL) | 826.5 ± 23.7 | 819.3 ± 26.5 | 855.0 ± 27.5 | 912.8 ± 46.4
Leukocytes (10^3^/μL) | 3.79 ± 0.40 | 3.53 ± 0.21 | 4.29 ± 0.34 | 4.42 ± 0.41
Segmented neutrophils (10^3^/μL) | 0.46 ± 0.05 | 0.52 ± 0.05 | 0.50 ± 0.06 | 0.57 ± 0.06
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 3.27 ± 0.34 | 2.96 ± 0.18 | 3.75 ± 0.29 | 3.83 ± 0.36
Monocytes (10^3^/μL) | 0.00 ± 0.00 | 0.01 ± 0.00 | 0.01 ± 0.01 | 0.00 ± 0.00
Basophils (10^3^/μL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL) | 0.05 ± 0.02 | 0.04 ± 0.01 | 0.03 ± 0.01 | 0.02 ± 0.01

* Significantly different (P≤0.05) from the control group by Dunn’s test

** Significantly different (P≤0.01) from the control group by Shirley’s test

a Mean ± standard error. Statistical tests were performed on unrounded data.

TABLE G5 Hematology Data for p53 Haploinsufficient Mice in the 26-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Male
n | 15 | 15 | 15 | 15
Automated hematocrit (%) | 48.2 ± 0.6 | 47.7 ± 0.4 | 46.9 ± 0.4 | 46.5 ± 0.5
Hemoglobin (g/dL) | 15.5 ± 0.2 | 15.3 ± 0.2 | 15.1 ± 0.1 | 14.9 ± 0.2
Erythrocytes (10^6^/μL) | 10.69 ± 0.13 | 10.51 ± 0.12 | 10.39 ± 0.08 | 10.19 ± 0.11^**^
Reticulocytes (10^6^/μL) | 0.12 ± 12.1 | 0.12 ± 0.01 | 0.11 ± 0.01 | 0.11 ± 0.01
Nucleated erythrocytes (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 45.1 ± 0.2 | 45.5 ± 0.2 | 45.2 ± 0.2 | 45.6 ± 0.2
Mean cell hemoglobin (pg) | 14.5 ± 0.1 | 14.6 ± 0.1 | 14.6 ± 0.1 | 14.6 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 32.1 ± 0.1 | 32.1 ± 0.1 | 32.3 ± 0.1 | 32.1 ± 0.1
Platelets (10^3^/μL) | 983.1 ± 77.3 | 936.5 ± 35.8 | 1,001.0 ± 30.0^*^ | 1,055.4 ± 19.9^**^
Leukocytes (10^3^/μL) | 5.15 ± 0.31 | 6.31 ± 0.41^*^ | 5.60 ± 0.21 | 6.09 ± 0.41
Segmented neutrophils (10^3^/μL) | 0.45 ± 0.05 | 0.48 ± 0.05 | 0.46 ± 0.05 | 0.52 ± 0.05
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 4.64 ± 0.30 | 5.76 ± 0.38^*^ | 5.08 ± 0.22 | 5.51 ± 0.38
Monocytes (10^3^/μL) | 0.03 ± 0.01 | 0.04 ± 0.01 | 0.03 ± 0.01 | 0.04 ± 0.01
Basophils (10^3^/μL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL) | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.01
Female
n | 15 | 14 | 14 | 13
Automated hematocrit (%) | 46.9 ± 0.5 | 46.7 ± 0.5 | 46.6 ± 0.3 | 46.1 ± 0.7
Hemoglobin (g/dL) | 15.2 ± 0.2 | 15.2 ± 0.2 | 15.2 ± 0.1 | 15.0 ± 0.2
Erythrocytes (10^6^/μL) | 10.42 ± 0.13 | 10.29 ± 0.12 | 10.16 ± 0.10 | 10.09 ± 0.16
Reticulocytes (10^6^/μL) | 0.19 ± 0.01 | 0.18 ± 0.01 | 0.19 ± 0.01 | 0.18 ± 0.01
Nucleated erythrocytes (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 45.0 ± 0.2 | 45.4 ± 0.2 | 45.8 ± 0.3^**^ | 45.8 ± 0.2^**^
Mean cell hemoglobin (pg) | 14.6 ± 0.1 | 14.8 ± 0.1 | 15.0 ± 0.1^**^ | 14.9 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 32.5 ± 0.1 | 32.6 ± 0.2 | 32.6 ± 0.1 | 32.5 ± 0.2
Platelets (10^3^/μL) | 1,007.9 ± 91.9 | 947.4 ± 64.7 | 978.8 ± 55.3 | 998.3 ± 40.0
Leukocytes (10^3^/μL) | 3.15 ± 0.33 | 3.56 ± 0.14 | 3.19 ± 0.23 | 3.74 ± 0.20^*^
Segmented neutrophils (10^3^/μL) | 0.31 ± 0.04 | 0.37 ± 0.03 | 0.36 ± 0.03 | 0.40 ± 0.03
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 2.80 ± 0.29 | 3.14 ± 0.14 | 2.80 ± 0.21 | 3.32 ± 0.18^*^
Monocytes (10^3^/μL) | 0.01 ± 0.00 | 0.01 ± 0.01 | 0.01 ± 0.00 | 0.01 ± 0.01
Basophils (10^3^/μL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL) | 0.04 ± 0.02 | 0.03 ± 0.01 | 0.02 ± 0.01 | 0.02 ± 0.01

* Significantly different (P≤0.05) from the vehicle control group by Dunn’s or Shirley’s test

** Significantly different (P≤0.01) from the vehicle control group by Shirley’s test

a Mean ± standard error. Statistical tests were performed on unrounded data.