# APPENDIX F GENETIC TOXICOLOGY

TABLE F1 Frequency of Micronuclei in Normochromatic Erythrocytes and Percent Polychromatic Erythrocytes in Peripheral Blood of Tg.AC Hemizygous Mice Following Administration of Bromodichloromethane in Drinking Water for 26 Weeks^a^

Compound | Dose (mg/L) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | Pairwise P Value^c^ | PCEs^b^ (%)
Male
Water^d^ | | 13 | 1.19 ± 0.27 | | 2.9 ± 0.1
Bromodichloromethane | 175 | 12 | 0.92 ± 0.14 | 0.8280 | 3.6 ± 0.3
Bromodichloromethane | 350 | 12 | 1.83 ± 0.28 | 0.0321 | 3.4 ± 0.2
Bromodichloromethane | 700 | 14 | 1.79 ± 0.35 | 0.0375 | 3.0 ± 0.2
| | | P=0.008^e^
Female
Water | | 10 | 0.65 ± 0.18 | | 3.5 ± 0.3
Bromodichloromethane | 175 | 13 | 1.04 ± 0.22 | 0.0806 | 3.4 ± 0.2
Bromodichloromethane | 350 | 11 | 1.41 ± 0.15 | 0.0082 | 3.7 ± 0.3
Bromodichloromethane | 700 | 13 | 0.88 ± 0.20 | 0.1862 | 3.3 ± 0.3
| | | P=0.314

a Study was performed at SITEK Research Laboratories. The detailed protocol is presented by MacGregor et al. (1990). PCE=polychromatic erythrocyte, NCE=normochromatic erythrocyte

b Mean ± standard error

c Pairwise comparison with the untreated control group; significant at P≤0.008 (ILS, 1990)

d Untreated control

e Significance of micronucleated NCEs/1,000 NCEs tested by one-tailed trend test, significant at P≤0.025 (ILS, 1990)

TABLE F2 Frequency of Micronuclei in Normochromatic Erythrocytes and Percent Polychromatic Erythrocytes in Peripheral Blood of Tg.AC Hemizygous Mice Following Dermal Administration of Bromodichloromethane for 26 Weeks^a^

Compound | Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | Pairwise P Value^c^ | PCEs^b^ (%)
Male
Acetone^d^ | | 13 | 1.04 ± 0.24 | | 3.0 ± 0.2
Bromodichloromethane | 64 | 14 | 1.39 ± 0.21 | 0.1195 | 3.0 ± 0.2
Bromodichloromethane | 128 | 15 | 1.40 ± 0.18 | 0.1119 | 3.4 ± 0.2
Bromodichloromethane | 256 | 13 | 1.81 ± 0.21 | 0.0100 | 3.2 ± 0.2
| | | P=0.012^e^
Female
Acetone | | 11 | 0.77 ± 0.16 | | 3.5 ± 0.2
Bromodichloromethane | 64 | 10 | 1.25 ± 0.19 | 0.0611 | 3.5 ± 0.3
Bromodichloromethane | 128 | 12 | 1.25 ± 0.21 | 0.0547 | 3.6 ± 0.3
Bromodichloromethane | 256 | 10 | 1.25 ± 0.24 | 0.0611 | 3.3 ± 0.2
| | | P=0.103

a Study was performed at SITEK Research Laboratories. The detailed protocol is presented by MacGregor et al. (1990). PCE=polychromatic erythrocyte, NCE=normochromatic erythrocyte

b Mean ± standard error

c Pairwise comparison with the vehicle control group; significant at P≤0.008 (ILS, 1990)

d Vehicle control

e Significance of micronucleated NCEs/1,000 NCEs tested by one-tailed trend test, significant at P≤0.025 (ILS, 1990)

TABLE F3 Frequency of Micronuclei in Normochromatic Erythrocytes and Percent Polychromatic Erythrocytes in Peripheral Blood of Tg.AC Hemizygous Mice Following Treatment with Bromodichloromethane by Gavage for 26 Weeks^a^

Compound | Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | Pairwise P Value^c^ | PCEs^b^ (%)
Male
Corn oil^d^ | | 13 | 1.00 ± 0.21 | | 2.9 ± 0.2
Bromodichloromethane | 25 | 14 | 1.25 ± 0.14 | 0.1938 | 2.9 ± 0.2
Bromodichloromethane | 50 | 12 | 1.54 ± 0.23 | 0.0440 | 3.0 ± 0.2
Bromodichloromethane | 100 | 14 | 1.29 ± 0.22 | 0.1636 | 2.7 ± 0.2
| | | P=0.188^e^
Female
Corn oil | | 11 | 1.05 ± 0.24 | | 3.6 ± 0.2
Bromodichloromethane | 25 | 14 | 1.00 ± 0.19 | 0.5628 | 3.8 ± 0.6
Bromodichloromethane | 50 | 13 | 0.96 ± 0.24 | 0.6140 | 3.1 ± 0.2
Bromodichloromethane | 100 | 13 | 0.96 ± 0.20 | 0.6140 | 3.5 ± 0.3
| | | P=0.613

a Study was performed at SITEK Research Laboratories. The detailed protocol is presented by MacGregor et al. (1990). PCE=polychromatic erythrocyte, NCE=normochromatic erythrocyte

b Mean ± standard error.

c Pairwise comparison with the vehicle control group; significant at P≤0.008 (ILS, 1990)

d Vehicle control

e Significance of micronucleated NCEs/1,000 NCEs tested by one-tailed trend test, significant at P≤0.025 (ILS, 1990)

TABLE F4 Frequency of Micronuclei in Normochromatic Erythrocytes and Percent Polychromatic Erythrocytes in Peripheral Blood of p53 Haploinsufficient Mice Following Administration of Bromodichloromethane in Drinking Water for 26 Weeks^a^

Compound | Dose (mg/L) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | Pairwise P Value^c^ | PCEs^b^ (%)
Male
Water^d^ | | 15 | 1.13 ± 0.19 | | 2.9 ± 0.2
Bromodichloromethane | 175 | 14 | 1.36 ± 0.21 | 0.2222 | 2.7 ± 0.1
Bromodichloromethane | 350 | 15 | 2.23 ± 0.25 | 0.0005 | 2.8 ± 0.1
Bromodichloromethane | 700 | 15 | 1.57 ± 0.21 | 0.0742 | 3.0 ± 0.2
| | | P=0.057^e^
Female
Water | | 15 | 0.97 ± 0.19 | | 3.0 ± 0.2
Bromodichloromethane | 175 | 15 | 1.00 ± 0.17 | 0.4482 | 2.9 ± 0.1
Bromodichloromethane | 350 | 14 | 1.29 ± 0.19 | 0.1256 | 2.9 ± 0.2
Bromodichloromethane | 700 | 15 | 1.33 ± 0.14 | 0.0926 | 3.1 ± 0.1
| | | P=0.064

a Study was performed at SITEK Research Laboratories. The detailed protocol is presented by MacGregor et al. (1990). PCE=polychromatic erythrocyte, NCE=normochromatic erythrocyte

b Mean ± standard error.

c Pairwise comparison with the untreated control group; significant at P≤0.008 (ILS, 1990)

d Untreated control

e Significance of micronucleated NCEs/1,000 NCEs tested by one-tailed trend test, significant at P≤0.025 (ILS, 1990)

TABLE F5 Frequency of Micronuclei in Normochromatic Erythrocytes and Percent Polychromatic Erythrocytes in Peripheral Blood of p53 Haploinsufficient Mice Following Treatment with Bromodichloromethane by Gavage for 26 Weeks^a^

Compound | Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | Pairwise P Value^c^ | PCEs^b^ (%)
Male
Corn oil^d^ | | 15 | 1.67 ± 0.21 | | 2.8 ± 0.2
Bromodichloromethane | 25 | 15 | 1.67 ± 0.17 | 0.5000 | 2.6 ± 0.2
Bromodichloromethane | 50 | 15 | 1.47 ± 0.17 | 0.7322 | 2.6 ± 0.2
Bromodichloromethane | 100 | 15 | 1.60 ± 0.24 | 0.5801 | 2.6 ± 0.1
| | | P=0.615^e^
Female
Corn oil | | 15 | 1.07 ± 0.14 | | 3.1 ± 0.2
Bromodichloromethane | 25 | 14 | 0.86 ± 0.18 | 0.7916 | 2.9 ± 0.2
Bromodichloromethane | 50 | 14 | 1.11 ± 0.18 | 0.4412 | 3.0 ± 0.2
Bromodichloromethane | 100 | 14 | 1.25 ± 0.19 | 0.2580 | 2.9 ± 0.2
| | | P=0.161

a Study was performed at SITEK Research Laboratories. The detailed protocol is presented by MacGregor et al. (1990). PCE=polychromatic erythrocyte, NCE=normochromatic erythrocyte

b Mean ± standard error.

c Pairwise comparison with the vehicle control group; significant at P≤0.008 (ILS, 1990)

d Vehicle control

e Significance of micronucleated NCEs/1,000 NCEs tested by one-tailed trend test, significant at P≤0.025 (ILS, 1990)