# APPENDIX E SUMMARY OF LESIONS IN p53 HAPLOINSUFFICIENT MICE IN THE GAVAGE STUDIES OF BROMODICHLOROMETHANE

TABLE E1 Summary of the Incidence of Neoplasms in Male p53 Haploinsufficient Mice in the 26-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Survivors
Terminal sacrifice | 15 | 15 | 15 | 15
Animals examined microscopically | 15 | 15 | 15 | 15
Genital System
Epididymis | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | | | 1 (7%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Alveolar/bronchiolar carcinoma | | | | 1 (7%)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | | | 1 (7%)
Systems Examined with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Hematopoietic System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^c^ | | | | 2
Total primary neoplasms | | | | 2
Total animals with malignant neoplasms | | | | 2
Total malignant neoplasms | | | | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE E2 Summary of the Incidence of Nonneoplastic Lesions in Male p53 Haploinsufficient Mice in the 26-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Survivors
Terminal sacrifice | 15 | 15 | 15 | 15
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Infiltration cellular, lymphocyte | | | 2 (13%)
Inflammation | 13 (87%) | 14 (93%) | 13 (87%) | 15 (100%)
Necrosis | | | | 1 (7%)
Hepatocyte, fatty change | 10 (67%) | 9 (60%) | 4 (27%) | 11 (73%)
Hepatocyte, vacuolization cytoplasmic | 15 (100%) | 15 (100%) | 13 (87%) | 15 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Hyperkeratosis | | | | 1 (7%)
Inflammation | | 1 (7%) | 1 (7%) | 1 (7%)
Epithelium, hyperplasia | | 2 (13%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Hypertrophy | 6 (40%) | 2 (13%)
Subcapsular, hyperplasia | 2 (13%) | 6 (40%) | 6 (40%) | 3 (20%)
Pituitary gland | (14) | (15) | (15) | (15)
Cyst | 1 (7%) | 4 (27%) | | 2 (13%)
Thyroid gland | (15) | (15) | (15) | (15)
Inflammation | 1 (7%)
Genital System
Epididymis | (15) | (15) | (15) | (15)
Granuloma sperm | 2 (13%)
Inflammation | 1 (7%) | | | 1 (7%)
Testes | (15) | (15) | (15) | (15)
Inflammation, granulomatous | | 1 (7%)
Mineralization | | 1 (7%)
Germinal epithelium, degeneration | 3 (20%) | 2 (13%) | 1 (7%) | 1 (7%)
Hematopoietic System
Spleen | (15) | (15) | (15) | (15)
Lymphoid follicle, hyperplasia | | | | 1 (7%)
Thymus | (15) | (15) | (15) | (15)
Cyst | 11 (73%) | 9 (60%) | 9 (60%) | 11 (73%)
Nervous System
Brain | | | | (1)
Hydrocephalus | | | | 1 (100%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Inflammation | | | | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Casts protein | 2 (13%) | | 5 (33%) | 2 (13%)
Hydronephrosis | | 1 (7%)
Nephropathy | 8 (53%) | 9 (60%) | 8 (53%) | 8 (53%)
Renal tubule, degeneration | | | | 4 (27%)
Renal tubule, vacuolization cytoplasmic | 12 (80%) | 5 (33%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Integumentary System
Musculoskeletal System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE E3 Summary of the Incidence of Neoplasms in Female p53 Haploinsufficient Mice in the 26-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Accidental death | | | 1
Moribund | | 1 | | 1
Survivors
Terminal sacrifice | 15 | 14 | 14 | 14
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Osteosarcoma, metastatic, uncertain primary site | | | | 1 (7%)
Hematopoietic System
Lymph node | | | | (2)
Lumbar, osteosarcoma, metastatic, uncertain primary site | | | | 1 (50%)
Integumentary System
Skin | | | | (2)
Subcutaneous tissue, osteosarcoma | | | | 1 (50%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Osteosarcoma, metastatic, uncertain primary site | | | | 1 (7%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Genital System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^b^ | | | | 1
Total primary neoplasms | | | | 1
Total animals with malignant neoplasms | | | | 1
Total malignant neoplasms | | | | 1
Total animals with metastatic neoplasms | | | | 1
Total metastatic neoplasms | | | | 3
Total animals with malignant neoplasms uncertain primary site | | | | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE E4 Summary of the Incidence of Nonneoplastic Lesions in Female p53 Haploinsufficient Mice in the 26-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Accidental death | | | 1
Moribund | | 1 | | 1
Survivors
Terminal sacrifice | 15 | 14 | 14 | 14
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Esophagus | | | (1)
Hyperkeratosis | | | 1 (100%)
Liver | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | | | 2 (13%)
Infiltration cellular, lymphocyte | 5 (33%) | 4 (27%) | 3 (20%)
Inflammation | 14 (93%) | 15 (100%) | 14 (93%) | 14 (93%)
Hepatocyte, fatty change | 2 (13%) | 2 (13%) | 3 (20%) | 11 (73%)
Hepatocyte, vacuolization cytoplasmic | 10 (67%) | 9 (60%) | 10 (67%) | 13 (87%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Inflammation | | | 1 (7%) | 1 (7%)
Epithelium, hyperplasia | | | | 1 (7%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Subcapsular, hyperplasia | 14 (93%) | 15 (100%) | 12 (80%) | 14 (93%)
Parathyroid gland | | | (2)
Cyst | | | 2 (100%)
Pituitary gland | (15) | (15) | (15) | (15)
Cyst | | | 1 (7%)
Hyperplasia | | 1 (7%)
Thyroid gland | (15) | (15) | (15) | (15)
Ectopic thymus | 1 (7%) | | | 1 (7%)
Inflammation | 3 (20%) | 1 (7%) | 1 (7%)
General Body System
Peritoneum | | | | (1)
Inflammation | | | | 1 (100%)
Genital System
Ovary | (15) | (15) | (15) | (15)
Cyst | 2 (13%) | 1 (7%) | 2 (13%) | 2 (13%)
Uterus | (15) | (15) | (15) | (15)
Inflammation | 2 (13%) | 2 (13%)
Necrosis | | | | 1 (7%)
Thrombosis | | | | 1 (7%)
Endometrium, hyperplasia, cystic | 9 (60%) | 9 (60%) | 12 (80%) | 10 (67%)
Hematopoietic System
Lymph node | | | | (2)
Mediastinal, atrophy | | | | 1 (50%)
Lymph node, mandibular | (15) | (15) | (15) | (15)
Atrophy | | | | 1 (7%)
Lymph node, mesenteric | (15) | (15) | (15) | (14)
Atrophy | | | | 1 (7%)
Spleen | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | | 2 (13%) | 2 (13%)
Thymus | (15) | (15) | (15) | (15)
Atrophy | | | | 2 (13%)
Cyst | 6 (40%) | 5 (33%) | 9 (60%) | 7 (47%)
Hyperplasia, atypical | | | | 1 (7%)
Necrosis | | | 1 (7%)
Integumentary System
Skin | | | | (2)
Subcutaneous tissue, edema | | | | 1 (50%)
Nervous System
Brain | | | | (1)
Hydrocephalus | | | | 1 (100%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Infiltration cellular, lymphocyte | 3 (20%) | | 2 (13%) | 1 (7%)
Infiltration cellular, histiocyte | 1 (7%) | | | 1 (7%)
Inflammation | 1 (7%)
Pleura | | | (1)
Inflammation, suppurative | | | 1 (100%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Casts protein | 12 (80%) | 11 (73%) | 7 (47%) | 7 (47%)
Hydronephrosis | | | | 1 (7%)
Inflammation | | 1 (7%)
Nephropathy | 1 (7%) | 3 (20%) | 1 (7%)
Systems Examined with No Lesions Observed
Cardiovascular System
Musculoskeletal System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE E5 Summary of the Incidence of Neoplasms in Male p53 Haploinsufficient Mice in the 41-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early death
Moribund | | 1
Survivors
Terminal sacrifice | 10 | 9 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Intestine small, duodenum | (10) | (10) | (10) | (9)
Intestine small, jejunum | (10) | (10) | (10) | (9)
Liver | (10) | (10) | (10) | (10)
Hepatocellular adenoma | 2 (20%)
Mesentery | (1) | (1)
Fibrosarcoma | | 1 (100%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Adenoma | | | | 1 (10%)
Integumentary System
Skin | | | | (1)
Squamous cell papilloma | | | | 1 (100%)
Musculoskeletal System
Skeletal muscle | | (1)
Sarcoma | | 1 (100%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Alveolar/bronchiolar adenoma | | | | 1 (10%)
Systemic Lesions
Multiple organs | (10) | (10) | (10) | (10)
Lymphoma malignant | 1 (10%) | | 1 (10%) | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Genital System
Hematopoietic System
Nervous System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 3 | 2 | 1 | 4
Total primary neoplasms | 3 | 2 | 1 | 4
Total animals with benign neoplasms | 2 | | | 3
Total benign neoplasms | 2 | | | 3
Total animals with malignant neoplasms | 1 | 2 | 1 | 1
Total malignant neoplasms | 1 | 2 | 1 | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE E6 Summary of the Incidence of Nonneoplastic Lesions in Male p53 Haploinsufficient Mice in the 41-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early death
Moribund | | 1
Survivors
Terminal sacrifice | 10 | 9 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | | 1 (10%)
Infiltration cellular, lymphocyte | 2 (20%) | 3 (30%) | 1 (10%) | 3 (30%)
Inflammation | 7 (70%) | 9 (90%) | 9 (90%) | 9 (90%)
Necrosis | | | | 1 (10%)
Hepatocyte, fatty change | 6 (60%) | 6 (60%) | 5 (50%) | 10 (100%)
Hepatocyte, vacuolization cytoplasmic | 10 (100%) | 9 (90%) | 10 (100%) | 10 (100%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Hypertrophy | 3 (30%) | 2 (20%) | 2 (20%) | 1 (10%)
Subcapsular, hyperplasia | 2 (20%) | | 1 (10%) | 2 (20%)
Parathyroid gland | (1)
Cyst | 1 (100%)
Pituitary gland | (10) | (10) | (10) | (10)
Cyst | 4 (40%) | 2 (20%) | 3 (30%) | 1 (10%)
Genital System
Epididymis | (10) | (10) | (10) | (10)
Infiltration cellular, lymphocyte | 1 (10%) | 1 (10%)
Inflammation | | | 1 (10%)
Testes | (10) | (10) | (10) | (10)
Mineralization | | 2 (20%) | 1 (10%)
Germinal epithelium, degeneration | 2 (20%) | 5 (50%) | 2 (20%) | 2 (20%)
Hematopoietic System
Lymph node, mandibular | (9) | (10) | (10) | (10)
Infiltration cellular, polymorphonuclear | | | | 1 (10%)
Spleen | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | | 1 (10%)
Thymus | (9) | (10) | (9) | (10)
Cyst | 6 (67%) | 7 (70%) | 6 (67%) | 4 (40%)
Epithelial cell, hyperplasia | | 1 (10%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Infiltration cellular, lymphocyte | 1 (10%) | 1 (10%)
Alveolar epithelium, hyperplasia | | | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Casts protein | 1 (10%) | 2 (20%)
Cyst | 1 (10%)
Mineralization | | | | 1 (10%)
Nephropathy | 4 (40%) | 3 (30%) | 4 (40%) | 9 (90%)
Renal tubule, degeneration | | 1 (10%) | | 10 (100%)
Renal tubule, dilatation | | 1 (10%)
Renal tubule, vacuolization cytoplasmic | 8 (80%) | 5 (50%) | 1 (10%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE E7 Summary of the Incidence of Neoplasms in Female p53 Haploinsufficient Mice in the 41-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Accidental death | | | 1
Moribund | | 1 | 1 | 1
Natural death | 1
Survivors
Terminal sacrifice | 9 | 9 | 8 | 9
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Histiocytic sarcoma | | | 1 (10%)
Mesentery | | | (1)
Histiocytic sarcoma | | | 1 (100%)
Pancreas | | | (1)
Histiocytic sarcoma | | | 1 (100%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Histiocytic sarcoma | | | 1 (10%)
Pituitary gland | (10) | (10) | (10) | (10)
Adenoma | | 1 (10%)
Genital System
Ovary | (10) | (10) | (10) | (10)
Histiocytic sarcoma | | | 1 (10%)
Uterus | (10) | (10) | (10) | (10)
Histiocytic sarcoma | | | 1 (10%)
Hematopoietic System
Lymph node, mesenteric | (10) | (10) | (10) | (10)
Histiocytic sarcoma | | | 1 (10%)
Spleen | (10) | (10) | (10) | (10)
Musculoskeletal System
Bone | (1) | (2) | | (1)
Osteoma | | 1 (50%)
Osteosarcoma | 1 (100%) | 1 (50%) | | 1 (100%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Histiocytic sarcoma | | | 1 (10%)
Osteosarcoma, metastatic, bone | 1 (10%)
Alveolar epithelium, adenoma | | | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Histiocytic sarcoma | | | 1 (10%)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Histiocytic sarcoma | | | 1 (10%)
Lymphoma malignant | | 1 (10%) | 2 (20%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Integumentary System
Nervous System
Special Senses System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 1 | 4 | 4 | 1
Total primary neoplasms | 1 | 4 | 4 | 1
Total animals with benign neoplasms | | 2 | 1
Total benign neoplasms | | 2 | 1
Total animals with malignant neoplasms | 1 | 2 | 3 | 1
Total malignant neoplasms | 1 | 2 | 3 | 1
Total animals with metastatic neoplasms | 1
Total metastatic neoplasms | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE E8 Summary of the Incidence of Nonneoplastic Lesions in Female p53 Haploinsufficient Mice in the 41-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Accidental death | | | 1
Moribund | | 1 | 1 | 1
Natural death | 1
Survivors
Terminal sacrifice | 9 | 9 | 8 | 9
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Esophagus | | | (1)
Perforation | | | 1 (100%)
Liver | (10) | (10) | (10) | (10)
Infiltration cellular, lymphocyte | 3 (30%) | 2 (20%) | 3 (30%)
Inflammation | 6 (60%) | 10 (100%) | 7 (70%) | 8 (80%)
Necrosis | | 2 (20%) | 1 (10%)
Hepatocyte, fatty change | 3 (30%) | 3 (30%) | 6 (60%) | 9 (90%)
Hepatocyte, vacuolization cytoplasmic | 9 (90%) | 10 (100%) | 9 (90%) | 10 (100%)
Mesentery | | | (1)
Inflammation, suppurative | | | 1 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Hyperkeratosis | | | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Subcapsular, hyperplasia | 10 (100%) | 9 (90%) | 9 (90%) | 10 (100%)
Parathyroid gland | (1)
Cyst | 1 (100%)
Pituitary gland | (10) | (10) | (10) | (10)
Cyst | | | 1 (10%)
Thyroid gland | (10) | (10) | (10) | (10)
Inflammation | 1 (10%)
Genital System
Ovary | (10) | (10) | (10) | (10)
Atrophy | 1 (10%) | 1 (10%)
Cyst | | | 3 (30%) | 1 (10%)
Oviduct | (2) | | (1)
Infiltration cellular, lymphocyte | 2 (100%) | | 1 (100%)
Uterus | (10) | (10) | (10) | (10)
Inflammation | 2 (20%) | 2 (20%) | 1 (10%) | 1 (10%)
Endometrium, hyperplasia, cystic | 9 (90%) | 8 (80%) | 8 (80%) | 10 (100%)
Hematopoietic System
Lymph node, mandibular | (10) | (10) | (10) | (10)
Hyperplasia | | 1 (10%)
Lymph node, mesenteric | (10) | (10) | (10) | (10)
Atrophy | 1 (10%) | | | 1 (10%)
Spleen | (10) | (10) | (10) | (10)
Atrophy | 1 (10%)
Hematopoietic cell proliferation | 1 (10%) | 1 (10%) | 1 (10%)
Thymus | (9) | (10) | (10) | (10)
Atrophy | 1 (11%) | 2 (20%) | 2 (20%) | 1 (10%)
Cyst | 6 (67%) | 8 (80%) | 8 (80%) | 8 (80%)
Necrosis | | | 1 (10%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Infiltration cellular, lymphocyte | 1 (10%) | 2 (20%) | 1 (10%)
Alveolar epithelium, hyperplasia | | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Accumulation, hyaline droplet | | | 1 (10%)
Casts protein | 7 (70%) | 4 (40%) | 6 (60%) | 6 (60%)
Mineralization | 1 (10%)
Nephropathy | 2 (20%) | 3 (30%) | 1 (10%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion