# APPENDIX D SUMMARY OF LESIONS IN p53 HAPLOINSUFFICIENT MICE IN THE DRINKING WATER STUDIES OF BROMODICHLOROMETHANE

TABLE D1 Summary of the Incidence of Neoplasms in Male p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Survivors
Terminal sacrifice | 15 | 15 | 15 | 15
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Hepatocellular adenoma | 1 (7%)
Endocrine System
Thyroid gland | (15) | (14) | (15) | (15)
Follicular cell, carcinoma | 1 (7%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Genital System
Hematopoietic System
Integumentary System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^b^ | 2
Total primary neoplasms | 2
Total animals with benign neoplasms | 1
Total benign neoplasms | 1
Total animals with malignant neoplasms | 1
Total malignant neoplasms | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE D2 Summary of the Incidence of Nonneoplastic Lesions in Male p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Survivors
Terminal sacrifice | 15 | 15 | 15 | 15
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Inflammation | 12 (80%) | 14 (93%) | 13 (87%) | 13 (87%)
Hepatocyte, fatty change | 4 (27%) | 5 (33%) | 1 (7%)
Hepatocyte, vacuolization cytoplasmic | 15 (100%) | 15 (100%) | 13 (87%) | 11 (73%)
Mesentery | | | (1)
Fat, necrosis | | | 1 (100%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Hyperplasia | | 2 (13%)
Hypertrophy | | 2 (13%) | | 2 (13%)
Subcapsular, hyperplasia | 2 (13%) | 3 (20%) | 1 (7%) | 3 (20%)
Pituitary gland | (15) | (15) | (15) | (15)
Cyst | 3 (20%) | 1 (7%) | 1 (7%) | 4 (27%)
Thyroid gland | (15) | (14) | (15) | (15)
Cyst | 1 (7%)
Genital System
Epididymis | (15) | (15) | (15) | (15)
Granuloma sperm | | 1 (7%) | | 1 (7%)
Inflammation | | | 1 (7%)
Testes | (15) | (15) | (15) | (15)
Mineralization | | 1 (7%) | 1 (7%) | 2 (13%)
Germinal epithelium, degeneration | | 2 (13%) | | 1 (7%)
Hematopoietic System
Thymus | (15) | (15) | (15) | (15)
Cyst | 9 (60%) | 12 (80%) | 6 (40%) | 9 (60%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Fibrosis | | 1 (7%)
Infiltration cellular, histiocyte | | 1 (7%)
Alveolar epithelium, hyperplasia | | 1 (7%)
Special Senses System
Eye | | (1)
Cataract | | 1 (100%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Casts protein | 1 (7%) | 5 (33%) | 4 (27%) | 7 (47%)
Cyst | | | | 1 (7%)
Mineralization | | | | 1 (7%)
Nephropathy | 7 (47%) | 3 (20%) | 11 (73%) | 13 (87%)
Cortex, crystals | | | | 1 (7%)
Renal tubule, degeneration | | | 9 (60%) | 12 (80%)
Renal tubule, dilatation | | 5 (33%) | 4 (27%) | 6 (40%)
Renal tubule, vacuolization cytoplasmic | 14 (93%) | 1 (7%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Integumentary System
Musculoskeletal System
Nervous System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE D3 Summary of the Incidence of Neoplasms in Female p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early death
Natural death | | | 1
Survivors
Terminal sacrifice | 15 | 15 | 14 | 15
Animals examined microscopically | 15 | 15 | 15 | 15
Genital System
Uterus | (15) | (15) | (15) | (15)
Polyp stromal | | 2 (13%) | | 1 (7%)
Polyp stromal, multiple | 1 (7%)
Systems Examined with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Hematopoietic System
Integumentary System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^b^ | 1 | 2 | | 1
Total primary neoplasms | 1 | 2 | | 1
Total animals with benign neoplasms | 1 | 2 | | 1
Total benign neoplasms | 1 | 2 | | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE D4 Summary of the Incidence of Nonneoplastic Lesions in Female p53 Haploinsufficient Mice in the 26-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early death
Natural death | | | 1
Survivors
Terminal sacrifice | 15 | 15 | 14 | 15
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Infiltration cellular, lymphocyte | 1 (7%) | 4 (27%) | 4 (27%) | 1 (7%)
Inflammation | 13 (87%) | 13 (87%) | 12 (80%) | 12 (80%)
Necrosis | | 2 (13%) | 2 (13%) | 1 (7%)
Hepatocyte, fatty change | | 1 (7%) | 1 (7%) | 10 (67%)
Hepatocyte, vacuolization cytoplasmic | 11 (73%) | 10 (67%) | 7 (47%) | 11 (73%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Subcapsular, hyperplasia | 13 (87%) | 12 (80%) | 14 (93%) | 14 (93%)
Parathyroid gland | | (1)
Cyst | | 1 (100%)
Pituitary gland | (15) | (15) | (15) | (15)
Cyst | | | 1 (7%) | 2 (13%)
Thyroid gland | (15) | (15) | (15) | (14)
Cyst | | 1 (7%)
C-cell, hyperplasia | | 1 (7%)
Genital System
Ovary | (15) | (15) | (15) | (15)
Angiectasis | | | | 1 (7%)
Cyst | 2 (13%) | 1 (7%) | 2 (13%) | 5 (33%)
Uterus | (15) | (15) | (15) | (15)
Inflammation | 1 (7%) | | 1 (7%) | 1 (7%)
Endometrium, hyperplasia, cystic | 8 (53%) | 7 (47%) | 9 (60%) | 8 (53%)
Hematopoietic System
Spleen | (15) | (15) | (15) | (15)
Lymphoid follicle, atrophy | | | 1 (7%)
Lymphoid follicle, hyperplasia | | | | 1 (7%)
Thymus | (15) | (15) | (15) | (15)
Atrophy | | | 1 (7%)
Cyst | 6 (40%) | 11 (73%) | 9 (60%) | 11 (73%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Congestion | | | 1 (7%)
Infiltration cellular, lymphocyte | 1 (7%) | 1 (7%) | 1 (7%)
Inflammation | | | | 1 (7%)
Thrombosis | | | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Casts protein | 3 (20%) | 10 (67%) | 7 (47%) | 6 (40%)
Nephropathy | 2 (13%) | 2 (13%) | 2 (13%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE D5 Summary of the Incidence of Neoplasms in Male p53 Haploinsufficient Mice in the 42-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 1 | | | 3
Natural death | | | 1
Survivors
Terminal sacrifice | 9 | 10 | 9 | 7
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Intestine small, duodenum | (10) | (10) | (10) | (10)
Intestine small, jejunum | (10) | (10) | (9) | (10)
Intestine small, ileum | (10) | (10) | (10) | (10)
Liver | (10) | (10) | (10) | (10)
Hepatocellular adenoma | | 1 (10%) | 1 (10%)
Mesentery | | | (1)
Genital System
Epididymis | (10) | (10) | (10) | (10)
Prostate | | | | (1)
Sarcoma | | | | 1 (100%)
Musculoskeletal System
Skeletal muscle | | | (1)
Rhabdomyosarcoma | | | 1 (100%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Alveolar/bronchiolar carcinoma | | | | 1 (10%)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Lymphoma malignant | 1 (10%) | | 2 (20%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Hematopoietic System
Integumentary System
Nervous System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 1 | 1 | 4 | 2
Total primary neoplasms | 1 | 1 | 4 | 2
Total animals with benign neoplasms | | 1 | 1
Total benign neoplasms | | 1 | 1
Total animals with malignant neoplasms | 1 | | 3 | 2
Total malignant neoplasms | 1 | | 3 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE D6 Summary of the Incidence of Nonneoplastic Lesions in Male p53 Haploinsufficient Mice in the 42-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 1 | | | 3
Natural death | | | 1
Survivors
Terminal sacrifice | 9 | 10 | 9 | 7
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Esophagus | | | | (1)
Muscularis, degeneration | | | | 1 (100%)
Liver | (10) | (10) | (10) | (10)
Atypia cellular | | | | 1 (10%)
Clear cell focus | | 1 (10%)
Hematopoietic cell proliferation | | | | 1 (10%)
Infiltration cellular, lymphocyte | 1 (10%) | 2 (20%)
Inflammation | 9 (90%) | 5 (50%) | 7 (70%) | 6 (60%)
Necrosis | | | | 2 (20%)
Hepatocyte, fatty change | 8 (80%) | 4 (40%) | 3 (30%) | 4 (40%)
Hepatocyte, vacuolization cytoplasmic | 9 (90%) | 10 (100%) | 10 (100%) | 9 (90%)
Salivary glands | | | | (2)
Inflammation | | | | 2 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Inflammation | | | | 1 (10%)
Epithelium, hyperplasia | 1 (10%) | 1 (10%) | 1 (10%) | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Hyperplasia | | 1 (10%)
Hypertrophy | 2 (20%) | 4 (40%) | 2 (20%)
Subcapsular, hyperplasia | 2 (20%) | 2 (20%) | 3 (30%) | 2 (20%)
Islets, pancreatic | | (1)
Hyperplasia | | 1 (100%)
Parathyroid gland | | (1)
Cyst | | 1 (100%)
Pituitary gland | (10) | (9) | (10) | (10)
Cyst | 4 (40%) | 3 (33%) | 3 (30%) | 3 (30%)
Genital System
Testes | (10) | (10) | (10) | (10)
Mineralization | | 1 (10%)
Germinal epithelium, degeneration | 2 (20%) | 2 (20%) | 1 (10%) | 3 (30%)
Hematopoietic System
Lymph node, mandibular | (10) | (10) | (10) | (10)
Atrophy | | | | 1 (10%)
Lymph node, mesenteric | (10) | (10) | (10) | (10)
Atrophy | 1 (10%) | | | 2 (20%)
Spleen | (10) | (10) | (10) | (10)
Atrophy | | | | 3 (30%)
Hematopoietic cell proliferation | 1 (10%)
Thymus | (10) | (10) | (10) | (10)
Atrophy | | | 1 (10%) | 3 (30%)
Cyst | 8 (80%) | 7 (70%) | 3 (30%) | 4 (40%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Alveolar epithelium, hyperplasia | | | 1 (10%)
Special Senses System
Harderian gland | | | | (1)
Inflammation | | | | 1 (100%)
Lacrimal gland | (1) | | | (1)
Inflammation | 1 (100%) | | | 1 (100%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Casts protein | | | 1 (10%)
Hydronephrosis | | | 1 (10%) | 1 (10%)
Infiltration cellular, lymphocyte | 1 (10%)
Mineralization | | | 1 (10%) | 1 (10%)
Nephropathy | 5 (50%) | 4 (40%) | 9 (90%) | 8 (80%)
Renal tubule, degeneration | | | 6 (60%) | 10 (100%)
Renal tubule, dilatation | 1 (10%) | | 3 (30%) | 2 (20%)
Renal tubule, necrosis | | | | 1 (10%)
Renal tubule, vacuolization cytoplasmic | 10 (100%) | 5 (50%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Integumentary System
Musculoskeletal System
Nervous System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE D7 Summary of the Incidence of Neoplasms in Female p53 Haploinsufficient Mice in the 42-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 1 | 1 | | 1
Natural death | | | | 1
Survivors
Terminal sacrifice | 9 | 9 | 10 | 8
Animals examined microscopically | 10 | 10 | 10 | 10
Genital System
Uterus | (10) | (10) | (10) | (10)
Polyp stromal | 2 (20%)
Hematopoietic System
Lymph node | (1) | (2)
Carcinoma, metastatic, skin | 1 (100%)
Mediastinal, osteosarcoma, metastatic, bone | | 1 (50%)
Renal, carcinoma, metastatic, skin | 1 (100%)
Integumentary System
Mammary gland | | | | (1)
Carcinoma | | | | 1 (100%)
Skin | (1)
Carcinoma | 1 (100%)
Musculoskeletal System
Bone | | (2)
Vertebra, osteosarcoma | | 2 (100%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Carcinoma, metastatic, skin | 1 (10%)
Osteosarcoma, metastatic, bone | | 1 (10%)
Osteosarcoma, metastatic, uncertain primary site | 1 (10%)
Pleura | | (1)
Osteosarcoma, metastatic, bone | | 1 (100%)
Systems Examined with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Nervous System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^b^ | 3 | 2 | | 1
Total primary neoplasms | 3 | 2 | | 1
Total animals with benign neoplasms | 2
Total benign neoplasms | 2
Total animals with malignant neoplasms | 1 | 2 | | 1
Total malignant neoplasms | 1 | 2 | | 1
Total animals with metastatic neoplasms | 2 | 1
Total metastatic neoplasms | 4 | 3
Total animals with malignant neoplasms of uncertain primary site | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE D8 Summary of the Incidence of Nonneoplastic Lesions in Female p53 Haploinsufficient Mice in the 42-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 1 | 1 | | 1
Natural death | | | | 1
Survivors
Terminal sacrifice | 9 | 9 | 10 | 8
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 2 (20%) | 1 (10%) | | 1 (10%)
Infiltration cellular | | 1 (10%)
Infiltration cellular, lymphocyte | 2 (20%) | 4 (40%) | 4 (40%) | 2 (20%)
Inflammation | 8 (80%) | 7 (70%) | 8 (80%) | 7 (70%)
Necrosis | 3 (30%) | 2 (20%) | 1 (10%) | 1 (10%)
Hepatocyte, fatty change | 2 (20%) | 2 (20%) | 3 (30%) | 6 (60%)
Hepatocyte, vacuolization cytoplasmic | 9 (90%) | 9 (90%) | 10 (100%) | 8 (80%)
Serosa, inflammation | | | | 1 (10%)
Mesentery | | (1) | | (1)
Inflammation | | | | 1 (100%)
Fat, necrosis | | 1 (100%)
Salivary glands | | | (1)
Atrophy | | | 1 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Hyperkeratosis | | 1 (10%) | | 2 (20%)
Inflammation | | | 1 (10%)
Epithelium, hyperplasia | | 2 (20%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Subcapsular, hyperplasia | 9 (90%) | 10 (100%) | 10 (100%) | 8 (80%)
Pituitary gland | (10) | (10) | (10) | (10)
Cyst | 1 (10%)
Hyperplasia | | | | 1 (10%)
Pars intermedia, hyperplasia | | | 1 (10%)
Thyroid gland | (10) | (10) | (10) | (10)
Inflammation | | | 1 (10%)
Genital System
Ovary | (10) | (9) | (10) | (10)
Angiectasis | | 1 (11%)
Atrophy | | | | 1 (10%)
Cyst | 3 (30%) | 2 (22%) | 1 (10%) | 2 (20%)
Uterus | (10) | (10) | (10) | (10)
Inflammation | 2 (20%) | 1 (10%) | 2 (20%) | 1 (10%)
Endometrium, hyperplasia, cystic | 8 (80%) | 8 (80%) | 8 (80%) | 6 (60%)
Hematopoietic System
Lymph node | (1) | (2)
Mediastinal, infiltration cellular, plasma cell | | 1 (50%)
Lymph node, mandibular | (10) | (10) | (10) | (9)
Atrophy | 1 (10%)
Hematopoietic cell proliferation | | 1 (10%)
Hyperplasia, atypical | | | 1 (10%)
Lymph node, mesenteric | (10) | (10) | (10) | (10)
Atrophy | 1 (10%)
Hematopoietic cell proliferation | 1 (10%) | 1 (10%)
Spleen | (10) | (10) | (10) | (10)
Atrophy | | | | 1 (10%)
Hematopoietic cell proliferation | 2 (20%) | 1 (10%) | | 2 (20%)
Thymus | (10) | (9) | (10) | (10)
Atrophy | 2 (20%) | 1 (11%) | | 2 (20%)
Cyst | 7 (70%) | 6 (67%) | 8 (80%) | 8 (80%)
Integumentary System
Skin | (1)
Ulcer | 1 (100%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Hemorrhage | | 1 (10%)
Infiltration cellular, lymphocyte | 1 (10%) | | | 1 (10%)
Infiltration cellular, histiocyte | | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Accumulation, hyaline droplet | | | | 1 (10%)
Casts protein | 8 (80%) | 1 (10%) | 5 (50%) | 3 (30%)
Infiltration cellular, lymphocyte | 1 (10%) | 4 (40%) | | 1 (10%)
Mineralization | | | | 1 (10%)
Nephropathy | 3 (30%) | 1 (10%) | 8 (80%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion