# APPENDIX C SUMMARY OF LESIONS IN Tg.AC HEMIZYGOUS MICE IN THE GAVAGE STUDIES OF BROMODICHLOROMETHANE

TABLE C1 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 26-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Accidental death | 1
Moribund | 1 | 1 | 3
Survivors
Died last week of study | | | | 1
Terminal sacrifice | 13 | 14 | 12 | 14
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Stomach, forestomach | (15) | (15) | (15) | (15)
Squamous cell papilloma | 4 (27%) | 2 (13%) | 2 (13%) | 5 (33%)
Squamous cell papilloma, multiple | 5 (33%) | 3 (20%) | 9 (60%) | 7 (47%)
Tooth | (3) | (2) | (3) | (3)
Odontogenic tumor | 2 (67%) | 2 (100%) | 3 (100%) | 2 (67%)
Sarcoma | 1 (33%)
Integumentary System
Skin | (1) | (1) | (1) | (5)
Squamous cell papilloma | | 1 (100%) | | 4 (80%)
Squamous cell papilloma, multiple | 1 (100%) | | | 1 (20%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Alveolar/bronchiolar adenoma | | | 1 (7%) | 1 (7%)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15)
Leukemia erythrocytic | 1 (7%) | | | 1 (7%)
Lymphoma malignant | | 1 (7%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 11 | 6 | 13 | 14
Total primary neoplasms | 14 | 9 | 15 | 21
Total animals with benign neoplasms | 9 | 5 | 11 | 13
Total benign neoplasms | 10 | 6 | 12 | 18
Total animals with malignant neoplasms | 2 | 1 | | 1
Total malignant neoplasms | 2 | 1 | | 1
Total animals with uncertain neoplasms-benign or malignant | 2 | 2 | 3 | 2
Total uncertain neoplasms | 2 | 2 | 3 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE C2 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 26-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Accidental death | 1
Moribund | 1 | 1 | 3
Survivors
Died last week of study | | | | 1
Terminal sacrifice | 13 | 14 | 12 | 14
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Esophagus | (1)
Inflammation | 1 (100%)
Liver | (15) | (15) | (15) | (15)
Cyst | | | | 1 (7%)
Hematopoietic cell proliferation | | 1 (7%)
Inflammation | 6 (40%) | 7 (47%) | 9 (60%) | 8 (53%)
Necrosis | 1 (7%) | | 1 (7%)
Hepatocyte, fatty change | 1 (7%)
Hepatocyte, vacuolization cytoplasmic | 3 (20%) | 1 (7%) | 3 (20%) | 3 (20%)
Mesentery | (1) | | (1)
Fat, necrosis | 1 (100%) | | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Hyperkeratosis | 1 (7%)
Tooth | (3) | (2) | (3) | (3)
Inflammation | | | | 1 (33%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Hypertrophy | 6 (40%) | 8 (53%) | 5 (33%) | 7 (47%)
Subcapsular, hyperplasia | | 2 (13%)
Pituitary gland | (15) | (15) | (15) | (15)
Cyst | 2 (13%) | 2 (13%) | 1 (7%) | 1 (7%)
Thyroid gland | (15) | (15) | (15) | (15)
Cyst | 2 (13%) | 2 (13%) | | 1 (7%)
Genital System
Epididymis | (15) | (15) | (15) | (15)
Inflammation | | | 1 (7%)
Preputial gland | | | (2)
Cyst | | | 1 (50%)
Duct, ectasia | | | 1 (50%)
Testes | (15) | (15) | (15) | (15)
Germinal epithelium, degeneration | 1 (7%) | 4 (27%) | 1 (7%)
Hematopoietic System
Lymph node, mandibular | (15) | (15) | (15) | (15)
Atrophy | | | | 1 (7%)
Hyperplasia | 1 (7%) | | | 2 (13%)
Infiltration cellular, plasma cell | | 2 (13%)
Lymph node, mesenteric | (15) | (14) | (15) | (15)
Atrophy | 1 (7%) | | | 1 (7%)
Spleen | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | 1 (7%) | 1 (7%) | 2 (13%)
Lymphoid follicle, atrophy | 1 (7%) | | 1 (7%)
Thymus | (14) | (15) | (15) | (15)
Atrophy | 2 (14%) | 1 (7%) | 3 (20%) | 2 (13%)
Cyst | 7 (50%) | 5 (33%) | 4 (27%) | 8 (53%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Edema | | 1 (7%)
Inflammation | | | | 1 (7%)
Alveolar epithelium, hyperplasia | | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Casts protein | 3 (20%) | | | 6 (40%)
Cyst | | 1 (7%)
Hydronephrosis | | 1 (7%)
Nephropathy | 2 (13%) | 8 (53%) | 3 (20%) | 4 (27%)
Artery, inflammation | | 1 (7%)
Renal tubule, degeneration | | | | 4 (27%)
Renal tubule, dilatation | 2 (13%) | 1 (7%) | 5 (33%) | 4 (27%)
Renal tubule, hypertrophy | | | 4 (27%) | 1 (7%)
Renal tubule, necrosis | | | | 1 (7%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE C3 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 26-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Accidental deaths | 1 | | | 1
Moribund | 1 | | | 1
Natural deaths | 2 | 1 | 2
Survivors
Terminal sacrifice | 11 | 14 | 13 | 13
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Salivary glands | (1) | | | (1)
Duct, carcinoma | 1 (100%) | | | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Squamous cell papilloma | 3 (20%) | 3 (20%) | 4 (27%)
Squamous cell papilloma, multiple | 3 (20%) | 5 (33%) | 6 (40%) | 11 (73%)
Tooth | (4) | | (3) | (2)
Odontogenic tumor | 4 (100%) | | 3 (100%) | 2 (100%)
Genital System
Ovary | (15) | (15) | (15) | (15)
Uterus | (15) | (15) | (15) | (15)
Polyp stromal | | 1 (7%)
Integumentary System
Skin | (1) | (3) | (6) | (2)
Squamous cell papilloma | 1 (100%) | 1 (33%) | 5 (83%) | 2 (100%)
Squamous cell papilloma, multiple | | 2 (67%)
Special Senses System
Zymbal’s gland | | | (1)
Adenoma | | | 1 (100%)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15)
Leukemia erythrocytic | 2 (13%) | 2 (13%) | 1 (7%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Hematopoietic System
Musculoskeletal System
Nervous System
Respiratory System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 10 | 10 | 12 | 13
Total primary neoplasms | 14 | 14 | 20 | 16
Total animals with benign neoplasms | 7 | 9 | 12 | 12
Total benign neoplasms | 7 | 12 | 16 | 13
Total animals with malignant neoplasms | 3 | 2 | 1 | 1
Total malignant neoplasms | 3 | 2 | 1 | 1
Total animals with uncertain neoplasms-benign or malignant | 4 | | 3 | 2
Total uncertain neoplasms | 4 | | 3 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE C4 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 26-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Accidental deaths | 1 | | | 1
Moribund | 1 | | | 1
Natural deaths | 2 | 1 | 2
Survivors
Terminal sacrifice | 11 | 14 | 13 | 13
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Esophagus | (1) | | | (1)
Perforation | 1 (100%) | | | 1 (100%)
Liver | (15) | (15) | (15) | (15)
Basophilic focus | 1 (7%)
Cyst | | | 1 (7%)
Hematopoietic cell proliferation | 1 (7%) | | 1 (7%) | 1 (7%)
Hemorrhage | | 1 (7%)
Hepatodiaphragmatic nodule | | 1 (7%)
Inflammation | 11 (73%) | 13 (87%) | 13 (87%) | 13 (87%)
Necrosis | 1 (7%) | | 4 (27%) | 1 (7%)
Hepatocyte, fatty change | | 5 (33%) | 8 (53%) | 7 (47%)
Hepatocyte, vacuolization cytoplasmic | | 6 (40%) | 4 (27%) | 3 (20%)
Salivary glands | (1) | | | (1)
Atrophy | | | | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Hyperkeratosis | 1 (7%)
Epithelium, hyperplasia | | 1 (7%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Mineralization | | 1 (7%)
Subcapsular, hyperplasia | 7 (47%) | 10 (67%) | 8 (53%) | 6 (40%)
Parathyroid gland | | (1)
Cyst | | 1 (100%)
Pituitary gland | (15) | (15) | (15) | (15)
Angiectasis | | | 1 (7%)
Cyst | 1 (7%) | | 1 (7%) | 2 (13%)
Thyroid gland | (15) | (15) | (15) | (15)
Cyst | 2 (13%) | 2 (13%) | 3 (20%) | 1 (7%)
Genital System
Ovary | (15) | (15) | (15) | (15)
Atrophy | | | | 1 (7%)
Cyst | 4 (27%) | 2 (13%) | 4 (27%) | 4 (27%)
Uterus | (15) | (15) | (15) | (15)
Atrophy | | | | 1 (7%)
Inflammation | | 1 (7%)
Endometrium, hyperplasia, cystic | 12 (80%) | 9 (60%) | 12 (80%) | 13 (87%)
Hematopoietic System
Lymph node, mandibular | (14) | (15) | (15) | (15)
Hyperplasia | | | | 1 (7%)
Infiltration cellular, plasma cell | 1 (7%) | | | 1 (7%)
Lymph node, mesenteric | (14) | (15) | (15) | (15)
Atrophy | | 1 (7%)
Spleen | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | | 2 (13%) | 1 (7%)
Lymphoid follicle, atrophy | 3 (20%) | | | 1 (7%)
Thymus | (13) | (15) | (15) | (15)
Atrophy | 2 (15%) | 3 (20%) | 1 (7%) | 3 (20%)
Cyst | 2 (15%) | 5 (33%) | 5 (33%) | 2 (13%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Inflammation | | | 2 (13%)
Thrombosis | | | | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Casts protein | 4 (27%) | 5 (33%) | 5 (33%) | 4 (27%)
Cyst | | | 1 (7%) | 2 (13%)
Mineralization | | | | 1 (7%)
Nephropathy | 1 (7%) | 3 (20%) | 3 (20%) | 1 (7%)
Renal tubule, degeneration | | | 1 (7%)
Renal tubule, dilatation | 1 (7%)
Renal tubule, hypertrophy | 1 (7%) | 1 (7%) | 1 (7%) | 8 (53%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE C5 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 41-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Accidental deaths | 1 | 3
Moribund | 3 | 1 | 4 | 2
Survivors
Terminal sacrifice | 6 | 6 | 6 | 8
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Intestine large, rectum | (1) | (1) | (1) | (1)
Anus, squamous cell papilloma | | | | 1 (100%)
Liver | (10) | (10) | (10) | (10)
Salivary glands | (2) | | (2) | (1)
Duct, carcinoma | 2 (100%) | | 2 (100%) | 1 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Squamous cell papilloma | 2 (20%) | 1 (10%) | 4 (40%) | 1 (10%)
Squamous cell papilloma, multiple | 6 (60%) | 5 (50%) | 5 (50%) | 5 (50%)
Tooth | (4) | (2) | (4) | (4)
Odontogenic tumor | 4 (100%) | 2 (100%) | 4 (100%) | 4 (100%)
Integumentary System
Skin | (5) | (6) | (5) | (7)
Squamous cell papilloma | 1 (20%) | 2 (33%) | | 4 (57%)
Squamous cell papilloma, multiple | 4 (80%) | 4 (67%) | 4 (80%) | 2 (29%)
Special Senses System
Harderian gland | | | (1)
Adenoma | | | 1 (100%)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Leukemia erythrocytic | | | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Musculoskeletal System
Nervous System
Respiratory System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 10 | 7 | 10 | 10
Total primary neoplasms | 19 | 14 | 21 | 18
Total animals with benign neoplasms | 8 | 6 | 10 | 7
Total benign neoplasms | 13 | 12 | 14 | 13
Total animals with malignant neoplasms | 2 | | 3 | 1
Total malignant neoplasms | 2 | | 3 | 1
Total animals with uncertain neoplasms-benign or malignant | 4 | 2 | 4 | 4
Total uncertain neoplasms | 4 | 2 | 4 | 4

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE C6 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 41-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Accidental deaths | 1 | 3
Moribund | 3 | 1 | 4 | 2
Survivors
Terminal sacrifice | 6 | 6 | 6 | 8
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 2 (20%) | | 1 (10%) | 1 (10%)
Inflammation | 7 (70%) | 6 (60%) | 8 (80%) | 5 (50%)
Necrosis | | 2 (20%)
Hepatocyte, fatty change | | | 2 (20%)
Hepatocyte, vacuolization cytoplasmic | 6 (60%) | 3 (30%) | 7 (70%) | 7 (70%)
Hepatocyte, vacuolization cytoplasmic, diffuse | | 2 (20%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Hyperkeratosis | 2 (20%) | | 3 (30%) | 2 (20%)
Epithelium, hyperplasia | 2 (20%) | | 3 (30%) | 2 (20%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Hypertrophy | 7 (70%) | 3 (30%) | 6 (60%) | 7 (70%)
Subcapsular, hyperplasia | | 1 (10%) | 2 (20%)
Pituitary gland | (10) | (10) | (10) | (10)
Cyst | 1 (10%) | 1 (10%) | | 1 (10%)
Thyroid gland | (10) | (10) | (10) | (10)
Cyst | 2 (20%) | | 1 (10%) | 1 (10%)
Genital System
Epididymis | (10) | (10) | (10) | (10)
Atrophy | 1 (10%) | | | 1 (10%)
Preputial gland | | | (1)
Inflammation, suppurative | | | 1 (100%)
Testes | (10) | (10) | (10) | (10)
Germinal epithelium, degeneration | 2 (20%) | 1 (10%) | | 1 (10%)
Hematopoietic System
Lymph node, mandibular | (10) | (9) | (9) | (10)
Hematopoietic cell proliferation | 1 (10%)
Hyperplasia | 1 (10%) | 1 (11%) | 1 (11%) | 1 (10%)
Infiltration cellular, plasma cell | 1 (10%) | | 2 (22%) | 1 (10%)
Lymph node, mesenteric | (10) | (10) | (10) | (10)
Hyperplasia | 1 (10%)
Spleen | (10) | (10) | (10) | (10)
Atrophy | | 1 (10%)
Hematopoietic cell proliferation | 4 (40%) | | 2 (20%) | 1 (10%)
Thymus | (9) | (10) | (10) | (10)
Atrophy | 3 (33%) | 3 (30%) | 3 (30%) | 2 (20%)
Cyst | 4 (44%) | 2 (20%) | 2 (20%) | 3 (30%)
Integumentary System
Skin | (5) | (6) | (5) | (7)
Hyperplasia | | 1 (17%) | 2 (40%) | 4 (57%)
Inflammation | | | | 1 (14%)
Subcutaneous tissue, fibrosis | | | | 1 (14%)
Nervous System
Peripheral nerve | | | (1)
Degeneration | | | 1 (100%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Inflammation | 1 (10%) | 1 (10%) | 2 (20%)
Alveolar epithelium, hyperplasia | | | | 1 (10%)
Perivascular, inflammation | | 1 (10%) | 1 (10%)
Pleura | | (3)
Inflammation, suppurative | | 3 (100%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Casts protein | 3 (30%) | 1 (10%) | | 1 (10%)
Cyst | | 1 (10%) | 2 (20%)
Nephropathy | 3 (30%) | 4 (40%) | 6 (60%) | 6 (60%)
Glomerulus, inflammation, membranoproliferative | | | 1 (10%)
Renal tubule, degeneration | | | | 6 (60%)
Renal tubule, dilatation | | 2 (20%) | 2 (20%) | 4 (40%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE C7 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 41-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 1 | | | 2
Natural deaths | 2 | 1 | 1 | 1
Survivors
Terminal sacrifice | 7 | 9 | 9 | 7
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Salivary glands | | | | (3)
Duct, carcinoma | | | | 3 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Squamous cell papilloma | 3 (30%) | 1 (10%) | 3 (30%) | 1 (10%)
Squamous cell papilloma, multiple | 1 (10%) | 6 (60%) | 5 (50%) | 9 (90%)
Tooth | (4) | (3) | (3) | (2)
Odontogenic tumor | 4 (100%) | 3 (100%) | 3 (100%) | 2 (100%)
Hematopoietic System
Lymph node | | | | (1)
Mediastinal, squamous cell carcinoma, metastatic, skin | | | | 1 (100%)
Lymph node, mandibular | (10) | (10) | (10) | (9)
Squamous cell carcinoma, metastatic, skin | | | | 1 (11%)
Spleen | (10) | (10) | (10) | (10)
Integumentary System
Skin | (6) | (5) | (7) | (7)
Squamous cell carcinoma | | | | 1 (14%)
Squamous cell papilloma | 3 (50%) | 2 (40%) | 2 (29%) | 3 (43%)
Squamous cell papilloma, multiple | 3 (50%) | 2 (40%) | 4 (57%) | 4 (57%)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Leukemia erythrocytic | | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Genital System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 10 | 7 | 9 | 10
Total primary neoplasms | 14 | 15 | 17 | 23
Total animals with benign neoplasms | 8 | 7 | 9 | 10
Total benign neoplasms | 10 | 11 | 14 | 17
Total animals with malignant neoplasms | | 1 | | 4
Total malignant neoplasms | | 1 | | 4
Total animals with metastatic neoplasms | | | | 1
Total metastatic neoplasms | | | | 2
Total animals with uncertain neoplasms-benign or malignant | 4 | 3 | 3 | 2
Total uncertain neoplasms | 4 | 3 | 3 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE C8 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 41-Week Gavage Study of Bromodichloromethane^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 1 | | | 2
Natural deaths | 2 | 1 | 1 | 1
Survivors
Terminal sacrifice | 7 | 9 | 9 | 7
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Gallbladder | | (1)
Inflammation, chronic active | | 1 (100%)
Intestine large, colon | (10) | (10) | (10) | (10)
Inflammation | 1 (10%)
Intestine large, cecum | (10) | (10) | (10) | (10)
Edema | 1 (10%)
Inflammation | 1 (10%)
Intestine small, ileum | (10) | (10) | (10) | (10)
Ulcer | 1 (10%)
Liver | (10) | (10) | (10) | (10)
Cytomegaly | | | | 1 (10%)
Hematopoietic cell proliferation | 1 (10%) | 2 (20%) | | 3 (30%)
Inflammation | 8 (80%) | 9 (90%) | 10 (100%) | 6 (60%)
Necrosis | 2 (20%) | 2 (20%) | 1 (10%) | 1 (10%)
Hepatocyte, fatty change | | 2 (20%) | 8 (80%) | 5 (50%)
Hepatocyte, vacuolization cytoplasmic | 6 (60%) | 9 (90%) | 10 (100%) | 9 (90%)
Mesentery | (1)
Hemorrhage | 1 (100%)
Artery, inflammation | 1 (100%)
Artery, thrombosis | 1 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Hyperkeratosis | 1 (10%) | 2 (20%) | 4 (40%) | 4 (40%)
Epithelium, hyperplasia | 1 (10%) | 2 (20%) | 4 (40%) | 4 (40%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 1 (10%) | | | 1 (10%)
Subcapsular, hyperplasia | 5 (50%) | 6 (60%) | 4 (40%) | 7 (70%)
Islets, pancreatic | | | | (1)
Hyperplasia | | | | 1 (100%)
Pituitary gland | (10) | (10) | (10) | (10)
Cyst | 2 (20%) | 1 (10%) | 1 (10%)
Thyroid gland | (10) | (10) | (10) | (10)
Cyst | 2 (20%) | 5 (50%) | 2 (20%) | 2 (20%)
Genital System
Ovary | (10) | (10) | (10) | (10)
Amyloid deposition | | | | 1 (10%)
Atrophy | | 1 (10%)
Cyst | 1 (10%) | | 3 (30%) | 1 (10%)
Inflammation, suppurative | | | 1 (10%)
Oviduct | | | | (1)
Inflammation, suppurative | | | | 1 (100%)
Uterus | (10) | (10) | (10) | (10)
Inflammation | | 1 (10%) | | 1 (10%)
Inflammation, granulomatous | | | | 1 (10%)
Endometrium, hyperplasia, cystic | 7 (70%) | 10 (100%) | 9 (90%) | 8 (80%)
Hematopoietic System
Lymph node, mandibular | (10) | (10) | (10) | (9)
Hyperplasia | | | 1 (10%)
Infiltration cellular, plasma cell | 2 (20%) | 1 (10%) | | 2 (22%)
Lymph node, mesenteric | (10) | (10) | (10) | (10)
Atrophy | | 1 (10%) | | 1 (10%)
Ectasia | 1 (10%)
Spleen | (10) | (10) | (10) | (10)
Atrophy | 2 (20%) | | | 1 (10%)
Hematopoietic cell proliferation | 1 (10%) | 2 (20%) | | 5 (50%)
Thymus | (10) | (10) | (10) | (9)
Atrophy | 2 (20%) | 1 (10%) | | 4 (44%)
Cyst | 3 (30%) | 2 (20%) | 5 (50%) | 3 (33%)
Integumentary System
Mammary gland | | | | (1)
Inflammation, granulomatous | | | | 1 (100%)
Skin | (6) | (5) | (7) | (7)
Hyperplasia | 1 (17%) | 3 (60%) | | 2 (29%)
Epidermis, hyperplasia, focal | | 1 (20%) | 1 (14%)
Subcutaneous tissue, hemorrhage | | | 1 (14%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Inflammation | | | | 1 (10%)
Perivascular, inflammation | 2 (20%) | | | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Amyloid deposition | | | 1 (10%)
Casts protein | 1 (10%) | 2 (20%) | 6 (60%)
Cyst | | | 1 (10%)
Infiltration cellular, lymphocyte | | 1 (10%)
Nephropathy | 3 (30%) | 4 (40%) | | 5 (50%)
Renal tubule, hypertrophy | | | | 1 (10%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion