# APPENDIX B SUMMARY OF LESIONS IN Tg.AC HEMIZYGOUS MICE IN THE DRINKING WATER STUDIES OF BROMODICHLOROMETHANE

TABLE B1 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | 3 | 3 | 1
Survivors
Terminal sacrifice | 13 | 12 | 12 | 14
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Salivary glands | (1) | (2) | | (1)
Duct, carcinoma | | 2 (100%) | | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Squamous cell papilloma | 3 (20%) | 3 (20%) | 5 (33%) | 3 (20%)
Squamous cell papilloma, multiple | 2 (13%) | 2 (13%) | 1 (7%) | 1 (7%)
Tooth | (4) | (4) | (3) | (2)
Odontogenic tumor | 4 (100%) | 4 (100%) | 3 (100%) | 2 (100%)
Integumentary System
Skin | (6) | (2) | (2) | (1)
Squamous cell papilloma | 2 (33%) | 2 (100%) | 1 (50%)
Squamous cell papilloma, multiple | 4 (67%) | | | 1 (100%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Carcinoma, metastatic, salivary glands | | 1 (7%)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15)
Leukemia erythrocytic | | 1 (7%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 9 | 11 | 9 | 7
Total primary neoplasms | 15 | 14 | 10 | 8
Total animals with benign neoplasms | 9 | 6 | 7 | 5
Total benign neoplasms | 11 | 7 | 7 | 5
Total animals with malignant neoplasms | | 3 | | 1
Total malignant neoplasms | | 3 | | 1
Total animals with metastatic neoplasms | | 1
Total metastatic neoplasms | | 1
Total animals with uncertain neoplasms-benign or malignant | 4 | 4 | 3 | 2
Total uncertain neoplasms | 4 | 4 | 3 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B2 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | 3 | 3 | 1
Survivors
Terminal sacrifice | 13 | 12 | 12 | 14
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Esophagus | (1)
Hyperkeratosis | 1 (100%)
Intestine small, duodenum | (15) | (15) | (15) | (15)
Erosion | | | | 1 (7%)
Liver | (15) | (15) | (15) | (15)
Cyst | | | | 1 (7%)
Hematopoietic cell proliferation | 1 (7%) | 1 (7%)
Inflammation | 7 (47%) | 6 (40%) | 7 (47%) | 5 (33%)
Necrosis | 3 (20%) | 1 (7%) | 3 (20%) | 3 (20%)
Hepatocyte, vacuolization cytoplasmic | 6 (40%) | 4 (27%) | 3 (20%) | 3 (20%)
Salivary glands | (1) | (2) | | (1)
Inflammation | 1 (100%)
Inflammation, chronic active | | 1 (50%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Epithelium, hyperplasia | | | | 1 (7%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Hyperplasia | 1 (7%)
Hypertrophy | 6 (40%) | 7 (47%) | 7 (47%) | 9 (60%)
Subcapsular, hyperplasia | | 1 (7%) | 1 (7%) | 1 (7%)
Pituitary gland | (15) | (15) | (15) | (15)
Cyst | | 1 (7%)
Inflammation, suppurative | 1 (7%)
Necrosis | 1 (7%)
Thyroid gland | (15) | (15) | (15) | (15)
Cyst | 2 (13%) | 1 (7%) | | 1 (7%)
Genital System
Epididymis | (15) | (15) | (15) | (15)
Inflammation | | | 1 (7%)
Preputial gland | (3) | | | (1)
Inflammation | 2 (67%) | | | 1 (100%)
Duct, ectasia | 3 (100%) | | | 1 (100%)
Testes | (15) | (15) | (15) | (15)
Hypoplasia | | 1 (7%)
Germinal epithelium, degeneration | 3 (20%) | 2 (13%) | 3 (20%) | 3 (20%)
Hematopoietic System
Lymph node, mandibular | (15) | (15) | (14) | (13)
Hyperplasia | | 1 (7%)
Infiltration cellular, plasma cell | | 1 (7%) | 1 (7%)
Inflammation | 1 (7%)
Necrosis | | 1 (7%)
Spleen | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | 4 (27%) | 2 (13%)
Lymphoid follicle, atrophy | 1 (7%) | | | 1 (7%)
Thymus | (15) | (14) | (15) | (15)
Atrophy | | 1 (7%) | 1 (7%) | 1 (7%)
Integumentary System
Skin | (6) | (2) | (2) | (1)
Epidermis, hyperplasia, focal | | | 1 (50%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Inflammation | 1 (7%) | | 1 (7%) | 1 (7%)
Thrombosis | | | 1 (7%) | 1 (7%)
Alveolar epithelium, hyperplasia | 1 (7%) | 2 (13%)
Special Senses System
Eye | | (1)
Retina, degeneration | | 1 (100%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Casts protein | 1 (7%) | 2 (13%) | 1 (7%) | 1 (7%)
Cyst | | 2 (13%) | 3 (20%)
Mineralization | | | | 2 (13%)
Nephropathy | 4 (27%) | 3 (20%) | 4 (27%) | 11 (73%)
Renal tubule, degeneration | | 4 (27%) | 4 (27%) | 9 (60%)
Renal tubule, dilatation | 4 (27%) | 11 (73%) | 14 (93%) | 15 (100%)
Renal tubule, hypertrophy | 1 (7%) | 3 (20%) | 6 (40%) | 11 (73%)
Renal tubule, necrosis | | | | 1 (7%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE B3 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 1 | | 3 | 1
Natural deaths | 4 | 2 | 1 | 1
Survivors
Terminal sacrifice | 10 | 13 | 11 | 13
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Salivary glands | | | (1) | (1)
Duct, carcinoma | | | | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Squamous cell papilloma | 3 (20%) | 2 (13%) | 2 (13%) | 4 (27%)
Squamous cell papilloma, multiple | 1 (7%) | 2 (13%) | 2 (13%) | 2 (13%)
Tooth | (3) | (2) | (4) | (2)
Odontogenic tumor | 3 (100%) | 2 (100%) | 3 (75%) | 2 (100%)
Odontogenic tumor, multiple | | | 1 (25%)
Genital System
Vagina | (2) | (2) | (1)
Squamous cell papilloma | 2 (100%) | 2 (100%)
Integumentary System
Skin | | (1) | (6) | (3)
Squamous cell papilloma | | 1 (100%) | 4 (67%) | 1 (33%)
Squamous cell papilloma, multiple | | | 1 (17%) | 2 (67%)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15)
Leukemia erythrocytic | 2 (13%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Hematopoietic System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 9 | 9 | 10 | 9
Total primary neoplasms | 11 | 9 | 13 | 12
Total animals with benign neoplasms | 6 | 7 | 7 | 8
Total benign neoplasms | 6 | 7 | 9 | 9
Total animals with malignant neoplasms | 2 | | | 1
Total malignant neoplasms | 2 | | | 1
Total animals with uncertain neoplasms-benign or malignant | 3 | 2 | 4 | 2
Total uncertain neoplasms | 3 | 2 | 4 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B4 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 26-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 1 | | 3 | 1
Natural deaths | 4 | 2 | 1 | 1
Survivors
Terminal sacrifice | 10 | 13 | 11 | 13
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Esophagus | (1)
Hyperkeratosis | 1 (100%)
Liver | (15) | (15) | (15) | (15)
Basophilic focus | | | 1 (7%)
Hematopoietic cell proliferation | 1 (7%) | 1 (7%) | 3 (20%) | 1 (7%)
Inflammation | 11 (73%) | 11 (73%) | 13 (87%) | 14 (93%)
Mitotic alteration | | | | 1 (7%)
Necrosis | | 2 (13%) | | 1 (7%)
Hepatocyte, fatty change | | 4 (27%) | 8 (53%) | 10 (67%)
Hepatocyte, hypertrophy | 1 (7%) | 2 (13%) | 8 (53%) | 12 (80%)
Hepatocyte, vacuolization cytoplasmic | 2 (13%) | 5 (33%) | 4 (27%) | 8 (53%)
Salivary glands | | | (1) | (1)
Inflammation | | | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Hyperkeratosis | | 1 (7%) | | 1 (7%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | | 1 (7%) | 1 (7%)
Hypertrophy | | | 1 (7%)
Subcapsular, hyperplasia | 8 (53%) | 8 (53%) | 7 (47%) | 10 (67%)
Pituitary gland | (15) | (15) | (15) | (15)
Cyst | 1 (7%) | 1 (7%) | | 1 (7%)
Hypertrophy | | | | 1 (7%)
Thyroid gland | (15) | (14) | (15) | (15)
Cyst | 1 (7%) | 1 (7%) | 2 (13%) | 1 (7%)
Inflammation | | | | 1 (7%)
Genital System
Ovary | (15) | (15) | (15) | (15)
Cyst | | 2 (13%) | 1 (7%)
Oviduct | (1)
Inflammation, suppurative | 1 (100%)
Uterus | (15) | (15) | (15) | (15)
Hydrometra | | 1 (7%)
Inflammation, suppurative | 1 (7%)
Endometrium, hyperplasia, cystic | 9 (60%) | 8 (53%) | 9 (60%) | 8 (53%)
Hematopoietic System
Lymph node, mandibular | (15) | (15) | (15) | (15)
Hyperplasia | | 1 (7%) | 1 (7%)
Infiltration cellular, plasma cell | 1 (7%) | | | 1 (7%)
Infiltration cellular, polymorphonuclear | 1 (7%) | 1 (7%)
Spleen | (15) | (15) | (15) | (15)
Atrophy | | | | 1 (7%)
Hematopoietic cell proliferation | 2 (13%) | 3 (20%) | 3 (20%) | 1 (7%)
Lymphoid follicle, atrophy | 1 (7%) | | 1 (7%)
Red pulp, atrophy | | | | 1 (7%)
Thymus | (14) | (15) | (15) | (14)
Atrophy | 2 (14%) | 1 (7%) | 1 (7%) | 1 (7%)
Integumentary System
Skin | | (1) | (6) | (3)
Epidermis, hyperplasia, focal | | | 1 (17%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Infiltration cellular, histiocyte | | | | 1 (7%)
Inflammation | | | 1 (7%) | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Casts protein | | 1 (7%) | 3 (20%) | 2 (13%)
Cyst | 2 (13%) | 3 (20%) | 1 (7%) | 2 (13%)
Inflammation | | 1 (7%)
Nephropathy | 1 (7%) | | 1 (7%) | 4 (27%)
Renal tubule, hypertrophy | 1 (7%) | 2 (13%) | 5 (33%) | 2 (13%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE B5 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 42-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 4 | | | 1
Natural deaths | | 1 | 2
Survivors
Terminal sacrifice | 6 | 9 | 8 | 9
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Intestine large, rectum | | (1)
Anus, squamous cell papilloma | | 1 (100%)
Liver | (10) | (10) | (10) | (10)
Stomach, forestomach | (10) | (10) | (10) | (10)
Squamous cell papilloma | 4 (40%) | 4 (40%) | 4 (40%) | 2 (20%)
Squamous cell papilloma, multiple | 3 (30%) | 2 (20%) | 3 (30%) | 4 (40%)
Tooth | (3) | (2) | (3) | (2)
Odontogenic tumor | 3 (100%) | 2 (100%) | 3 (100%) | 2 (100%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Adenoma | | | | 1 (10%)
Adrenal medulla | (10) | (10) | (10) | (10)
Pituitary gland | (10) | (10) | (10) | (10)
Integumentary System
Skin | (8) | (8) | (8) | (8)
Squamous cell papilloma | | 1 (13%) | | 3 (38%)
Squamous cell papilloma, multiple | 8 (100%) | 5 (63%) | 8 (100%) | 5 (63%)
Subcutaneous tissue, sarcoma | | 1 (13%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Alveolar/bronchiolar adenoma | | 2 (20%) | 1 (10%) | 1 (10%)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Leukemia erythrocytic | 1 (10%) | | 1 (10%) | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Genital System
Hematopoietic System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 10 | 10 | 10 | 10
Total primary neoplasms | 19 | 18 | 20 | 19
Total animals with benign neoplasms | 8 | 9 | 9 | 9
Total benign neoplasms | 15 | 15 | 16 | 16
Total animals with malignant neoplasms | 1 | 1 | 1 | 1
Total malignant neoplasms | 1 | 1 | 1 | 1
Total animals with uncertain neoplasms-benign or malignant | 3 | 2 | 3 | 2
Total uncertain neoplasms | 3 | 2 | 3 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B6 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 42-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 4 | | | 1
Natural deaths | | 1 | 2
Survivors
Terminal sacrifice | 6 | 9 | 8 | 9
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Esophagus | | | (1)
Inflammation | | | 1 (100%)
Liver | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | | 1 (10%) | 1 (10%) | 1 (10%)
Inflammation | 5 (50%) | 4 (40%) | 8 (80%) | 7 (70%)
Necrosis | | | 1 (10%) | 1 (10%)
Hepatocyte, fatty change | | 3 (30%) | 2 (20%)
Hepatocyte, vacuolization cytoplasmic | 7 (70%) | 9 (90%) | 8 (80%) | 8 (80%)
Mesentery | (1) | | (1)
Fat, necrosis | 1 (100%) | | 1 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Hyperkeratosis | | 1 (10%)
Epithelium, hyperplasia | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Hypertrophy | 5 (50%) | 4 (40%) | 4 (40%) | 4 (40%)
Subcapsular, hyperplasia | 1 (10%) | 1 (10%) | 2 (20%)
Pituitary gland | (10) | (10) | (10) | (10)
Cyst | 2 (20%) | 3 (30%) | 1 (10%)
Thyroid gland | (10) | (10) | (10) | (10)
Cyst | 2 (20%) | 2 (20%) | 1 (10%) | 2 (20%)
Follicle, cyst | | 1 (10%) | | 1 (10%)
Genital System
Preputial gland | (1)
Duct, ectasia | 1 (100%)
Testes | (10) | (10) | (10) | (10)
Mineralization | 2 (20%)
Germinal epithelium, degeneration | 3 (30%) | | 1 (10%) | 1 (10%)
Hematopoietic System
Lymph node, mandibular | (10) | (10) | (10) | (10)
Angiectasis | | | 1 (10%)
Hyperplasia | | | 1 (10%)
Infiltration cellular, plasma cell | 1 (10%) | 1 (10%) | 1 (10%) | 2 (20%)
Spleen | (10) | (10) | (10) | (10)
Atrophy | | 1 (10%)
Hematopoietic cell proliferation | | 1 (10%) | 1 (10%) | 1 (10%)
Thymus | (9) | (9) | (10) | (10)
Atrophy | 1 (11%) | 1 (11%) | 1 (10%)
Cyst | 2 (22%) | 3 (33%) | 4 (40%) | 5 (50%)
Integumentary System
Skin | (8) | (8) | (8) | (8)
Hyperplasia | | 2 (25%) | 1 (13%) | 1 (13%)
Inflammation | 1 (13%)
Control epidermis, hyperplasia | 2 (25%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Infiltration cellular, histiocyte | 1 (10%)
Inflammation | | 2 (20%) | 1 (10%)
Alveolar epithelium, hyperplasia | 1 (10%) | | | 1 (10%)
Perivascular, inflammation | | | 1 (10%) | 3 (30%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Casts protein | 2 (20%) | | 1 (10%) | 4 (40%)
Cyst | 3 (30%) | 1 (10%) | 1 (10%)
Hydronephrosis | 1 (10%) | | 2 (20%)
Infiltration cellular, plasma cell | | | 1 (10%)
Mineralization | | | | 2 (20%)
Nephropathy | 4 (40%) | 7 (70%) | 8 (80%) | 9 (90%)
Artery, inflammation | | 1 (10%)
Glomerulus, inflammation, membranoproliferative | | | | 1 (10%)
Renal tubule, degeneration | | | 2 (20%) | 6 (60%)
Renal tubule, dilatation | 1 (10%) | 8 (80%) | 8 (80%) | 10 (100%)
Renal tubule, hypertrophy | | | | 1 (10%)
Renal tubule, vacuolization cytoplasmic | 1 (10%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE B7 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 42-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 3 | 2 | 5 | 5
Natural deaths | 2 | | 1 | 1
Survivors
Terminal sacrifice | 5 | 8 | 4 | 4
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Salivary glands | (1)
Duct, carcinoma | 1 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Squamous cell papilloma | 2 (20%) | 1 (10%) | 3 (30%) | 4 (40%)
Squamous cell papilloma, multiple | 3 (30%) | 2 (20%) | 3 (30%) | 1 (10%)
Tooth | (3) | (3) | (3) | (2)
Odontogenic tumor | 3 (100%) | 3 (100%) | 3 (100%) | 2 (100%)
Genital System
Ovary | (10) | (10) | (10) | (10)
Uterus | (10) | (10) | (10) | (10)
Leiomyosarcoma | | | 1 (10%)
Sarcoma stromal | | 1 (10%)
Integumentary System
Skin | (8) | (8) | (8) | (6)
Squamous cell papilloma | 2 (25%) | 1 (13%) | 3 (38%) | 1 (17%)
Squamous cell papilloma, multiple | 4 (50%) | 6 (75%) | 4 (50%) | 4 (67%)
Subcutaneous tissue, lipoma | | 1 (13%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Alveolar/bronchiolar adenoma | | | 1 (10%)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Leukemia erythrocytic | 1 (10%) | | | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Hematopoietic System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 9 | 10 | 10 | 9
Total primary neoplasms | 16 | 15 | 18 | 13
Total animals with benign neoplasms | 7 | 8 | 8 | 7
Total benign neoplasms | 11 | 11 | 14 | 10
Total animals with malignant neoplasms | 2 | 1 | 1 | 1
Total malignant neoplasms | 2 | 1 | 1 | 1
Total animals with uncertain neoplasms-benign or malignant | 3 | 3 | 3 | 2
Total uncertain neoplasms | 3 | 3 | 3 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B8 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 42-Week Drinking Water Study of Bromodichloromethane^a^

| 0 mg/L | 175 mg/L | 350 mg/L | 700 mg/L
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 3 | 2 | 5 | 5
Natural deaths | 2 | | 1 | 1
Survivors
Terminal sacrifice | 5 | 8 | 4 | 4
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Intestine large, colon | (10) | (10) | (10) | (10)
Necrosis’ | 1 (10%)
Epithelium, regeneration | 1 (10%)
Liver | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 1 (10%) | 3 (30%) | 1 (10%) | 1 (10%)
Infiltration cellular | 2 (20%)
Inflammation | 5 (50%) | 10 (100%) | 8 (80%) | 7 (70%)
Necrosis | 2 (20%) | | 2 (20%)
Hepatocyte, fatty change | | 6 (60%) | 6 (60%) | 6 (60%)
Hepatocyte, vacuolization cytoplasmic | 5 (50%) | 8 (80%) | 8 (80%) | 8 (80%)
Mesentery | (1) | (1) | | (1)
Inflammation, suppurative | 1 (100%)
Artery, inflammation | | 1 (100%) | | 1 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Hyperkeratosis | | | 1 (10%)
Epithelium, hyperplasia | 3 (30%) | | 1 (10%) | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 1 (10%)
Subcapsular, hyperplasia | 6 (60%) | 5 (50%) | 7 (70%) | 8 (80%)
Pituitary gland | (10) | (10) | (10) | (10)
Cyst | 2 (20%) | 3 (30%) | 1 (10%) | 2 (20%)
Hyperplasia | 1 (10%)
Thyroid gland | (10) | (10) | (10) | (10)
Cyst | | 1 (10%) | 1 (10%)
Inflammation | 2 (20%) | 1 (10%) | 1 (10%)
General Body System
Peritoneum | (1)
Inflammation | 1 (100%)
Genital System
Ovary | (10) | (10) | (10) | (10)
Atrophy | 2 (20%) | 2 (20%) | 1 (10%) | 2 (20%)
Cyst | 1 (10%) | 1 (10%) | 1 (10%)
Inflammation | | 2 (20%)
Inflammation, suppurative | 2 (20%)
Oviduct | (1)
Inflammation | 1 (100%)
Uterus | (10) | (10) | (10) | (10)
Inflammation | 1 (10%) | | 1 (10%)
Endometrium, hyperplasia, cystic | 7 (70%) | 9 (90%) | 6 (60%) | 6 (60%)
Hematopoietic System
Lymph node | (2)
Mediastinal, infiltration cellular, plasma cell | 1 (50%)
Renal, hyperplasia | 1 (50%)
Lymph node, mandibular | (10) | (10) | (10) | (10)
Atrophy | | | 1 (10%)
Hyperplasia | | 1 (10%) | 2 (20%)
Infiltration cellular, plasma cell | 1 (10%) | 1 (10%) | | 2 (20%)
Lymph node, mesenteric | (10) | (10) | (9) | (10)
Hematopoietic cell proliferation | 1 (10%)
Spleen | (10) | (10) | (10) | (10)
Atrophy | | | 1 (10%) | 1 (10%)
Hematopoietic cell proliferation | 3 (30%) | 3 (30%) | | 2 (20%)
Thymus | (10) | (10) | (10) | (10)
Atrophy | 4 (40%) | 2 (20%) | 2 (20%) | 2 (20%)
Cyst | 3 (30%) | 3 (30%) | 3 (30%) | 4 (40%)
Integumentary System
Skin | (8) | (8) | (8) | (6)
Abscess | | 1 (13%)
Hyperkeratosis | | | | 1 (17%)
Hyperplasia, focal | | | | 1 (17%)
Ulcer | | | | 1 (17%)
Control epidermis, hyperplasia | | 1 (13%)
Epidermis, hyperplasia, focal | | | | 1 (17%)
Subcutaneous tissue, inflammation | | 1 (13%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Inflammation | | | 2 (20%)
Alveolar epithelium, hyperplasia | 1 (10%) | | 2 (20%) | 1 (10%)
Perivascular, inflammation | | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Casts protein | | 1 (10%) | | 2 (20%)
Cyst | | 1 (10%) | 5 (50%) | 2 (20%)
Hydronephrosis | 2 (20%)
Infarct | | | 1 (10%)
Inflammation | 1 (10%)
Mineralization | | | | 1 (10%)
Nephropathy | 4 (40%) | 2 (20%) | 4 (40%) | 2 (20%)
Glomerulus, inflammation, membranoproliferative | 1 (10%) | | | 1 (10%)
Renal tubule, accumulation, hyaline droplet | 1 (10%)
Renal tubule, hypertrophy | | | 2 (20%) | 1 (10%)
Systems Examined with No Lesions Observed
Cardiovascular System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion