# APPENDIX A SUMMARY OF LESIONS IN Tg.AC HEMIZYGOUS MICE IN THE DERMAL STUDIES OF BROMODICHLOROMETHANE

TABLE A1 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Bromodichloromethane^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | 1
Natural deaths | | | | 2
Survivors
Terminal sacrifice | 13 | 14 | 15 | 13
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Salivary glands | | (1)
Duct, carcinoma | | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Squamous cell papilloma | 3 (20%) | 4 (27%) | 4 (27%) | 4 (27%)
Squamous cell papilloma, multiple | 1 (7%) | | 2 (13%) | 2 (13%)
Tooth | (3) | (3)
Odontogenic tumor | 3 (100%) | 3 (100%)
Integumentary System
Skin | (15) | (15) | (15) | (15)
Squamous cell papilloma | | 3 (20%) | 2 (13%) | 3 (20%)
Squamous cell papilloma, multiple | 1 (7%) | | 1 (7%) | 1 (7%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Alveolar/bronchiolar adenoma | 1 (7%)
Squamous cell carcinoma, metastatic, salivary glands | | 1 (7%)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15)
Leukemia erythrocytic | 1 (7%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 9 | 9 | 8 | 8
Total primary neoplasms | 10 | 11 | 9 | 10
Total animals with benign neoplasms | 5 | 7 | 8 | 8
Total benign neoplasms | 6 | 7 | 9 | 10
Total animals with malignant neoplasms | 1 | 1
Total malignant neoplasms | 1 | 1
Total animals with metastatic neoplasms | | 1
Total metastatic neoplasms | | 1
Total animals with uncertain neoplasms-benign or malignant | 3 | 3
Total uncertain neoplasms | 3 | 3

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A2 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Bromodichloromethane^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | 1
Natural deaths | | | | 2
Survivors
Terminal sacrifice | 13 | 14 | 15 | 13
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | 1 (7%) | 1 (7%) | | 1 (7%)
Inflammation | 8 (53%) | 8 (53%) | 5 (33%) | 6 (40%)
Necrosis | 1 (7%) | 1 (7%) | 1 (7%) | 2 (13%)
Hepatocyte, fatty change | 1 (7%)
Hepatocyte, vacuolization cytoplasmic | 4 (27%) | 2 (13%) | 5 (33%) | 4 (27%)
Mesentery | | | (1)
Fat, necrosis | | | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Hyperkeratosis | | | | 1 (7%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Hyperplasia | 1 (7%)
Hypertrophy | 9 (60%) | 9 (60%) | 6 (40%) | 8 (53%)
Vacuolization cytoplasmic | | | | 1 (7%)
Subcapsular, hyperplasia | 1 (7%) | 1 (7%) | | 2 (13%)
Thyroid gland | (15) | (15) | (15) | (15)
Cyst | 1 (7%) | | 2 (13%)
Genital System
Testes | (15) | (15) | (15) | (15)
Germinal epithelium, degeneration | 3 (20%) | 1 (7%) | 2 (13%) | 1 (7%)
Hematopoietic System
Lymph node, mandibular | (15) | (15) | (14) | (14)
Atrophy | | | | 1 (7%)
Infiltration cellular, plasma cell | 1 (7%)
Lymph node, mesenteric | (14) | (15) | (15) | (15)
Atrophy | | 1 (7%)
Spleen | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | 1 (7%) | 2 (13%) | 1 (7%) | 1 (7%)
Lymphoid follicle, atrophy | | | | 1 (7%)
Lymphoid follicle, hyperplasia | | | | 1 (7%)
Thymus | (15) | (15) | (15) | (15)
Atrophy | 1 (7%) | 1 (7%) | | 2 (13%)
Integumentary System
Skin | (15) | (15) | (15) | (15)
Epidermis, hyperplasia, focal | 1 (7%)
Subcutaneous tissue, inflammation | | 1 (7%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Inflammation | | 1 (7%) | 1 (7%)
Thrombosis | | | 1 (7%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Casts protein | 3 (20%) | 1 (7%) | | 2 (13%)
Cyst | 1 (7%) | | | 1 (7%)
Hydronephrosis | 1 (7%) | | | 1 (7%)
Inflammation | | | | 1 (7%)
Nephropathy | 7 (47%) | 6 (40%) | 7 (47%) | 6 (40%)
Artery, inflammation | 1 (7%) | | 1 (7%)
Renal tubule, dilatation | 1 (7%) | | | 1 (7%)
Renal tubule, hypertrophy | | | | 1 (7%)
Renal tubule, necrosis | | | | 1 (7%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A3 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Bromodichloromethane^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | 3 | 1 | 4
Natural deaths | 2 | 2 | 2 | 1
Survivors
Terminal sacrifice | 11 | 10 | 12 | 10
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Salivary glands | (1)
Duct, carcinoma | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Squamous cell papilloma | | 3 (20%) | 2 (13%) | 4 (27%)
Squamous cell papilloma, multiple | 2 (13%) | 1 (7%) | 3 (20%)
Tooth | (2) | (3) | (2) | (1)
Odontogenic tumor | 2 (100%) | 3 (100%) | 2 (100%) | 1 (100%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Adrenal medulla | (15) | (15) | (15) | (15)
Pituitary gland | (15) | (15) | (15) | (15)
Genital System
Ovary | (15) | (14) | (15) | (15)
Uterus | (15) | (15) | (15) | (15)
Vagina | | | (1)
Squamous cell papilloma | | | 1 (100%)
Hematopoietic System
Lymph node, mandibular | (15) | (15) | (15) | (15)
Spleen | (15) | (15) | (15) | (15)
Integumentary System
Skin | (15) | (15) | (15) | (15)
Squamous cell papilloma | 1 (7%) | 4 (27%) | 2 (13%) | 1 (7%)
Skin, site of application, squamous cell papilloma | | 1 (7%)
Special Senses System
Zymbal’s gland | | | | (1)
Squamous cell papilloma | | | | 1 (100%)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15)
Leukemia erythrocytic | | 1 (7%) | | 1 (7%)
Leukemia granulocytic | | 1 (7%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Respiratory System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 6 | 11 | 8 | 6
Total primary neoplasms | 6 | 14 | 10 | 8
Total animals with benign neoplasms | 3 | 8 | 7 | 5
Total benign neoplasms | 3 | 9 | 8 | 6
Total animals with malignant neoplasms | 1 | 2 | | 1
Total malignant neoplasms | 1 | 2 | | 1
Total animals with uncertain neoplasms-benign or malignant | 2 | 3 | 2 | 1
Total uncertain neoplasms | 2 | 3 | 2 | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A4 Summary of the Incidence Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Bromodichloromethane^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | 3 | 1 | 4
Natural deaths | 2 | 2 | 2 | 1
Survivors
Terminal sacrifice | 11 | 10 | 12 | 10
Animals examined microscopically | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | 1 (7%) | 1 (7%) | 1 (7%) | 3 (20%)
Inflammation | 14 (93%) | 11 (73%) | 14 (93%) | 11 (73%)
Necrosis | 3 (20%) | 2 (13%) | 4 (27%) | 2 (13%)
Hepatocyte, vacuolization cytoplasmic | 3 (20%) | 7 (47%) | 5 (33%) | 5 (33%)
Mesentery | (1)
Necrosis | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15)
Inflammation | | | 1 (7%)
Epithelium, hyperkeratosis | 1 (7%)
Epithelium, hyperplasia | 1 (7%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15)
Subcapsular, hyperplasia | 8 (53%) | 8 (53%) | 11 (73%) | 5 (33%)
Pituitary gland | (15) | (15) | (15) | (15)
Cyst | 4 (27%) | 1 (7%) | 1 (7%) | 2 (13%)
Thyroid gland | (15) | (15) | (15) | (15)
Cyst | 2 (13%) | 1 (7%) | 1 (7%) | 1 (7%)
Genital System
Ovary | (15) | (14) | (15) | (15)
Cyst | 1 (7%) | | | 2 (13%)
Uterus | (15) | (15) | (15) | (15)
Inflammation, suppurative | 2 (13%) | | 1 (7%)
Endometrium, hyperplasia, cystic | 7 (47%) | 6 (40%) | 10 (67%) | 6 (40%)
Hematopoietic System
Lymph node | (1)
Mediastinal, hyperplasia | 1 (100%)
Lymph node, mandibular | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | | | 1 (7%)
Infiltration cellular, plasma cell | | 1 (7%) | 1 (7%) | 1 (7%)
Spleen | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | 2 (13%) | 1 (7%) | 1 (7%) | 4 (27%)
Thymus | (15) | (15) | (15) | (14)
Atrophy | | 3 (20%) | 1 (7%)
Integumentary System
Skin | (15) | (15) | (15) | (15)
Epidermis, hyperplasia, focal | | | 1 (7%)
Respiratory System
Lung | (15) | (15) | (15) | (15)
Inflammation | 1 (7%)
Alveolar epithelium, hyperplasia | 1 (7%)
Artery, inflammation | | 1 (7%)
Special Senses System
Eye | | (1) | | (1)
Retina, degeneration | | 1 (100%) | | 1 (100%)
Urinary System
Kidney | (15) | (15) | (15) | (15)
Casts protein | 6 (40%) | 5 (33%) | 5 (33%) | 4 (27%)
Cyst | 2 (13%) | 2 (13%) | | 1 (7%)
Hydronephrosis | | | 1 (7%)
Mineralization | | 1 (7%)
Nephropathy | | | 2 (13%) | 3 (20%)
Artery, inflammation | | 1 (7%) | | 1 (7%)
Renal tubule, hypertrophy | | 1 (7%) | 1 (7%) | 4 (27%)
Renal tubule, necrosis | 1 (7%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A5 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Bromodichloromethane^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 3 | | 1 | 1
Natural deaths | 1 | 2 | | 1
Survivors
Terminal sacrifice | 6 | 8 | 9 | 8
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Salivary glands | (1)
Duct, carcinoma | 1 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Squamous cell papilloma | 2 (20%) | 4 (40%) | 3 (30%) | 3 (30%)
Squamous cell papilloma, multiple | 1 (10%) | 2 (20%) | 2 (20%) | 3 (30%)
Tooth | (3) | (1) | (2) | (2)
Odontogenic tumor | 3 (100%) | 1 (100%) | 2 (100%) | 2 (100%)
Integumentary System
Skin | (10) | (10) | (10) | (10)
Squamous cell papilloma | 4 (40%) | 1 (10%) | | 1 (10%)
Squamous cell papilloma, multiple | 2 (20%) | 4 (40%) | 7 (70%) | 2 (20%)
Site of application, squamous cell papilloma | | | 1 (10%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Alveolar/bronchiolar adenoma | | 2 (20%)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Leukemia erythrocytic | | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 7 | 8 | 9 | 9
Total primary neoplasms | 13 | 15 | 15 | 11
Total animals with benign neoplasms | 6 | 7 | 9 | 8
Total benign neoplasms | 9 | 13 | 13 | 9
Total animals with malignant neoplasms | 1 | 1
Total malignant neoplasms | 1 | 1
Total animals with uncertain neoplasms-benign or malignant | 3 | 1 | 2 | 2
Total uncertain neoplasms | 3 | 1 | 2 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A6 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Bromodichloromethane^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 3 | | 1 | 1
Natural deaths | 1 | 2 | | 1
Survivors
Terminal sacrifice | 6 | 8 | 9 | 8
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 3 (30%) | 1 (10%) | 1 (10%) | 1 (10%)
Inflammation | 6 (60%) | 3 (30%) | 6 (60%) | 3 (30%)
Necrosis | 1 (10%) | 1 (10%) | 1 (10%) | 1 (10%)
Hepatocyte, fatty change | | 1 (10%)
Hepatocyte, vacuolization cytoplasmic | 6 (60%) | 7 (70%) | 8 (80%) | 7 (70%)
Mesentery | | | (1)
Fat, necrosis | | | 1 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Hyperkeratosis | | | | 1 (10%)
Epithelium, hyperplasia | 2 (20%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Hypertrophy | 5 (50%) | 3 (30%) | 4 (40%) | 4 (40%)
Subcapsular, hyperplasia | | | 1 (10%) | 1 (10%)
Pituitary gland | (10) | (10) | (10) | (10)
Cyst | 1 (10%) | 2 (20%) | 1 (10%) | 2 (20%)
Thyroid gland | (10) | (10) | (10) | (10)
Cyst | | | | 3 (30%)
Genital System
Epididymis | (10) | (10) | (10) | (10)
Inflammation | | | 1 (10%)
Testes | (10) | (10) | (10) | (10)
Germinal epithelium, degeneration | 1 (10%) | 2 (20%) | | 1 (10%)
Hematopoietic System
Lymph node, mandibular | (10) | (10) | (10) | (10)
Hyperplasia | | 1 (10%) | 1 (10%)
Infiltration cellular, plasma cell | 2 (20%)
Spleen | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 4 (40%) | 2 (20%) | 3 (30%) | 1 (10%)
Pigmentation | | | | 1 (10%)
Lymphoid follicle, atrophy | | | | 1 (10%)
Thymus | (9) | (10) | (9) | (9)
Atrophy | 1 (11%) | | 2 (22%) | 1 (11%)
Cyst | 4 (44%) | 2 (20%) | 1 (11%) | 3 (33%)
Integumentary System
Skin | (10) | (10) | (10) | (10)
Hyperplasia | | 1 (10%) | | 1 (10%)
Inflammation | | | | 1 (10%)
Inflammation, focal | 1 (10%) | 2 (20%) | 1 (10%)
Ulcer | | | | 1 (10%)
Control epidermis, hyperplasia | | | | 1 (10%)
Dermis skin, site of application, inflammation | | | | 1 (10%)
Epidermis, hyperplasia, focal | 1 (10%) | 1 (10%)
Epidermis, skin, site of application, hyperplasia | | | 1 (10%) | 1 (10%)
Epidermis, skin, site of application, hyperplasia, focal | 1 (10%)
Epidermis, skin, site of application, inflammation, focal | 1 (10%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Inflammation | 1 (10%) | | 1 (10%)
Alveolar epithelium, hyperplasia | | | 1 (10%)
Perivascular, inflammation | 1 (10%) | | 1 (10%) | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Casts protein | 1 (10%) | 2 (20%) | 4 (40%) | 2 (20%)
Cyst | 1 (10%) | 1 (10%) | 2 (20%) | 2 (20%)
Hydronephrosis | | 2 (20%)
Nephropathy | 6 (60%) | 5 (50%) | 3 (30%) | 6 (60%)
Artery, inflammation | | | 1 (10%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System
Special Senses System

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A7 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Bromodichloromethane^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 4 | 4 | 3 | 4
Natural deaths | 1 | 2 | | 1
Survivors
Terminal sacrifice | 5 | 4 | 7 | 5
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Leiomyosarcoma, metastatic, vagina | 1 (10%)
Mesentery | | | | (1)
Salivary glands | | | (1)
Duct, carcinoma | | | 1 (100%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Squamous cell papilloma | | 2 (20%) | 3 (30%) | 2 (20%)
Squamous cell papilloma, multiple | 1 (10%) | 2 (20%) | 2 (20%) | 2 (20%)
Tooth | (4) | (4) | (4) | (3)
Odontogenic tumor | 4 (100%) | 3 (75%) | 3 (75%) | 3 (100%)
Genital System
Ovary | (10) | (10) | (10) | (10)
Leiomyosarcoma, metastatic, vagina | 1 (10%)
Uterus | (10) | (10) | (10) | (10)
Vagina | (2) | (1) | (2) | (4)
Leiomyosarcoma | 1 (50%)
Squamous cell papilloma | 1 (50%) | 1 (100%) | 2 (100%) | 2 (50%)
Hematopoietic System
Lymph node | (1) | (1) | | (1)
Lymph node, mandibular | (10) | (10) | (10) | (9)
Lymph node, mesenteric | (9) | (9) | (10) | (10)
Leiomyosarcoma, metastatic, vagina | 1 (11%)
Spleen | (10) | (10) | (10) | (10)
Thymus | (10) | (10) | (10) | (10)
Integumentary System
Mammary gland | (10) | (10) | (10) | (10)
Skin | (10) | (10) | (10) | (10)
Squamous cell carcinoma | 1 (10%)
Squamous cell papilloma | 4 (40%) | 3 (30%) | 5 (50%) | 1 (10%)
Squamous cell papilloma, multiple | 2 (20%) | | 2 (20%)
Vulva, squamous cell papilloma | | | | 1 (10%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Alveolar/bronchiolar adenoma | | | 1 (10%) | 1 (10%)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Leukemia erythrocytic | 2 (20%) | 3 (30%) | | 2 (20%)
Lymphoma malignant | | | | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 8 | 8 | 9 | 9
Total primary neoplasms | 16 | 14 | 19 | 15
Total animals with benign neoplasms | 6 | 5 | 8 | 4
Total benign neoplasms | 8 | 8 | 15 | 9
Total animals with malignant neoplasms | 4 | 3 | 1 | 3
Total malignant neoplasms | 4 | 3 | 1 | 3
Total animals with metastatic neoplasms | 1
Total metastatic neoplasms | 3
Total animals with uncertain neoplasms-benign or malignant | 4 | 3 | 3 | 3
Total uncertain neoplasms | 4 | 3 | 3 | 3

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A8 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Bromodichloromethane^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10
Early deaths
Moribund | 4 | 4 | 3 | 4
Natural deaths | 1 | 2 | | 1
Survivors
Terminal sacrifice | 5 | 4 | 7 | 5
Animals examined microscopically | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 4 (40%) | 2 (20%) | 1 (10%) | 4 (40%)
Inflammation | 7 (70%) | 6 (60%) | 9 (90%) | 5 (50%)
Necrosis | | 1 (10%) | 1 (10%)
Hepatocyte, vacuolization cytoplasmic | 4 (40%) | 4 (40%) | 7 (70%) | 6 (60%)
Stomach, forestomach | (10) | (10) | (10) | (10)
Epithelium, hyperplasia | 1 (10%) | | | 1 (10%)
Tooth | (4) | (4) | (4) | (3)
Peridontal tissue, hyperplasia | | 1 (25%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | | | 1 (10%) | 1 (10%)
Subcapsular, hyperplasia | 7 (70%) | 5 (50%) | 5 (50%) | 7 (70%)
Parathyroid gland | (1)
Cyst | 1 (100%)
Pituitary gland | (10) | (10) | (10) | (10)
Cyst | | 1 (10%) | 1 (10%) | 1 (10%)
Thyroid gland | (10) | (10) | (10) | (10)
Cyst | 2 (20%) | 3 (30%) | 1 (10%) | 1 (10%)
Inflammation | | | | 1 (10%)
Genital System
Ovary | (10) | (10) | (10) | (10)
Atrophy | 1 (10%) | | 3 (30%) | 1 (10%)
Cyst | 1 (10%) | 1 (10%) | 2 (20%) | 1 (10%)
Inflammation | | 1 (10%)
Inflammation, suppurative | 1 (10%)
Oviduct | | | (1)
Inflammation | | | 1 (100%)
Uterus | (10) | (10) | (10) | (10)
Hydrometra | | | 1 (10%)
Inflammation | | 1 (10%)
Endometrium, hyperplasia, cystic | 5 (50%) | 4 (40%) | 5 (50%) | 7 (70%)
Hematopoietic System
Lymph node, mandibular | (10) | (10) | (10) | (9)
Hyperplasia | 3 (30%) | | 1 (10%) | 1 (11%)
Infiltration cellular, plasma cell | | 1 (10%)
Lymph node, mesenteric | (9) | (9) | (10) | (10)
Hyperplasia | 1 (11%)
Spleen | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 3 (30%) | 2 (20%) | 1 (10%) | 2 (20%)
Lymphoid follicle, atrophy | | 1 (10%)
Thymus | (10) | (10) | (10) | (10)
Atrophy | 2 (20%) | 6 (60%) | 2 (20%) | 2 (20%)
Cyst | 3 (30%) | 2 (20%) | 2 (20%) | 3 (30%)
Integumentary System
Skin | (10) | (10) | (10) | (10)
Hyperplasia | | | 2 (20%) | 1 (10%)
Inflammation, focal | 2 (20%) | 1 (10%) | | 1 (10%)
Control epidermis, hyperplasia | 2 (20%) | | | 1 (10%)
Epidermis, hyperplasia, focal | 1 (10%) | 1 (10%) | 1 (10%) | 1 (10%)
Epidermis, skin, site of application, hyperplasia | | 1 (10%) | | 1 (10%)
Epidermis, skin, site of application, inflammation | | 1 (10%)
Respiratory System
Lung | (10) | (10) | (10) | (10)
Inflammation | 1 (10%)
Alveolar epithelium, hyperplasia | | | 2 (20%)
Perivascular, infiltration cellular, mononuclear cell | 1 (10%)
Perivascular, inflammation | | | | 1 (10%)
Special Senses System
Eye | | | | (1)
Retina, degeneration | | | | 1 (100%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Accumulation, hyaline droplet | 1 (10%) | 1 (10%)
Casts protein | 2 (20%) | 1 (10%) | 1 (10%) | 1 (10%)
Cyst | 1 (10%) | | | 2 (20%)
Hydronephrosis | 1 (10%) | 1 (10%)
Inflammation | | 1 (10%)
Mineralization | | | 1 (10%)
Nephropathy | 2 (20%) | 1 (10%) | 4 (40%) | 1 (10%)
Artery, inflammation | 1 (10%)
Glomerulus, inflammation, membranoproliferative | 1 (10%) | 3 (30%) | | 2 (20%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Musculoskeletal System
Nervous System

a Number of animals examined microscopically at the site and the number of animals with lesion