# REFERENCES

Albert, R.E., French, J.E., Maronpot, R., Spalding, J., and Tennant, R. (1996). Mechanism of skin tumorigenesis by contact sensitizers: The effect of the corticosteroid fluocinolone acetonide on inflammation and tumor induction by 2,4 dinitro-1-fluorobenzene in the skin of the TG.AC (v-Ha-ras) mouse. Environ. Health Perspect. 104, 1062–1068.8930547
The Aldrich Library of FT-IR Spectra (1985). 1st ed. (C.J. Pouchert, Ed.), Vol. 1. Aldrich Chemical Company, Inc., Milwaukee, WI.
2000-2001 Aldrich Handbook of Fine Chemicals and Laboratory Equipment (2000), p. 1272. The Sigma-Aldrich Chemical Company. Milwaukee, WI.
American Chemical Society (ACS) (1990). Chemcyclopedia ’91, p. 234. American Chemical Society, Washington, DC.
American Industrial Hygiene Association (AIHA) (1981). Workplace environmental exposure level guide: Pentaerythritol triacrylate. Am. Ind. Hyg. Assoc. J. 42, B45–B46.7315732
Andrews, L.S., and Clary, J.J. (1986). Review of the toxicity of multifunctional acrylates. J. Toxicol. Environ. Health 19, 149–164.3531535
Argyris, T.S. (1981). The regulation of epidermal hyperplastic growth. Crit. Rev. Toxicol. 9, 151–200.7026175
Ashby, J., and Tennant, R.W. (1991). Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the U.S. NTP. Mutat. Res. 257, 229–306.1707500
Ashby, J., and Tennant, R.W. (1994). Prediction of rodent carcinogenicity for 44 chemicals: Results. Mutagenesis 9, 7–15.8208133
Bailer, A.J., and Portier, C.J. (1988). Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics 44, 417–431.3390507
Barratt, M., Basketter, D., Chamberlain, M., Admans, G., and Langowski, J. (1994). An expert system rulebase for identifying contact allergens. Toxicol. In Vitro 8, 1053–1060.20693071
Bauluz, C., Larcher, F., Ballestin, C., Grande, T., and Jorcano, J. (1994). Augmented expression of cytokines in mouse epidermal tumor cells and its possible involvement in the induction of hematopoietic alterations. Mol. Carcinog. 11, 155–163.7945804
Bieler, G.S., and Williams, R.L. (1993). Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics 49, 793–801.8241374
Björkner, B. (1984). The sensitizing capacity of multifunctional acrylates in the guinea pig. Contact Dermatitis 11, 236–246.6499426
Björkner, B., Dahlquist, I., and Fregert, S. (1980). Allergic contact dermatitis from acrylates in ultraviolet curing inks. Contact Dermatitis 6, 405–409.6449348
Boorman, G.A., Montgomery, C.A., Jr., Eustis, S.L., Wolfe, M.J., McConnell, E.E., and Hardisty, J.F. (1985). Quality assurance in pathology for rodent carcinogenicity studies. In Handbook of Carcinogen Testing (H.A. Milman and E.K. Weisburger, Eds.), pp. 345–357. Noyes Publications, Park Ridge, NJ.
Bull, J.E., Parker, D., and Turk, J.L. (1985). Predictive value of assessment of lymph node weight and T-lymphocyte proliferation in contact sensitivity in acrylates. J. Invest. Dermatol. 85, 403–406.3877123
Cannon, R.E., Spalding, J.W., Trempus, C.S., Szczesniak, C.J., Virgil, K.M., Humble, M.C., and Tennant, R.W. (1997). Kinetics of wound-induced v-Ha-ras transgene expression and papilloma in transgenic Tg.AC mice. Mol. Carcinog. 20, 108–114.9328441
Carpenter, C.P., Weil, C.S., and Smyth, H.F., Jr. (1974). Range finding toxicity data: List VIII. Toxicol. Appl. Pharmacol. 28, 313–319.4854023
Celanese Chemical Company (1979). A Two/Four Week Dermal Toxicity Study in Rabbits (Project No. 5304-78). Submitted by Biodynamics, Inc., East Millstone, NJ, to Celanese Chemical Company, New York.
Celanese Chemical Company (1981). A 28-Day Dermal Toxicity Study in Rabbits Using Test Materials C-178, C-179, C-180, C-181, C-182, C-191, and C-192 with cover letter dated 081585 (Project No. 6510-80). Submitted by Biodynamics, Inc., East Millstone, NJ, to Celanese Chemical Company, New York.
Celanese Chemical Company (1982a). Celanese Multifunctional Monomers: A Guide to Application, Safety and Handling, pp. 1–35. Celanese Chemical Company, New York.
Celanese Chemical Company (1982b). An Acute Intraperitoneal Toxicity Study in Rats (Project No. 6817-81). Submitted by Biodynamics, Inc., East Millstone, NJ, to Celanese Chemical Company, New York.
Celanese Chemical Company (1982c). Evaluation of a Substantial Risk Submission on Pentaerythritol Triacrylate, with Enclosures. Celanese Chemical Company, New York.
Celanese Corporation, Inc. (1986). Chronic Mouse Dermal Toxicity Study Using Nine Chemicals With Cover Letter Dated 081985. Submitted by Kettering Laboratory, University of Cincinnati Medical Center, Cincinnati, to Celanese Corporation, New York.
Clemmensen, S. (1984). Cross-reaction patterns in guinea pigs sensitized to acrylic monomers. Drug Chem. Toxicol. 7, 527–540.6534730
Code of Federal Regulations (CFR) 21, Part 58.
Cofield, B.G., Storrs, F.J., and Strawn, C.B. (1985). Contact allergy to aziridine paint hardener. Arch. Dermatol. 121, 373–376.3156563
Cox, D.R. (1972). Regression models and life-tables. J. R. Stat. Soc. B34, 187–220.
Crawford, B.D. (1985). Perspectives on the somatic mutation model of carcinogenesis. In Advances in Modern Environmental Toxicology. Mechanisms and Toxicity of Chemical Carcinogens and Mutagens (M.A. Mehlman, W.G. Flamm, and R.J. Lorentzen, Eds.), pp. 13–59. Princeton Scientific Publishing Co., Inc., Princeton, NJ.
Dahlquist, I., Fregert, S., and Trulson, L. (1983). Contact allergy to trimethylolpropane triacrylate (TMPTA) in an aziridine plastic hardener. Contact Dermatitis 9, 122–124.6221863
Dearfield, K.L., Millis, C.S., Harrington-Brock, K., Doerr, C.L., and Moore, M.M. (1989). Analysis of the genotoxicity of nine acrylate/methacrylate compounds in L5178Y mouse lymphoma cells. Mutagenesis 4, 381–393.2687634
DePass, L.R. (1982). Carcinogenicity testing of photocurable coatings. Radiat. Curing 9, 18–24.
DePass, L.R., Maronpot, R.R., and Weil, C.S. (1985). Dermal oncogenicity bioassays of monofunctional and multifunctional acrylates and acrylate-based oligomers. J. Toxicol. Environ. Health 16, 55–60.4068056
DiGiovanni, J. (1991). Modification of multistage skin carcinogenesis in mice. Prog. Exp. Tumor Res. 33, 192–229.1902960
Dixon, W.J., and Massey, F.J., Jr. (1951). Introduction to Statistical Analysis, 1st ed., pp. 145–147. McGraw-Hill Book Company, Inc., New York.
Dunn, O.J. (1964). Multiple comparisons using rank sums. Technometrics 6, 241–252.
Dunnett, C.W. (1955). A multiple comparison procedure for comparing several treatments with a control. J. Am. Stat. Assoc. 50, 1096–1121.
Dunson, D.B., Haseman, J.K., van Birgelen, A.P.J.M., Stasiewicz, S., and Tennant, R.W. (2000). Statistical analysis of skin tumor data from Tg.AC mouse bioassays. Toxicol. Sci. 55, 293–302.10828260
Eastin, W.C., Haseman, J.K., Mahler, J.F., and Bucher, J.R. (1998). The National Toxicology Program evaluation of genetically altered mice as predictive models for identifying carcinogens. Toxicol. Pathol. 26, 461–473.9715504
Eastin, W.C., Mennear, J.H., Tennant, R.W., Stoll, R.E., Branstetter, D.G., Bucher, J.R., McCullough, B., Binder, R.L., Spalding, J.W., and Mahler, J.F. (2001). Tg.AC genetically altered mouse: Assay working group overview of available data. Toxicol. Pathol. 29, 60–80.11695563
Emmett, E.A. (1977). Contact dermatitis from poly-functional acrylic monomers. Contact Dermatitis 3, 245–248.145343
Emmett, E.A., and Kominsky, J.R. (1975). Health Hazard Evaluation (Report No. 75-106-247), pp.1-17. Submitted by Inmont Corporation, Paddock Road Facility, Cincinnati, OH, to the National Technical Information Service, U.S. Department of Commerce. Performed by the National Institute for Occupational Safety and Health.
Emmett, E.A., and Kominsky, J.R. (1977). Allergic contact dermatitis from ultraviolet cured inks. J. Occup. Med. 19, 113–115.138725
Enzmann, H., Bomhard, E., Iatropoulos, M., Ahr, H.J., Schlueter, G., and Williams, G.M. (1998). Short- and intermediate-term carcinogenicity testing – a review. Part 1: The prototypes mouse skin tumour assay and rat liver focus assay. Food Chem. Toxicol. 36, 979–995.9771562
Harvey, S.C. (1980). Antimicrobial drugs. In Remington’s Pharmaceutical Sciences (A. Osol, Ed.), p. 1107. Mack Publishing Company, Easton, PA.
Hennings, H., Glick, A.B., Greenhalgh, D.A., Morgan, D.L., Strickland, J.E., Tennenbaum, T., and Yuspa, S.H. (1993). Critical aspects of initiation, promotion, and progression in multistage epidermal carcinogenesis. Proc. Soc. Exp. Biol. Med. 202, 1–18.8424089
Hollander, M., and Wolfe, D.A. (1973). Nonparametric Statistical Methods, pp. 120–123. John Wiley and Sons, New York.
Honchel, R., Rosenzweig, B.A., Thompson, K.L., Blanchard, K.T., Furst, S.M., Stoll, R.E., and Sistare, F.D. (2001). Loss of palindromic symmetry in Tg.AC mice with a nonresponder phenotype. Mol. Carcinog. 30, 99–100.11241757
Integrated Laboratory Systems (ILS) (1990). Micronucleus Data Management and Statistical Analysis Software, Version 1.4. ILS, P.O. Box 13501, Research Triangle Park, NC 27707.
Jonckheere, A.R. (1954). A distribution-free k-sample test against ordered alternatives. Biometrika 41, 133–145.
Kalensky, J. (1987). Allergic contact eczema caused by PVC gloves, induced by pentaerythritol triacrylate (PETA). Cesk. Dermatol. 62, 305–312 (Abstr.).
Kaplan, E.L., and Meier, P. (1958). Nonparametric estimation from incomplete observations. J. Am. Stat. Assoc. 53, 457–481.
Kirk-Othmer Encyclopedia of Chemical Technology (1978). 3rd ed. (M. Grayson and D. Eckroth, Eds.), Vol. 1, pp. 778–789. John Wiley and Sons, New York.
Leder, A., Kuo, A., Cardiff, R.D., Sinn, E., and Leder, P. (1990). v-Ha-ras transgene abrogates the initiation step in mouse skin tumorigenesis: Effects of phorbol esters and retinoic acid. Proc. Natl. Acad. Sci. U.S.A. 87, 9178–9182.2251261
Lenga, R.E., Ed. (1988). The Sigma-Aldrich Library of Chemical Safety Data, ed. 2, Vol. II, p. 2700. Sigma-Aldrich Corporation, Milwaukee.
Liu, E.T. (1990). The role of ras gene mutations in myeloproliferative disorders. Clin. Lab. Med. 10, 797–807.2272174
Long, R.E., Knutsen, G., and Robinson, M. (1986). Myeloid hyperplasia in the SENCAR mouse: Differentiation from granulocytic leukemia. Environ. Health Perspect. 68, 117–123.3465532
McConnell, E.E., Solleveld, H.A., Swenberg, J.A., and Boorman, G.A. (1986). Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. JNCI 76, 283–289.3456066
MacGregor, J.T., Wehr, C.M., Henika, P.R., and Shelby, M.D. (1990). The in vivo erythrocyte micronucleus test: Measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam. Appl. Toxicol. 14, 513–522.2111256
Mahler, J.F., Flagler, N.D., Malarkey, D.E., Mann, P.C., Haseman, J.K., and Eastin, W. (1998). Spontaneous and chemically induced proliferative lesions in Tg.AC transgenic and p53-heterozygous mice. Toxicol. Pathol. 26, 501–511.9715509
Maronpot, R.R., and Boorman, G.A. (1982). Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol. Pathol. 10, 71–80.28094716
Miller, J.A., and Miller, E.C. (1977). Ultimate chemical carcinogens as reactive mutagenic electrophiles. In Origins of Human Cancer (H.H. Hiatt, J.D. Watson, and J.A. Winsten, Eds.), pp. 605–627. Cold Spring Harbor Laboratory, Cold Spring Harbor, NY.
Morrison, D.F. (1976). Multivariate Statistical Methods, 2nd ed., pp. 170–179. McGraw-Hill Book Company, New York.
Nagase, H., Bryson, S., Fee, F., and Balmain, A. (1996). Multigenic control of skin tumour development in mice. In 1996 Variation in the Human Genome (Ciba Foundation Symposium 197), pp. 156–180. Wiley, Chichester, England.
National Cancer Institute (NCI) (1987). Summary of data for chemical selection, pentaerythritol triacrylate. Prepared for NCI by Tracor Jitco/Technical Resources, Inc., under contract no. N01-CP-41003.
National Institute for Occupational Safety and Health (NIOSH) (1990). National Occupational Exposure Survey (1981-1983), unpublished provisional data as of July 1, 1990. NIOSH, Cincinnati, OH.
National Toxicology Program (NTP) (1986a). Carcinogenesis Studies of Ethyl Acrylate (CAS No. 140-88-5) in F344/N Rats and B6C3F_1_ Mice (Gavage Studies). Technical Report Series No. 259. NIH Publication No. 87-2515.
U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (1986b). Toxicology and Carcinogenesis Studies of Methyl Methacrylate (CAS No. 80-62-6) in F344/N Rats and B6C3F_1_ Mice (Inhalation Studies). Technical Report Series No. 314. NIH Publication No. 87-2570. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (1992). Toxicology and Carcinogenesis Studies of Resorcinol (CAS No. 108-46-3) in F344/N Rats and B6C3F_1_ Mice (Gavage Studies). Technical Report Series No. 403. NIH Publication No. 92-2858. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (1999). The Murine Local Lymph Node Assay: A Test Method for Assessing the Allergic Contact Dermatitis Potential of Chemicals/Compounds. The Results of an Independent Peer Review Evaluation Coordinated by the Interagency Coordinating Committee on the Validation of Alternative Methods (ICCVAM) and the National Toxicology Program Center for the Evaluation of Alternative Toxicological Methods (NICEATM). NIH Publication No. 99-4494. National Institute of Environmental Health Sciences, National Institutes of Health, U.S. Public Health Service, Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2005). Toxicology Studies of Trimethylolpropane Triacrylate (Technical Grade) (CAS No. 15625-89-5) in F344/N Rats, B6C3F_1_ Mice, and Genetically Modified (FVB Tg.AC Hemizygous) Mice (Dermal Studies). GMM Report Series No. 3. NIH Publication No. 06-4450. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
Nessel, C.S., Freeman, J.J., Forgash, R.C., and McKee, R.H. (1999). The role of dermal irritation in the skin tumor promoting activity of petroleum middle distillates. Toxicol. Sci. 49, 48–55.10367341
Nethercott, J.R. (1978). Skin problems associated with multifunctional acrylic monomers in ultraviolet curing inks. Br. J. Dermatol. 98, 541–552.148898
Nethercott, J.R., Jakubovic, H.R., Pilger, C., and Smith, J.W. (1983). Allergic contact dermatitis due to urethane acrylate in ultraviolet cured inks. Br. J. Ind. Med. 40, 241–250.6223656
Newmark, R.A., and Palazzotto, J. (1990). Carbon-13 NMR analysis of pentaerythritol triacrylate. Appl. Spectroscopy 44, 804–807.
Nylander-French, L.A., and French, J.E. (1998). Tripropylene glycol diacrylate but not ethyl acrylate induces skin tumors in a twenty-week short-term tumorigenesis study in Tg.AC (v-Ha-ras) mice. Toxicol. Pathol. 26, 476–483.9715506
Parker, D., and Turk, J.L. (1983). Contact sensitivity to acrylate compounds in guinea pigs. Contact Dermatitis 9, 55–60.6839739
Parker, D., Long, P.V., Bull, J.E., and Turk, J.L. (1985). Epicutaneous induction of tolerance with acrylates and related compounds. Contact Dermatitis 12, 146–154.3995943
Piegorsch, W.W., and Bailer, A.J. (1997). Statistics for Environmental Biology and Toxicology, Section 6.3.2. Chapman and Hall, London.
Portier, C.J., and Bailer, A.J. (1989). Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam. Appl. Toxicol. 12, 731–737.2744275
Portier, C.J., Hedges, J.C., and Hoel, D.G. (1986). Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 46, 4372–4378.3731095
Pritchard, J.B., French, J.E., Davis, B.J., and Haseman, J.K. (2003). The role of transgenic mouse models in carcinogen identification. Environ. Health Perspect. 111, 444–454.12676597
Radcure Specialties, Inc. (1990a). PETA monomer. Pentaerythritol triacrylate. Radcure Specialties, Inc., Louisville, KY.
Radcure Specialties, Inc. (1990b). Material safety data sheet for pentaerythritol triacrylate. Radcure Specialties, Inc., Louisville, KY.
Sax, N.I., and Lewis, R.J., Sr. (1989). Dangerous Properties of Industrial Materials, 7th ed., pp. 2668–2669. Van Nostrand Reinhold, New York.
Shelby, M.D. (1988). The genetic toxicity of human carcinogens and its implications. Mutat. Res. 204, 3–15.3277048
Shelby, M.D., and Witt, K.L. (1995). Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ. Mol. Mutagen. 25, 302–313.7607185
Shelby, M.D., and Zeiger, E. (1990). Activity of human carcinogens in the Salmonella and rodent bone-marrow cytogenetics tests. Mutat. Res. 234, 257–261.2366790
Shelby, M.D., Erexson, G.L., Hook, G.J., and Tice, R.R. (1993). Evaluation of a three-exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ. Mol. Mutagen. 21, 160–179.8444144
Shirley, E. (1977). A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics 33, 386–389.884197
Sistare, F.D., Thompson, K.L., Honchel, R., and DeGeorge, J. (2002). Evaluation of the Tg.AC transgenic mouse assay for testing the human carcinogenic potential of pharmaceuticals — practical pointers, mechanistic clues, and new questions. Int. J. Toxicol. 21, 65–79.11936901
Slaga, T.J., DiGiovanni, J., Winberg, L.D., and Budunova, I.V. (1995). Skin carcinogenesis: Characteristics, mechanisms, and prevention. Prog. Clin. Biol. Res. 391, 1–20.8532708
Smith, W.D.L. (1977). Allergic dermatitis due to a triacrylate in ultraviolet cured inks. Contact Dermatitis 3, 312–314.146587
Spalding, J.W., French, J.E., Tice, R.R., Furedi-Machacek, M., Haseman, J.K., and Tennant, R.W. (1999). Development of a transgenic mouse model for carcinogenesis bioassays: Evaluation of chemically induced skin tumors in Tg.AC mice. Toxicol. Sci. 49, 241–254.10416269
Spalding, J.W., French, J.E., Stasiewicz, S., Furedi-Machacek, M., Conner, F., Tice, R.R., and Tennant, R.W. (2000). Responses of transgenic mouse lines p53(+/–) and Tg.AC to agents tested in conventional carcinogenicity bioassays. Toxicol. Sci. 53, 213–223.10696769
Straus, D.S. (1981). Somatic mutation, cellular differentiation, and cancer causation. JNCI 67, 233–241.7021938
Tarone, R.E. (1975). Tests for trend in life table analysis. Biometrika 62, 679–682.
Tennant, R.W., Margolin, B.H., Shelby, M.D., Zeiger, E., Haseman, J.K., Spalding, J., Caspary, W., Resnick, M., Stasiewicz, S., Anderson, B., and Minor, R. (1987). Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science 236, 933–941.3554512
Tennant, R.W., Stasiewicz, S., Eastin, W.C., Mennear, J.H., and Spalding, J.W. (2001). The Tg.AC (v-Ha-ras) transgenic mouse: Nature of the model. Toxicol. Pathol. 29, 51–59.11695562
Thompson, K.L, Rosenzweig, B.A., and Sistare, F.D. (1998). An evaluation of the hemizygous transgenic Tg.AC mouse for carcinogenicity testing of pharmaceuticals. II. A genotypic marker that predicts tumorigenic responsiveness. Toxicol. Pathol. 26, 548–555.9715514
Thompson, K.L., Rosenzweig, B.A., Honchel, R., Cannon, R.E., Blanchard, K.T., Stoll, R.E, and Sistare, F.D. (2001). Loss of critical palindromic transgene promoter sequence in chemically induced Tg.AC mouse skin papillomas expressing transgene-derived mRNA. Mol. Carcinog. 32, 176–186.11746829
Trempus, C.S., Mahler, J.F., Ananthaswamy, H.N., Loughlin, S.M., French, J.E., and Tennant, R.W. (1998). Photocarcinogenesis and susceptibility to UV radiation in the v-Ha-ras transgenic Tg.AC mouse. J. Invest. Dermatol. 111, 445–451.9740239
Union Carbide Corporation (1979). Evaluation of the Dermal Carcinogenic Potential of Pentaerythritol Acrylate-HF (Project Report No. 42-105). Conducted by The Chemical Hygiene Fellowship of Carnegie Mellon Institute of Research, Pittsburgh, PA, for Union Carbide Corporation, Danbury, CT.
Union Carbide Corporation (1988). Evaluation of the Dermal Carcinogenic Potential of Pentaerythritol Acrylate-HF: Cover letter dated 072888. Conducted by The Chemical Hygiene Fellowship of Carnegie Mellon Institute of Research, Pittsburgh, PA, for Union Carbide Corporation, Danbury, CT.
U.S. Environmental Protection Agency (USEPA) (1991). TSCAPP: 1983 Production Statistics for Chemicals in the Nonconfidential Initial TSCA Chemical Substances Inventory. Office of Pesticides and Toxic Substances, Washington, D.C.
Van Miller, J.P., Garman, R.H., Hermansky, S.J., Mirsalis, J.C., and Frederick, C.B. (2003). Skin irritation, basal epithelial cell proliferation, and carcinogenicity evaluations of a representative specialty acrylate and methacrylate. Regul. Toxicol. Pharmacol. 37, 54–65.12662909
Williams, D.A. (1971). A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics 27, 103–117.5547548
Williams, D.A. (1972). The comparison of several dose levels with a zero dose control. Biometrics 28, 519–531.5037867
Witt, K.L., Knapton, A., Wehr, C.M., Hook, G.J., Mirsalis, J., Shelby, M.D., and MacGregor, J.T. (2000). Micronucleated erythrocyte frequency in peripheral blood of B6C3F_1_ mice from short-term, prechronic, and chronic studies of the NTP Carcinogenesis Bioassay Program. Environ. Mol. Mutagen. 36, 163–194.11044899
Yamamoto, S., Urano, K., and Nomura, T. (1998). Validation of transgenic mice harboring the human prototype C-Ha-ras gene as a bioassay model for rapid carcinogenicity testing. Toxicol. Lett. 102-103, 473–478.10022298
Zeiger, E., Anderson, B., Haworth, S., Lawlor, T., Mortelmans, K., and Speck, W. (1987). Salmonella mutagenicity tests: III. Results from the testing of 255 chemicals. Environ. Mutagen. 9 (Suppl. 9), 1–110.
Zeiger, E., Haseman, J.K., Shelby, M.D., Margolin, B.H., and Tennant, R.W. (1990). Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: Confirmation of earlier results with 41 additional chemicals. Environ. Mol. Mutagen. 16 (Suppl. 18), 1–14.