# DISCUSSION AND CONCLUSIONS

Pentaerythritol triacrylate and trimethylolpropane triacrylate are representative multifunctional acrylates. Chemically, multifunctional acrylates are esters of acrylic acid esterified to a polyhydroxy backbone molecule. Pentaerythritol triacrylate is a triester of acrylic acid with pentaerythritol, and trimethylolpropane triacrylate is a triester of acrylic acid with trimethylol propane.

Monofunctional acrylates, such as ethyl acrylate, and multifunctional acrylates, such as pentaerythritol triacrylate and trimethylolpropane triacrylate, readily undergo free radical polymerization initiated by a peroxy compound or by ultraviolet light. They are therefore used in photocurable inks and in other applications requiring the use of photocurable resins. Multifunctional acrylates are also used in glues and adhesives and in the manufacture of acrylic-based paints. The NTP studied both pentaerythritol triacrylate and trimethylolpropane triacrylate for toxicity and carcinogenicity. Results of the trimethylolpropane triacrylate studies are reported separately (NTP, 2005).

Human exposure to multifunctional acrylates has been documented only in occupational settings and has involved primarily dermal exposure (NIOSH, 1990). Workers involved in the manufacture, processing, product handling, and application of pentaerythritol triacrylate are at risk of exposure (Parker and Turk, 1983). However, the widespread use of these compounds in the manufacture of consumer products such as latex paints and floor polishes suggests a potential for significant nonoccupational exposure (Dearfield et al., 1989).

From the available data in the literature, the critical effects of multifunctional acrylates are skin and eye irritation. Also, some members of the multifunctional acrylate class are moderate to strong sensitizers in humans, but findings in animals are conflicting. Pentaerythritol triacrylate was not detected as a sensitizer in repeated-insult patch testing or in guinea pigs using the Buehler method. However, pentaerythritol triacrylate was positive in a guinea pig maximization test (Andrews and Clary 1986). The NTP has tested pentaerythritol triacrylate for its ability to induce hypersensitivity and irritancy in a rodent model (Appendix K). Pentaerythritol triacrylate was found to be an irritant in BALB/c mice at concentrations greater than 0.25%. Pentaerythritol triacrylate was found to be a sensitizing agent in BALB/c mice in the mouse ear swelling test at concentrations greater than 0.1% and in the local lymph node assay at concentrations greater than 0.25%. These studies suggest that pentaerythritol triacrylate has the potential to induce contact hypersensitivity responses in rodents and humans.

Repeated dermal exposure to acrylates including pentaerythritol triacrylate led to contact dermatitis in laboratory animals and humans (Andrews and Clary, 1986); the current 2-week and 3-month studies confirmed these findings. Skin was the major target organ of pentaerythritol triacrylate toxicity in the current studies. The chemical caused dose-related hyperplastic, vacuolar degenerative, and ultimately necrotizing lesions of the epidermis, accompanied by hyperplasia of sebaceous glands and a dermal chronic inflammation in male and female rats and mice. Rats had slightly more severe skin lesions than mice in the 2-week and 3-month studies. The systemic toxicity was minimal based on the results from clinical pathology, histopathology, and organ weight changes. In rats, a no-observed-adverse-effect level (NOAEL) for dermal lesions was not attained; the NOAEL for dermal effects was determined to be 0.75 mg/kg for male mice and less than 0.75 mg/kg for female mice.

The dose-related skin effects such as irritation, inflammation, and sustained hyperplasia at the site of application in rats and mice in the 3-month studies suggested pentaerythritol triacrylate may be a dermal carcinogen. Several studies have established that the induction of sustained cellular hyperplasia correlates well with the skin tumor formation ability of various tumor-promoting agents such as phorbol esters, several peroxides, and chrysarobin (Argyris, 1981; Hennings et al., 1993; Slaga et al., 1995). The NTP typically performs carcinogenicity studies in two species, rats and mice. Because skin was the only major organ of toxicity in the 2-week and 3-month studies, dermal carcinogenicity studies were conducted in mice only. For more than 60 years, studies have established the mouse as a sensitive animal model for epidermal carcinogenesis induced by chemical carcinogens (DiGiovanni, 1991). In addition, the mouse is thought to be an appropriate model for skin squamous cell cancer development in humans because of evidence that the known genetic aberrations in tumor cells are similar in human and mouse skin, especially mutational activation of the H-ras oncogene (Nagase et al., 1996).

When the current 3-month studies in rats and mice were completed, the NTP was evaluating several transgenic mouse models to supplement or replace the traditional 2-year bioassay studies in mice. The Tg.AC mouse model was showing promise for carcinogenicity testing (hazard identification) via dermal exposure. Efforts were under way to assess more fully the model’s potential. The major route of human exposure to pentaerythritol triacrylate is via the skin. Therefore, the NTP decided to conduct initial studies in the Tg.AC model, and upon completion of these studies, assess their findings in light of updated information about the Tg.AC model. Even if testing in additional species or strains were necessary, the Tg.AC studies would add to the body of knowledge concerning the Tg.AC model’s potential. This allowed assessment of the Tg.AC model in a completely prospective manner and provided an excellent test of the model.

Leder et al. (1990) developed a transgenic mouse model with an inducible zeta-globin promoter driving the expression of a mutated v-H-ras oncogene (the Tg.AC mouse). With the exception of the bone marrow, constitutive expression of the transgene cannot be detected in adult tissues. The transgene is transcriptionally silent until activated by full-thickness wounding, ultraviolet light, or specific chemical exposure (Cannon et al., 1997; Trempus et al., 1998). Topical application of carcinogens to the shaved dorsal surface of Tg.AC mice induces epidermal squamous cell papillomas or carcinomas, a reporter phenotype that defines the activity of the chemical. The oral route of administration can also generate tumorigenic responses in Tg.AC mice and result in squamous cell papillomas or carcinomas of the forestomach. To date, the induction of either spontaneous or induced neoplasms has been shown to require activation of transgene expression. Thus, the Tg.AC model could be viewed as genetically initiated due to the presence of the transgene. The model responds to both genotoxic and nongenotoxic carcinogens (Spalding et al., 1999, 2000; Tennant et al., 2001). The Tg.AC mouse model’s usefulness and limitations in detecting chemical carcinogens have been evaluated and published (Spalding et al., 2000; Eastin et al., 2001; Tennant et al., 2001; Pritchard et al., 2003, Sistare et al., 2002).

In mouse dermal carcinogenicity studies, squamous cell papillomas are used as an endpoint of the assay. Some of these papillomas have the potential to progress to squamous cell carcinomas, so they may be regarded as precursor neoplasms, and they may be a quantitative indicator of a carcinogenic process (Enzmann et al., 1998). The results of the current 6-month study clearly show the carcinogenic activity of pentaerythritol triacrylate at the site of application in the Tg.AC mice. The increased incidences of squamous cell papilloma were dose related in males and females. The incidences of papilloma were significantly increased in 3, 6, and 12 mg/kg males and females. Squamous cell carcinomas occurred in a few animals and the presence at the base of a papilloma in some suggested they arose from the papilloma. Increased incidences of nonneoplastic lesions also occurred at the site of application and included mild chronic active inflammation, hyperplasia of the epidermis, and hyperkeratosis in males and females.

The carcinogenic potential of pentaerythritol triacrylate was evaluated in three previous dermal studies in C3H/HeJ mice. DePass et al. (1985) found no tumors in treated animals. The number of grossly visible liver neoplasms was significantly increased in another study in which no treatment-related tumors were found on the skin; only gross lesions were examined histopathologically, and therefore, the actual incidence of liver neoplasms was not determined (Union Carbide, 1988; NCI, 1987). Dermal carcinogenicity studies on eight multifunctional acrylates including pentaerythritol triacrylate were conducted by the Celanese Corporation in C3H/HeJ mice (Andrews and Clary, 1986). Pentaerythritol triacrylate was administered to the intrascapular region of the skin twice weekly at a dose concentration of 100 mg/kg in mineral oil for 80 weeks. Slightly epilated and crusted skin with acanthosis and fibrosis was noted, but no papillomas were induced. Six of 50 mice treated with pentaerythritol triacrylate were reported to have lymphomas; these were not verified on subsequent reexamination (NCI, 1987). No systemic neoplasms related to pentaerythritol triacrylate administration were observed in the current study. The absence of carcinogenic activity in the Celanese studies could be due to the differences in experimental design and strain of mouse used. The dose concentration, 100 mg/kg, was more than eight times the highest dose (12 mg/kg) in the current study. No major effects on the skin were noted, most likely due to the use of mineral oil as a vehicle. Mineral oil is known to ameliorate the irritating properties of chemicals (Nessel et al., 1999).

Because the Tg.AC mouse model is a reporter phenotype used to predict potential systemic carcinogenicity in humans, it is important to know if the material is likely to be absorbed via dermal exposure in humans. Because of nonavailability of radiolabeled material, it was not determined if, or to what extent, pentaerythritol triacrylate was absorbed via the skin in the current study. There was, however, indirect evidence that pentaerythritol triacrylate would likely be absorbed. Absorption studies of trimethylolpropane triacrylate were successful, and trimethylolpropane triacrylate was absorbed via the dermal route in the Tg.AC mouse (NTP, 2005). Also, systemic lesions including chronic inflammation, hematopoietic cell proliferation, and myelodysplasia may have indicated some systemic exposure; however, these lesions may also have been secondary to the observed skin lesions.

The NTP has studied two monofunctional acrylates, ethyl acrylate (NTP, 1986a) and methyl methacrylate (NTP, 1986b), for carcinogenicity. Ethyl acrylate administered by gavage produced squamous cell papillomas in the forestomach of rats and mice at the doses that also induced considerable nonneoplastic pathology. Interestingly, ethyl acrylate was negative when dermally administered to the Tg.AC mouse (Nylander-French and French, 1998) and positive when given by gavage to another short-term ras model, the ras-H2 mouse (Yamamoto et al., 1998). Methyl methacrylate was not carcinogenic in rats or conventional mice when administered by inhalation for 2 years (NTP, 1986b). Of the eight multifunctional acrylates studied by the Celanese Corporation, two induced skin tumors at the site of application (Andrews and Clary, 1986). All these studies, including pentaerythritol triacrylate, suggest that carcinogenic activity of acrylates is expressed at the site of application only.

Insertion of the zeta-globin promoted v-Ha-ras trans-gene into the FVB mouse genome (Tg.AC) introduces a defined genetic lesion that is critical but insufficient by itself to induce benign or malignant tumors in skin unless activated. Activation and expression of the transgenic ras oncoprotein in this mouse line induces dose-related increases in papillomas (skin reporter phenotype) within weeks. In the current 6-month study, pentaerythritol triacrylate induced dose-related increases in the incidence of squamous cell papilloma, with neoplasms appearing as early as 9 weeks. Some neoplasms progressed to carcinoma by the end of the study. Two other multifunctional acrylates, tripropylene glycol diacrylate (Nylander-French and French, 1998) and trimethylolpropane triacrylate (NTP, 2005) induced skin papillomas in this model as well, suggesting the model is responsive to multifunctional acrylates. The Tg.AC model appears to respond to both genotoxic and nongenotoxic carcinogens. Chemically induced sustained cell proliferation may be an important component of the multistage process of mouse skin carcinogenesis, particularly for nongenotoxic carcinogens.

Pentaerythritol triacrylate was demonstrated to be a skin irritant and contact sensitizer, while trimethylolpropane triacrylate was characterized as an irritant with much weaker sensitizing potential than pentaerythritol triacrylate (NTP, 2005). Both compounds resulted in a positive papilloma response in the Tg.AC mouse. A review of the literature suggests that other known skin sensitizers are also positive when tested in the Tg.AC model including tripropylene glycol diacrylate, which, like trimethylolpropane triacrylate and pentaerythritol triacrylate, is a multifunctional acrylate (Nylander-French and French, 1998).

Resorcinol was nonmutagenic in Salmonella studies and was negative in 2-year NTP gavage studies in F344/N rats and B6C3F_1_ mice (NTP, 1992). It is known to produce skin sensitization in humans and mice, and has been used to produce skin peeling in humans (Harvey, 1980). In topical studies in the Tg.AC mouse, resorcinol gave a strong skin papilloma response in males and females. Dinitrofluorobenzene is another contact sensitizer that induced neoplasms in the Tg.AC mouse (Albert et al., 1996). In this study, the corticosteroid fluocinolone acetonide was used to block the cell mediated immune response; however, tumor induction still occurred. The authors concluded that cytotoxic property of dinitrofluorobenzene likely accounted for the tumorigenic response in this study.

In addition, based on positivity in the local lymph node assay, there are several other contact sensitizers (NTP, 1999) that were reviewed for tumor response in the Tg.AC mouse by Pritchard et al. (2003). A number of these chemicals were positive in the Tg.AC mouse, including pentachlorophenol, benzo[a]pyrene, and 7,12-dimethylbenzanthracene. The relationship is not straightforward though, as pyridine is a sensitizer that was negative in the transgenic mouse assay.

Contact sensitizers are generally electrophilic chemicals that produce protein adduction. Suggestive evidence of an overlap with carcinogens comes from structure-activity alerts for contact sensitizers (Barratt et al., 1994) and carcinogens (Ashby and Tennant, 1994). The possible relationship between induction of skin sensitization and activation of the transgene in Tg.AC mice may merit further study.

An increase in cell replication enhances all steps of neoplastic transformation and tumor development (Enzmann et al., 1998). However, in NTP dermal carcinogenicity studies on rotenone in Tg.AC mice, no papillomas were observed despite the extensive hyperplasia and inflammation in skin at the site of application (Eastin et al., 1998). This result suggests that the mechanism of skin papilloma formation is not yet clearly understood. Repeated dermal administration of pentaerythritol triacrylate in current studies caused sustained epidermal cell proliferation that led to formation of papillomas, a major characteristic of the known neoplasm promoters.

A systemic change was diagnosed in five 12 mg/kg male mice in the current 6-month pentaerythritol triacrylate study that involved one to several organs and had characteristics that variably resembled hematopoietic, inflammatory, and neoplastic processes. The most consistent presentation was an aberrant infiltration and/or proliferation of granulocyte-rich inflammatory cells. The major granulocyte component was the eosinophil, an inflammatory cell type usually associated with immune reactions or parasitic infections. The liver was the organ most frequently affected, although other tissues (epididymis, kidney, spleen, heart, lung, lymph nodes, and thymus) were also affected. The bone marrow, a site that would be expected to be affected, was not microscopically examined in these studies. Because of the variable morphology and uncertain biological behavior, assigning an appropriate diagnostic term was problematic. In its more severe form, the lesion may have resulted from infiltration and/or proliferation, and was diagnosed as myelodysplasia (Mahler et al., 1998). In milder cases, component cells appeared more infiltrative and the change was diagnosed as cellular infiltration. Separating the milder lesions from inflammation and extramedullary hematopoiesis was difficult.

This lesion complex, even in the severe state, appears to be nonneoplastic. This determination is based primarily on morphologic criteria used to distinguish granulocytic hyperplasia and granulocytic leukemia (Long et al., 1986), including the presence of granulocytes in multiple stages of maturation, as well as cells from other lineages such as megakaryocytes. In addition, recent studies suggest that myelodysplasia is a reversible lesion when the inciting chemical stimulus is withdrawn (C. Trempus, personal communication), further suggesting that it is a nonneoplastic process. Myelodysplasia has been previously reported in only one other Tg.AC mouse study of rotenone (Mahler et al., 1998). It has not been observed in untreated Tg.AC mice, and was not present in the vehicle controls in the current study. It has not been reported in other strains of mice; however, in subsequent studies of rotenone involving the Tg.AC and the parent FVB/N strain, it was identified in both (R. Maronpot, personal communication). In the rotenone study, epidermal hyperplasia and dermal inflammation were found at the site of application, but squamous papillomas were not induced, indicating that epidermal tumors are not required for the induction of myelodysplasia (Eastin et al., 1998). Since ras mutations are associated with myeloproliferative disorders (Liu, 1990), the activated v-Ha-ras oncogene in the genome of Tg.AC mice may predispose this strain to exuberant hematopoietic proliferation and infiltration, and myelodysplasia may be one manifestation of this genomic defect, triggered by an inflammatory stimulus (e.g. the skin). It is also possible that myelodysplasia represents an atypical hypersensitivity reaction in this strain. Clearly additional studies are needed to further clarify the biology of this lesion.

Hematopoietic cell proliferation occurred in the liver, spleen, and mandibular lymph node of animals in the 6 and 12 mg/kg groups. This reaction may have been at least partially due to the inflammatory stimulus at the skin site of application. Enhanced expression of hematopoietic cytokines by mouse epidermal tumor cells has also been demonstrated (Bauluz et al., 1994), suggesting that some of this response may have been due to treatment-induced squamous papillomas at the site of application.

The lack of mutagenic activity with pentaerythritol triacrylate in the Salmonella assay (Zeiger et al., 1987) combined with the negative results in the 3-month peripheral blood micronucleus test supports a nongenotoxic mode of action for this chemical. However, the positive results from other in vitro genotoxicity assays employing endpoints that are associated with chromosomal breakage events (Dearfield et al., 1989), along with the significant increase of micronucleated normochromatic erythrocytes seen in female Tg.AC mice treated with pentaerythritol triacrylate for 6 months (Appendix C), also indicate a potential for a genotoxic mode of action. Therefore, the available evidence does not permit classification of pentaerythritol triacrylate as either a genotoxic or a nongenotoxic carcinogen. Additional studies are needed to understand the mechanism of skin neoplasm formation by pentaerythritol triacrylate.

## Conclusions

Male and female Tg.AC hemizygous mice dosed with pentaerythritol triacrylate for 6 months had significantly increased incidences of squamous cell papilloma of the skin at the site of dermal application. Treatment-related squamous cell carcinomas occurred at the site of application in male mice.

Nonneoplastic lesions noted at the site of application included hyperkeratosis, chronic active inflammation, and epidermal hyperplasia. A hematopoietic disorder (myelodysplasia) occurred in dosed male mice.