# MATERIALS AND METHODS

## Procurement and Characterization

### Pentaerythritol Triacrylate

Pentaerythritol triacrylate was obtained in two lots. Lot 05318JW, obtained from Aldrich Chemical Company (Milwaukee, WI), was used during the 2-week studies, and lot HCC0340, obtained from Sartomer Company (Exton, PA), was used during the 3- and 6-month studies. Identity, moisture content, purity, and stability analyses were conducted by the analytical chemistry laboratories and the study laboratory (Battelle Columbus Laboratories, Columbus, OH). Reports on analyses performed in support of the pentaerythritol triacrylate studies are on file at the National Institute of Environmental Health Sciences.

The chemical, a clear, viscous liquid, was identified as pentaerythritol triacrylate using infrared spectroscopy and proton and carbon-13 nuclear magnetic resonance spectroscopy. All spectra were consistent with the structure of pentaerythritol triacrylate; the infrared spectrum was also consistent with a literature spectrum (Aldrich, 1985). The nuclear magnetic resonance spectra indicated a significant number of structurally related impurities in each lot.

The purity of lot 05318JW was determined by Galbraith Laboratories, Inc. (Knoxville, TN), using elemental analyses and by the analytical laboratory using gas chromatography, high-performance liquid chromatography (HPLC), and HPLC with mass spectrometry (HPLC/MS). The purity of lot HCC0340 was determined by the analytical and study laboratories using HPLC. Moisture content was determined by Galbraith Laboratories using Karl Fischer titration.

For lot 05318JW, elemental analyses for carbon, hydrogen, and oxygen were in agreement with the theoretical values for pentaerythritol triacrylate. Karl Fischer titration indicated approximately 943 ppm water. Gas chromatography indicated one major peak, five impurities with areas greater than 1% relative to the major peak area, and six impurities with relative areas between 0.5% and 1%. HPLC indicated a major peak, 18 impurities with areas greater than 1% relative to the major peak area, and five impurities with relative areas between 0.5% and 1%; the concentration of pentaerythritol triacrylate was determined to be approximately 10%. HPLC/MS indicated that eight of the 18 impurity components with relative areas greater than 1% included structurally related adducts, dimers, and acrylates as well as trimethylolpropane triacrylate and its related esters and adducts. No substantial amount of 4-methoxyphenol, a stabilizer added to pentaerythritol triacrylate, was detected. The overall purity of lot 05318JW was determined to be approximately 10% pentaerythritol triacrylate.

For lot HCC0340, HPLC indicated a major peak, seven impurity components with areas greater than 1% of the major peak area, and nine impurity components with relative areas between 0.5% and 1%. By comparison of the retention times of these impurity components to those in the HPLC/MS analysis of lot 05318JW, the impurities were tentatively identified as structurally related adducts, dimers, and acrylates as well as trimethylolpropane triacrylate and its related esters and adducts. The overall purity of lot HCC0340 was determined to be approximately 45% pentaerythritol triacrylate.

To ensure stability, the bulk chemical was stored at room temperature, protected from light in amber glass bottles with Teflon^®^-lined lids. Stability was monitored throughout the studies with gas chromatography. No degradation of the bulk chemical was detected.

### 12-O-Tetradecanoylphorbol-13-acetate

12-O-Tetradecanoylphorbol-13-acetate was obtained from Sigma Chemical Company (St. Louis, MO) in one lot (48H1178) for use in the 6-month study. Identity and purity analyses were conducted by the analytical chemistry laboratory, Research Triangle Institute (Research Triangle Park, NC). The bulk chemical was stored in its original containers, protected from light, at −20° C or less.

The chemical was identified as 12-O-tetradecanoylphorbol-13-acetate by infrared and proton NMR spectroscopy. The purity was determined with HPLC, which indicated a major peak, one impurity peak with an area of approximately 0.11% of the total peak area, and two minor impurities with areas less than 0.1% of the total peak area. The overall purity was determined to be greater than 99%.

### Acetone

Acetone was obtained in two lots from Honeywell Burdick and Jackson (Muskegon, MI) (lots BK792 and BL631) and in five lots from Spectrum Chemical Manufacturing Corporation (Gardena, CA) (lots JE342, KP206, LS0051, MI0172, and NE0173). Lots BK792, BL631, and JE342 were used in the 2-week studies, lots KP206 and LS0051 were used in the 3-month studies, and lots MI0172 and NE0173 were used in the 6-month study. Identity and purity analyses of lots BL631 and JE342 and all lots used in the 3- and 6-month studies were conducted by the analytical chemistry laboratory (Midwest Research Institute, Kansas City, MO) and the study laboratory.

The chemical, a clear liquid, was identified as acetone by the analytical chemistry laboratory (lots BL631, JE342, KP206, and LS0051) or the study laboratory (lots MI0172 and NE0173) using infrared spectroscopy. The purity was analyzed by the analytical chemistry laboratory (lots BL631, JE342, KP206, and LS0051) or the study laboratory (lots MI0172 and NE0173) using gas chromatography. No significant impurities were detected in any lot. The overall purity of each lot was determined to be greater than 99%.

To ensure stability, the bulk chemical was stored in amber glass bottles at room temperature. No degradation of the acetone was detected.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared twice (2-week studies) or approximately every 4 weeks by mixing pentaerythritol triacrylate and acetone to give the required concentration. The dose formulations were stored for up to 35 days for all studies at room temperature in amber glass bottles with Teflon^®^-lined lids except dose formulations prepared on September 9 and 12, 1996 (3-month studies), which were stored in amber (rat) or clear (mouse) glass vials with Teflon^®^ septa. Positive control formulations for the 6-month study were prepared twice by mixing 12-O-tetradecanoylphorbol-13-acetate with acetone to provide a concentration of 12.5 µg/mL.

Stability studies of the 6.25 and 100 mg/mL dose formulations for the 2-week studies and a 400 µg/mL formulation were performed by the study laboratory with gas chromatography. Stability was confirmed for at least 35 days for dose formulations stored in amber glass bottles with Teflon^®^-lined lids or septa, with minimal head-space, at temperatures up to 25° C and for 3 hours under animal room conditions, periodically or continually exposed to air and light.

Periodic analyses of the dose formulations of pentaerythritol triacrylate were conducted by the study laboratory using gas chromatography. The dose formulations were analyzed once during the 2-week studies; all dose formulations for rats and mice were within 10% of the target concentration. Animal room samples of these dose formulations were also analyzed; all animal room samples for rats and three of five for mice were within 10% of the target concentration. During the 3-month studies, the dose formulations were analyzed at the beginning, midpoint, and end of the studies; animal room samples of these dose formulations were also analyzed. Of the dose formulations analyzed, all 15 for rats and 14 of 15 for mice were within 10% of the target concentration; 10 of 15 animal room samples for rats and nine of 15 for mice were within 10% of the target concentration. During the 6-month study, the dose formulations were analyzed every 8 or 9 weeks. Of the dose formulations analyzed, 14 of 15 were within 10% of the target concentration; all five animal room samples were also within 10% of the target concentration. The single dose formulation in each of the 3- and 6-month studies that was not within 10% of the target concentration was remixed and reanalyzed and was found to be within 10% of the target concentration. The positive control formulations were analyzed by the analytical chemistry laboratory using HPLC with a system similar to that described for the positive control purity analysis and were found to be within 10% of the target concentration.

## 2-Week Studies

Male and female F344/N rats and B6C3F_1_ mice were obtained from Taconic Laboratory Animals and Services (Germantown, NY). On receipt, the rats and mice were 4 weeks old. Animals were quarantined for 11 days (rats) or 12 days (mice) and were 6 weeks old on the first day of the studies. Before the studies began, two male and two female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Groups of five male and five female rats and mice received dermal applications of 0, 12.5, 25, 50, 100, or 200 mg pentaerythritol triacrylate/kg body weight in acetone 5 days per week for 17 days; the dosing volumes were 0.5 mL/kg body weight for rats and 2 mL/kg for mice. Feed and water were available ad libitum. Rats and mice were housed individually. The animals were weighed initially, on day 8, and at the end of the studies; clinical findings were recorded daily. Details of the study design and animal maintenance are summarized in Table 1.

Necropsies were performed on all rats and mice. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Histopathologic examinations were performed on the skin (site of application) of all rats and mice and the thymus of all mice.

## 3-Month Studies

The 3-month studies were conducted to evaluate the cumulative toxic effects of repeated exposure to pentaerythritol triacrylate and to determine the appropriate doses to be used in the 6-month study.

Male and female F344/N rats and B6C3F_1_ mice were obtained from Taconic Laboratory Animals and Services. On receipt, the rats and mice were 4 weeks old. Animals were quarantined for 12 to 15 days and were 6 weeks old on the first day of the studies. Before the studies began, two male and two female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. During week 4 and at the end of the studies, serologic analyses were performed on five male and five female sentinel rats and mice using the protocols of the NTP Sentinel Animal Program (Appendix J).

Groups of 10 male and 10 female rats and mice received dermal applications of 0, 0.75, 1.5, 3, 6, or 12 mg/kg in acetone 5 days per week for 14 weeks; the dosing volumes were 0.5 mL/kg for rats and 2 mL/kg for mice. Additional groups of 10 male and 10 female rats designated for clinical pathology testing received the same doses for 23 days. Feed and water were available ad libitum. The feed was irradiated to reduce potential microbial contamination. Rats and mice were housed individually. The animals were weighed initially, weekly, and at the end of the studies; clinical findings were recorded weekly and at necropsy. Details of the study design and animal maintenance are summarized in Table 1.

Blood was collected from the retroorbital sinus of clinical pathology study rats on days 4 and 23 and from all core study rats and mice at the end of the studies for hematology and clinical chemistry (rats only) analyses. The animals were anesthetized with a mixture of carbon dioxide and oxygen. Samples for hematology analysis were placed in micro-collection tubes (Sarstedt, Inc., N5mbrecht, Germany) coated with potassium EDTA and inverted on an aliquot mixer to prevent clotting; samples for clinical chemistry evaluations were placed in serum separator tubes devoid of anticoagulant and centrifuged for the collection of serum. Hematocrit; hemoglobin concentration; erythrocyte, platelet, and leukocyte counts; mean cell volume; mean cell hemoglobin; and mean cell hemoglobin concentration were determined with a Cell-Dyn^®^ hematology analyzer (Abbott Diagnostics, Santa Clara, CA). Differential leukocyte counts and erythrocyte and platelet morphologies were determined microscopically from blood smears stained with a modified Wright-Giemsa stain. A Miller Disc was used to determine reticulocyte counts from smears prepared with blood stained with new methylene blue. For clinical chemistry analyses, serum samples were analyzed using a Hitachi 911^®^ chemistry analyzer (Boehringer Mannheim, Indianapolis, IN) and commercially available reagents. The parameters measured are listed in Table 1.

At the end of the 3-month studies, samples were collected for sperm count and motility and vaginal cytology evaluations on core study rats and mice in the vehicle control and the 3, 6, and 12 mg/kg groups. The parameters evaluated are listed in Table 1. For 12 consecutive days prior to scheduled terminal sacrifice, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65° C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all core study animals. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed on all core study rats and mice in the vehicle control and 12 mg/kg groups. The skin at the site of application was examined microscopically for core study animals in all groups. Table 1 lists the tissues and organs routinely examined.

## 6-Month Study

### Study Design

Groups of 15 male and 15 female mice received dermal applications of 0, 0.75, 1.5, 3, 6, or 12 mg/kg in acetone, 5 days per week, for 27 weeks; the dosing volume was 3.3 mL/kg. Additional groups of 15 male and 15 female mice maintained as positive controls received dermal applications of 1.25 µg 12-O-tetradecanoylphorbol-13-acetate per 100 mL acetone 3 days per week for 28 weeks; the dosing volume was held constant at 100 µL.

### Source and Specification of Animals

The foundation colony of FVB/N-TgN(v-Ha-ras) (i.e. Tg.AC) mice was reestablished in 1998 after observation of some Tg.AC mice that were nonresponsive to the tumor promoter 12-O-tetradecanoyl-phorbol-13-acetate after treatment with a defined exposure regimen known to induce skin papillomas at the site of application. The homozygous FVB/N-TgN(v-Ha-ras) (i.e. Tg.AC) colony was established using homozygous breeders showing an unequivocal pattern of bands of restriction enzyme digests of DNA (Thompson et al., 1998, 2001; Honchel et al., 2001) demonstrating a specific phenotype for the induction of papillomas by 12-O-tetradecanoyl-phorbol-13-acetate. All foundation colony breeders homozygous for the transgene are genotyped and test-mated with wildtype FVB mice and qualified as a homozygous transgenic mouse with a responder phenotype. Homozygous male breeders obtained from the litters of qualified homozygous foundation colonies were further qualified by test mating with wild type FVB/N mice and used to produce hemizygous Tg.AC mice. All Tg.AC hemizygous male and female mice are the product of this continuing quality control of the foundation and production colony.

Male and female Tg.AC hemizygous mice were obtained from the NIEHS/NTP colony at Taconic Laboratory Animals and Services. On receipt, the mice were 4 weeks old. Mice were quarantined for 11 days and were 6 weeks old on the first day of the studies. Before the study began, five male and five female mice were randomly selected for parasite evaluation and gross observation of disease. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix J).

### Animal Maintenance

Mice were housed individually. The core study mice were housed in the same room with positive control mice and mice in the trimethylolpropane triacrylate study (NTP, 2005). Feed and water were available ad libitum. The feed was irradiated to reduce potential microbial contamination. Cages and racks were rotated every 2 weeks. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is provided in Appendix I.

### Clinical Examinations and Pathology

The animals were observed twice daily and were weighed initially, weekly, and at the end of the study. Clinical findings were recorded weekly and at the end of the study.

In-life observations of papilloma formation on the skin were recorded weekly using the Toxicology Data Management System (TDMS). A papilloma was initially recorded as a mass. The observation “papilloma” was not entered into TDMS for a given animal until the first-observed mass was documented for 3 consecutive weeks. At the third observation, the mass (wart-like in appearance) was entered as a papilloma. Any new mass(es) appearing after the 3-week confirmation period for a given animal at a different site was entered into TDMS first as a mass until the third week, when it was entered as a papilloma. In a few instances, a papilloma that had been previously observed was missing, and therefore not recorded. Reappearance of a mass at a later time was entered into TDMS as a mass until the third observation week, when it was called a papilloma.

Necropsies and histopathologic examinations were performed on all core study mice. The heart, right kidney, liver, lung, right testis, and thymus were weighed. At necropsy, all organs and tissues were examined for grossly visible lesions, and selected tissues were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 5 µm, and stained with hematoxylin and eosin for microscopic examination. The tissues selected for microscopic evaluation represented gross lesions as well as major organs and tumor target tissues for mice in chronic rodent bioassays. These tissues were examined in all core study mice. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Because the Tg.AC model was initially intended to be a skin reporter phenotype, less emphasis was placed on microscopic examination of internal organs. However, with time and for a variety of reasons, more interest developed relative to effects in internal organs. Thus a reduced tissue list (compared to the standard 2-year bioassay) was adopted that included all tissues that are common targets in NTP carcinogenicity studies. While the gross examination would likely detect any significant carcinogenic effects, it is possible that chemically induced nonneoplastic lesions occurred in organs not examined. Tissues examined microscopically are listed in Table 1.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The slides, paraffin blocks, and residual wet tissues were sent to the NTP Archives for inventory, slide/block match, and wet tissue audit. The slides, individual animal data records, and pathology tables were sent to an independent quality assessment laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. A quality assessment pathologist evaluated all slides from nine male and nine female mice per group randomly selected from the vehicle control and 12 mg/kg groups and from all mice that died early. Slides of all tumors and of all skin sites of application, which was the primary target tissue, were reviewed. Selected slides of other potential target organs, including the liver, spleen, lymph nodes, epididymis, and testis, were also reviewed.

The quality assessment report and the reviewed slides were submitted to the NTP Pathology Review chairperson, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and quality assessment pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and quality assessment pathologists, or lesions of general interest were examined by the chairperson, NTP pathologist, and the pathology working group. When the NTP Pathology Review consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist, and NTP Pathology Review chairperson. Details of these review procedures have been described, in part, by Maronpot and Boorman (1982) and Boorman et al. (1985). For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al. (1986).

TABLE 1 Experimental Design and Materials and Methods in the Dermal Studies of Pentaerythritol Triacrylate

2-Week Studies | 3-Month Studies | 6-Month Study
Study Laboratory
Battelle Columbus Laboratories (Columbus, OH) | Battelle Columbus Laboratories (Columbus, OH) | Battelle Columbus Laboratories (Columbus, OH)
Strain and Species
F344/N rats | F344/N rats | Tg.AC [FVB/N-TgN(v-HA-ras)] hemizygous mice
B6C3F_1_ mice | B6C3F_1_ mice | Tg.AC [FVB/N-TgN(v-HA-ras)] hemizygous mice
Animal Source
Taconic Laboratory Animals and Service (Germantown, NY) | Taconic Laboratory Animals and Service (Germantown, NY) | Taconic Laboratory Animals and Services (Germantown, NY)
Time Held Before Studies
Rats: 11 days | Rats: 12 days (male) or 13 days (female) | 11 days
Mice: 12 days | Mice: 14 days (female) or 15 days (male)
Average Age When Studies Began
6 weeks | 6 weeks | 6 weeks
Date of First Dose
Rats: May 20, 1996 | Rats: September 16 (male) or 17 (female), 1996 | July 20, 1998
Mice: May 21, 1996 | Rats: September 16 (male) or 17 (female), 1996
| Mice: September 18 (female) or 19 (male), 1996
Duration of Dosing
5 days per week for 17 days | 5 days per week for 14 weeks | Core study: 5 days per week for 27 weeks
| | Positive control: 3 days per week for 28 weeks
Date of Last Dose
Rats: June 5, 1996 | Rats: December 17 (male) or 18 (female), 1996 | Core study: January 19-20 (male) or 20-21 (female), 1999
Mice: June 6, 1996 | Rats: December 17 (male) or 18 (female), 1996 | Core study: January 19-20 (male) or 20-21 (female), 1999
| Mice: December 19 (female) or 20 (male), 1996 | Positive control: January 27, 1999
Necropsy Dates
Rats: June 6, 1996 | Rats: December 17 (male) or 18 (female), 1996 | Core study: January 19-20 (male) or 20-21 (female), 1999
Mice: June 7, 1996 | Rats: December 17 (male) or 18 (female), 1996 | Core study: January 19-20 (male) or 20-21 (female), 1999
| Mice: December 19 (female) or 20 (male), 1996 | Positive control: January 27, 1999
Average Age at Necropsy
8 weeks | 19 weeks | 32 weeks
Size of Study Groups
5 males and 5 females | 10 males and 10 females | 15 males and 15 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 2-week studies | Same as 2-week studies
Animals per Cage
1 | 1 | 1
Method of Animal Identification
Tail tattoo | Tail tattoo | Tail tattoo
Diet
NTP-2000 pelleted diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed weekly | Same as 2-week studies, except feed was irradiated | Same as 3-month studies
Water
Tap water (Columbus municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum | Same as 2-week studies | Same as 2-week studies
Cages
Polycarbonate (Lab Products, Inc., Maywood, NJ), changed at least once per week, rotated every 2 weeks | Same as 2-week studies | Same as 2-week studies
Bedding
Sani-Chip® hardwood chips (P.J. Murphy Forest Products Corp., Montville, NJ), changed at least once per week | Same as 2-week studies, except bedding was irradiated | Same as 3-month studies
Cage Filters
Spun-bonded DuPont 2024 polyester (Snow Filtration Co., Cincinnati, OH), changed every 2 weeks | Same as 2-week studies | Same as 2-week studies
Racks
Stainless steel (Lab Products, Inc., Maywood, NJ), cleaned and rotated every 2 weeks | Same as 2-week studies | Same as 2-week studies
Animal Room Environment
Temperature: 72° ± 3° F | Temperature: 72° ± 3° F | Temperature: 72° ± 3° F
Relative humidity: 50% ± 15% | Relative humidity: 50% ± 15% | Relative humidity: 50% ± 15%
Room fluorescent light: 12 hours/day | Room fluorescent light: 12 hours/day | Room fluorescent light: 12 hours/day Room air changes: 10/hour
Room air changes: 10/hour | Room air changes: 10/hour
Doses
0, 12.5, 25, 50, 100, or 200 mg/kg in acetone by dermal application (dosing volume 0.5 mL/kg for rats and 2 mL/kg for mice) | 0, 0.75, 1.5, 3, 6, or 12 mg/kg in acetone by dermal application (dosing volume 0.5 mL/kg for rats and 2 mL/kg for mice) | Core study: 0, 0.75, 1.5, 3, 6, or 12 mg/kg in acetone by dermal application (dosing volume 3.3 mL/kg)
0, 12.5, 25, 50, 100, or 200 mg/kg in acetone by dermal application (dosing volume 0.5 mL/kg for rats and 2 mL/kg for mice) | 0, 0.75, 1.5, 3, 6, or 12 mg/kg in acetone by dermal application (dosing volume 0.5 mL/kg for rats and 2 mL/kg for mice) | Positive control: 1.25 μg 12-O-tetradecanoylphorbol-13-acetate/100 mL acetone by dermal application (dosing volume 100 μL)
Type and Frequency of Observation
Animals were observed twice daily and were weighed initially, on day 8, and at the end of the studies. Clinical findings were recorded daily. | Animals were observed twice daily and were weighed initially, weekly, and at the end of the studies. Clinical findings were recorded weekly and at the end of the studies for core study animals. | Animals were observed twice daily and were weighed initially, weekly, and at the end of the study. Clinical findings were recorded weekly and at the end of the study.
Method of Sacrifice
Carbon dioxide asphyxiation | Same as 2-week studies | Same as 2-week studies
Necropsy
Necropsies were performed on all animals. Organs weighed were the heart, right kidney, liver, lung, right testis, and thymus. | Necropsies were performed on all animals. Organs weighed were the heart, right kidney, liver, lung, right testis, and thymus. | Necropsies were performed on core study mice. Organs weighed were the heart, right kidney, liver, lung, right testis, and thymus.
Clinical Pathology
None | Blood was collected from the retroorbital sinus of special study rats on days 4 and 23 and from core study rats and mice at the end of the studies for hematology and clinical chemistry (rats only). | None
| Hematology: hematocrit; hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; erythrocyte morphology; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials
| Clinical chemistry: urea nitrogen, creatinine, total protein, albumin, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile acids
Histopathology
Histopathologic examinations were performed on the skin (site of application) of all animals and the thymus of all mice. | Complete histopathologic examinations were performed on vehicle control and 12 mg/kg rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, gallbladder (mice), heart with aorta, large intestine (cecum, colon, and rectum), small intestine (duodenum, jejunum, and ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, skin (site of application), spleen, stomach (forestomach and glandular), testis with epididymis and seminal vesicle, thymus, thyroid gland, trachea, urinary bladder, and uterus. The skin at the site of application was also examined in the remaining core study groups. | Histopathologic examinations were performed on all core study mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, heart, kidney, liver, lung, lymph nodes (mandibular, mediastinal, and mesenteric), ovary, pituitary gland, skin (site of application and inguinal), spleen, stomach (forestomach), testis with epididymis, thymus, thyroid gland, and uterus.
Sperm Motility and Vaginal Cytology
None | At the end of the studies, sperm samples were collected from male animals in the vehicle control and 3, 6, and 12 mg/kg groups for sperm count and motility evaluations. The following parameters were evaluated: spermatid heads per testis or cauda and per gram testis or cauda and epididymal spermatozoal motility. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 12 consecutive days prior to the end of the studies from females in the vehicle control and 3, 6, and 12 mg/kg groups for vaginal cytology evaluations. The percentage of time spent in the various estrous cycle stages and estrous cycle length were evaluated. | None

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier (1958) and is presented in the form of graphs. Animals found dead of other than natural causes were censored from the survival analyses; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s (1972) method for testing two groups for equality and Tarone’s (1975) life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Tables A1, A4, B1, and B4 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of statistical significance, the incidences of most neoplasms (Tables A3 and B3) and all nonneoplastic lesions are given as the numbers of animals affected at each site examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., harderian gland, intestine, and mammary gland) before microscopic evaluation, or when neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. Tables A3 and B3 also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, to animals that do not reach terminal sacrifice.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidences

The Poly-k test (Bailer and Portier, 1988; Portier and Bailer, 1989; Piegorsch and Bailer, 1997) was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal sacrifice; if the animal died prior to terminal sacrifice and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time (Bailer and Portier, 1988). Unless otherwise specified, a value of k=3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier (1988) following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344 rats and B6C3F_1_ mice (Portier et al., 1986). Bailer and Portier (1988) showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams (1993).

Tests of significance included pairwise comparisons of each dosed group with controls and a test for an overall dose-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence, and reported P values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1-P with the letter N added (e.g., P=0.99 is presented as P=0.01N).

The weekly in-life skin papilloma counts were evaluated by the method of Dunson et al. (2000). The assumed model separates effects on papilloma latency and multiplicity and accommodates important features of the data, including animal-to-animal variability in the expression of the transgene as reflected in the tumor counts. The two key parameters are Υ_1_, which measures the dose effect on incidence (proportion of animals with one or more papillomas during the study), and Υ_2_, which measures the dose effect on multiplicity (rate of appearance of additional papillomas after the initial papilloma has occurred). The model assumes that the rate (number of additional papillomas per time period) is exponentially increasing with respect to dose and that the rate remains constant across time.

More specifically, under the model, the increase in papilloma burden from one week to the next is assumed to be distributed as a Poisson random variable. The Poisson mean is assumed to depend on an animal-specific susceptibility variable, on exposure length, and on the dose. The rate of initial papilloma occurrence is assumed to be log-linear in time. The coefficients for time are levels of dose multiplied by Υ_1_ and the animal-specific susceptibility parameters. This implies that as the dose/time increases, the rate of occurrence for the first papilloma will increase exponentially (inverse of log) relative to increases in dose/time. A value of zero for Υ_1_ implies that dose is not associated with incidence (or, equivalently, the length of the latency period prior to initial onset), leaving only animal-specific characteristics to explain any variability.

After the latency period (after the first papilloma occurs), the Poisson mean changes to a rate that is only dependent on dose (that is, no animal-specific rates or dependency with time). More explicitly, the rate of occurrence of additional papillomas is assumed to be log-linear in time. A value of zero for Υ_2_ implies that dose is not associated with rate of additional papilloma occurrence. A non-zero value implies that the rate of additional papillomas increases with dose in a proportional fashion.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett (1955) and Williams (1971, 1972). Hematology, clinical chemistry, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley (1977) and Dunn (1964). Jonckheere’s test (Jonckheere, 1954) was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey (1951) were examined by NTP personnel, and implausible values were eliminated from the analysis. Average severity values were analyzed for significance with the Mann-Whitney U test (Hollander and Wolfe, 1973). Because vaginal cytology data are proportions (the proportion of the observation period that an animal was in a given estrous stage), an arcsine transformation was used to bring the data into closer conformance with a normality assumption. Treatment effects were investigated by applying a multivariate analysis of variance (Morrison, 1976) to the transformed data to test for simultaneous equality of measurements across doses.

## Quality Assurance Methods

The 3- and 6-month studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations (21 CFR, Part 58). In addition, as records from the 6-month studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent quality assurance contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of pentaerythritol triacrylate was assessed by testing the ability of the chemical to induce mutations in various strains of Salmonella typhimurium and increases in the frequency of micronucleated erythrocytes in mouse peripheral blood. The protocols for these studies and the results are given in Appendix C.

The genetic toxicity studies have evolved from an earlier effort by the NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity (Miller and Miller, 1977) and the somatic mutation theory of cancer (Straus, 1981; Crawford, 1985). However, it should be noted that not all cancers arise through genotoxic mechanisms.

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites (Ashby and Tennant, 1991). A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens) (Tennant et al., 1987; Zeiger et al., 1990). Additionally, no battery of tests that included the Salmonella test improved the predictivity of the Salmonella test alone. However, these other tests can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

The predictivity for carcinogenicity of a positive response in the acute in vivo bone marrow chromosome aberration test or micronucleus test appears to be less than that in the Salmonella test (Shelby et al., 1993; Shelby and Witt, 1995). However, clearly positive results in long-term peripheral blood micronucleus tests are associated with high predictivity for rodent carcinogenicity (Witt et al., 2000); negative results in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies. Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular chemical. Most organic chemicals that are identified by the International Agency for Research on Cancer as human carcinogens, other than hormones, are genotoxic. The vast majority of these are detected by both the Salmonella assay and rodent bone marrow cytogenetics tests (Shelby, 1988; Shelby and Zeiger, 1990).