# INTRODUCTION

PENTAERYTHRITOL TRIACRYLATE

CAS No. 3524-68-3

Chemical Formula: C_14_H_18_O_7_ Molecular Weight: 298.3

Synonyms: Acrylic acid, pentaerythritol triester; pentaerythrityl triacrylate; PETA; 2-propenoic acid, 2-(hydroxymethyl)-2-(((1-oxo-2-propenyl)oxy)methyl)-1,3-propanediyl ester; tetramethylolmethane triacrylate

Trade names: Aronix M 305, NK Ester A-TMM3, Setalux UV 2242; SR 444, Viscoat 300

## Chemical and Physical Properties

Pentaerythritol triacrylate is a colorless or light amber nonvolatile liquid; it also occurs as a white semisolid or crystalline solid at temperatures up to 40° C (Celanese, 1979; AIHA, 1981; Lenga, 1988). It has a characteristic acrylate odor (Radcure, 1990a). Pentaerythritol triacrylate has a melting range from 25° to 40° C and a boiling point of greater than 315° C at 760 mm Hg (AIHA, 1981; Radcure, 1990b). At 100° C, it has a vapor pressure of less than 0.01 mm Hg (Radcure, 1990b); its refractive index at 20° C is 1.4864 (Lenga, 1988). Pentaerythritol triacrylate is practically insoluble in water; hygroscopic; and incompatible with strong oxidizing agents, strong acids, and strong bases (Lenga, 1988; Radcure, 1990a). Pentaerythritol triacrylate may polymerize when exposed to sources of free radicals (Radcure, 1990b), direct light, and heat; it is stabilized with 300 to 400 ppm hydroquinone monomethyl ether (Aldrich, 2000). Decomposition products include toxic fumes of carbon monoxide and carbon dioxide (Lenga, 1988; Radcure, 1990a). The chemical is reactive and is therefore not available as pure pentaerythritol triacrylate.

## Production, Use, and Human Exposure

No information on the specific manufacturing process of pentaerythritol triacrylate was found in the literature. However, polyfunctional acrylate monomers can be produced by direct or trans-esterification methods (Kirk-Othmer, 1978).

Pentaerythritol is manufactured by the reaction of acetaldehyde with formaldehyde in alkaline medium such as sodium or calcium hydroxide (Kirk-Othmer, 1978). Initially, the alpha-hydrogen atoms of acetaldehyde condense with formaldehyde in three sequential aldol reactions to form pentaerythrose. Pentaerythrose is then reduced to pentaerythritol in a crossed Cannizzaro reaction with formaldehyde. Pentaerythritol esters have been synthesized by the usual methods of esterification using organic acids, acid anhydrides, or acid chlorides.

The U.S. Environmental Protection Agency’s Toxic Substances Control Act Inventory for 1983 indicated that approximately 100,000 to 1 million pounds of pentaerythritol triacrylate were produced by three U.S. companies providing annual production volumes (USEPA, 1991). The American Industrial Hygiene Association (1981) estimated the production of multi-functional acrylates including pentaerythritol triacrylate may be several million pounds per year. More recent production data were not available.

Pentaerythritol triacrylate is used in the production of ultraviolet-curable inks and coatings, electron beam irradiation-curable coatings, and radiation-cured and photocurable coatings of urethanes and epoxy resins; as a component of photopolymer and flexographic printing inks and plates and photoresists; as an ingredient of acrylic glues, adhesives, and anaerobic sealants; and as a modifier for polyester and fiberglass (Nethercott, 1978; Björkner, 1984; ACS, 1990; Newmark and Palazzotto, 1990). It is also used in colloidal dispersions for industrial baked coatings, waterborne and solvent-based alkyds, vinyl/acrylic nonwoven binders, paper and wood impregnates, wire and cable extrusion, polymer-impregnated concrete, and polymer concrete structural composites (Celanese, 1982a; NCI, 1987).

Workers involved in the manufacturing, processing, product handling, and application of pentaerythritol triacrylate are at risk of exposure (Parker and Turk, 1983). Surveys by the National Institute for Occupational Safety and Health (1990) found that 62 workers were potentially exposed to pentaerythritol triacrylate between 1981 and 1983. The American Industrial Hygiene Association (1981) established a workplace environmental exposure level (8-hour time-weighted average) of 1 mg pentaerythritol triacrylate/m^3^. Consumers may potentially be exposed through the use of products such as latex paint and floor polishes that contain pentaerythritol triacrylate (Dearfield et al., 1989). In addition, products that are made from high-impact acrylic molding powders containing pentaerythritol triacrylate include outboard motor shrouds, housings and containers, nameplates, toys, business machine components, and blow-molded bottles (NCI, 1987).

## Absorption, Distribution, Metabolism, and Excretion

No studies on the absorption, distribution, metabolism, or excretion of pentaerythritol triacrylate in experimental animals or in humans were found in a review of the literature.

## Toxicity

### Experimental Animals

Acute oral LD_50_ values reported for rats were 2.46 mL pentaerythritol triacrylate/kg body weight (Carpenter et al., 1974), 1,350 mg/kg (AIHA, 1981), or greater than 500 to 5,000 mg/kg (Andrews and Clary, 1986). Intraperitoneal injection LD_50_ values reported for rats ranged from 18.5 to 27 mg/kg (Celanese, Inc., 1982b). Dermal LD_50_ values for rabbits were 4 mL/kg (Carpenter et al., 1974), greater than 2,000 mg/kg (AIHA, 1981), and greater than 200 to 2,000 mg/kg (Andrews and Clary, 1986).

The maximum time rats could be exposed to concentrated vapors of pentaerythritol triacrylate with no deaths was 8 hours (Carpenter et al., 1974). Signs of neurological toxicity, including ataxia, flaccid limb and body tone, and abnormal righting and visual placing reflexes were seen in male and female albino Sprague-Dawley rats administered intraperitoneal injections of 10 to 100 mg/kg (Celanese, 1982c; NCI, 1987). Applications of this chemical to the eye of rabbits caused severe and corrosive irritation as well as corneal opacity (Carpenter et al., 1974; Andrews and Clary, 1986), and 1 mg of pentaerythritol triacrylate applied to the eye of rabbits resulted in severe irritation (Lenga, 1988; Sax and Lewis, 1989).

A significant increase in lymph node weight was noted in outbred male and female Hartley guinea pigs 4 to 6 days after epicutaneous immunization with 50 µmol of pentaerythritol triacrylate (Bull et al., 1985). Evidence of increased T-lymphocyte proliferation in the lymph node, as measured by an increase in the number of large pyroninophilic cells, was also observed. The authors concluded that a positive correlation exists among skin sensitization reactions, increased lymph node weights, and T-lymphocyte proliferation.

In a sensitization study by Nethercott (1978), 15 albino Hartley/Dalkin guinea pigs (sex not specified) were induced and then challenged with pentaerythritol triacrylate. Three intradermal injections were administered to each shoulder: 0.1 mL of 0.05% pentaerythritol triacrylate in propylene glycol, 0.05 mL of 0.1% pentaerythritol triacrylate in propylene glycol with 0.05 mL of Freund’s complete adjuvant (FCA), and 0.1 mL FCA. After 1 week, 25% pentaerythritol triacrylate in petrolatum was applied to the animals’ shaved shoulders, which were then wrapped for 48 hours. The animals were challenged 2 weeks after the topical exposure with skin patches of 10% pentaerythritol triacrylate in petrolatum for 24 hours. Thirteen of the animals reacted positively to pentaerythritol triacrylate.

In another study, female albino Hartley/Dalkin guinea pigs received three pairs of intradermal injections of 0.001% to 0.5% pentaerythritol triacrylate in propylene glycol, 0.05 mL of FCA mixed with 0.05 mL of the appropriate concentration of pentaerythritol triacrylate, and 0.1 mL of FCA in the shoulder (Nethercott et al., 1983). One week later, pentaerythritol triacrylate at the same concentrations was applied to the shaved shoulder via a filter paper patch; the patch was kept in place for 48 hours. The animals were challenged 2 weeks after topical exposure with 24-hour shaved-flank skin patches of nonirritant concentrations of pentaerythritol triacrylate. The percentage of animals sensitized at each concentration increased with exposure concentration, ranging from 15% of those receiving 0.001% pentaerythritol triacrylate to 100% of those receiving 0.5%.

The contact sensitization potential of pentaerythritol triacrylate was studied in male and female outbred Hartley guinea pigs using five different immunization protocols (Parker and Turk, 1983). On the first day of the Polak immunization method, animals were administered four footpad injections and one injection in the nape of the neck of a 0.1 mL emulsion containing 2 mg/mL pentaerythritol triacrylate in ethanol:saline (1:4) in FCA. On day 7, 0.02 mL of 0.1% or 0.25% pentaerythritol triacrylate in acetone:olive oil (4:1) was dropped onto the shaved flank of the animals. The skin tests were repeated weekly at different sites on the flank for up to 12 weeks. In the split adjuvant immunization method, 0.05 mL of FCA was injected into five sites on the dorsal shaved flank. One day later 0.1 mL pentaerythritol triacrylate in ethanol:saline (1:100) was injected intradermally into the same five sites. Skin tests as described for the Polak method were begun on day 14. In the maximization immunization method, guinea pigs received two intradermal injections of 0.1 mL FCA, 0.1 mL of 1% pentaerythritol triacrylate in saline, and 0.1 mL of 1% pentaerythritol triacrylate in FCA. Skin tests as described above were begun 14 days later. In the first epicutaneous method, 0.1 mL of a 0.3 M solution of pentaerythritol triacrylate in 95% ethanol:2-methoxyethanol:Tween 80 (9:9:2) was dropped once daily onto the animals’ shaved flank on days 1, 3, 5, 8, 10, and 12. On day 29, weekly skin testing as described above was begun. In the other epicutaneous method, 0.1 mL of 0.25% pentaerythritol triacrylate in acetone:olive oil (1:1) was applied once daily to a shaved area on the back of the neck for 5 days and again on days 8 through 12. The skin test procedure as described above began on day 22. In all methods, skin test sites were observed 24, 48, and 72 hours after application. Six guinea pigs exhibited positive skin reactions on the 14th day with the Polak method; reactions were graded on a scale of 0 (no reaction) to 3 (red and elevated reaction). Scores of 1.1 using 0.1% pentaerythritol triacrylate and 1.4 using 0.25% pentaerythritol triacrylate were reported. With the second epicutaneous method, five of six animals were sensitized; the severity of these reactions was not reported.

In a study to determine whether animals sensitized with trimethylolpropane triacrylate would exhibit cross-sensitivity when challenged with other multifunctional acrylates, albino female Dunkin Hartley guinea pigs were given three pairs of intradermal injections in the shoulder: 0.1 mL of FCA mixed 1:1 with water, 0.1 mL of 1% trimethylolpropane triacrylate in olive oil, and 0.1 mL of 1% trimethylolpropane triacrylate in olive oil with an equal amount of FCA (Björkner et al., 1980). After 1 week, a shoulder patch of 25% trimethylolpropane triacrylate in petrolatum was applied for 48 hours. Two weeks after this induction procedure, groups of 24 animals were challenged with occlusive patch tests of 0.5% or 0.1% pentaerythritol triacrylate in petrolatum applied to a shaved area of the flank for 24 hours. Twelve animals (50%) sensitized to trimethylolpropane triacrylate had positive reactions when challenged with 0.1% pentaerythritol triacrylate; 18 animals (75%) reacted positively to the 0.5% concentration, suggesting cross-sensitivity between the two compounds.

In a maximization test to determine skin sensitivity and cross-sensitivity reactions, groups of 15 female albino Dunkin Hartley guinea pigs were sensitized with intradermal injections of 1% commercial-grade pentaerythritol tri- or tetraacrylate in olive oil:acetone (9:1) followed by topical patches of 25% solutions of these chemicals in petrolatum and then challenged with two applications on the flank, 1 week apart, of 0.015 g of the test acrylate or trimethylolpropane triacrylate in petrolatum (Björkner, 1984). A 1% booster of the sensitizing chemical was administered intradermally on the neck 48 hours after the first challenge. Of the 10 animals that became sensitized to commercial-grade pentaerythritol triacrylate, seven also reacted to trimethylolpropane triacrylate. Only one guinea pig became sensitized to commercial-grade pentaerythritol tetraacrylate; this animal also reacted to trimethylolpropane triacrylate. It was concluded from these results that pentaerythritol triacrylate was the more potent sensitizer and that guinea pigs sensitized to pentaerythritol triacrylate may cross-react to trimethylolpropane triacrylate.

Bull et al. (1985) immunized outbred male and female Hartley guinea pigs (number not specified) with subcutaneous injection in the footpads and in the neck with 0.1 mL of an emulsion of pentaerythritol triacrylate in ethanol:saline (4:1). The total pentaerythritol triacrylate dose was approximately 11.5 µmol. In addition, five guinea pigs were sensitized by applying 50 µL of a 1M solution of pentaerythritol triacrylate in acetone:olive oil (4:1) to the dorsum of each animal’s right ear. Skin tests of 0.02 mL of 0.1% or 0.25% pentaerythritol triacrylate in acetone:olive oil (4:1) were applied to the shaved flank of the guinea pig one and two weeks after induction, and reactions were recorded at 24, 48, 72, and 96 hours. Immunization with pentaerythritol triacrylate by the Polak method resulted in positive skin reactions; sensitization was not induced by epicutaneous application.

Parker et al. (1985) extended the Bull et al. (1985) study to examine the ability of pentaerythritol triacrylate to induce a tolerance to the contact reactions seen in guinea pigs. Groups of five male and female outbred Hartley guinea pigs were immunized with pentaerythritol triacrylate and skin tested with pentaerythritol triacrylate as well as with additional acrylates of similar structure, as described by Bull et al. (1985). To induce tolerance epicutaneously, 0.1 mL of 10% pentaerythritol triacrylate in acetone was applied to the dorsum of each animal’s ear 14 and 7 days before immunization with methyl acrylate or trimethylolpropane triacrylate. Skin tests (methyl acrylate at 1% or 5%; trimethylolpropane triacrylate at 0.25% or 0.5%) were conducted with the immunizing compound 7 days after induction, and reactions were scored 24 and 48 hours after the patches were removed. Animals sensitized to pentaerythritol triacrylate also reacted to trimethylolpropane triacrylate, 4-vinyl pyridine, methyl acrylate, and methyl vinyl ketone, indicating that pentaerythritol triacrylate has the potential to cross-react with several other chemicals.

In another study to examine cross-reaction patterns of pentaerythritol triacrylate and other selected acrylates, female outbred SSc:AL guinea pigs were induced with three pairs of intradermal injections in the shoulder: 2 × 50 µL of FCA in sterile water (1:1); 2 × 50 µL of a 5% solution of the test chemical in soybean oil, and 2 × 50 µL of a 5% solution of the test chemical in FCA and water (1:1) (Clemmensen, 1984). On day 8, 250 mg of 10% sodium dodecyl sulfate in petrolatum was applied to the same site and left uncovered for 24 hours. On day 9, 400 µL of the test compound (100%) was applied to the test area on a patch held in place for 48 hours. Challenge patch tests were conducted on day 22 with up to six patches containing 25 µL 2% pentaerythritol triacrylate that were held on a shaved area of the animal’s flank for 24 hours. Reactions were graded 48 and 72 hours after the application of the patches. Seven of 20 animals that had been induced with triethyleneglycol dimethacrylate and nine of 19 animals induced with trimethylolpropane trimethacrylate reacted to pentaerythritol triacrylate. No cross-reaction was seen in animals induced with methylmethacrylate or ethyleneglycol dimethacrylate. The author concluded that pentaerythritol triacrylate is a potent sensitizer that can cross-react with other acrylates.

Groups of five male and five female New Zealand White rabbits received unoccluded dermal applications of 200 mg pentaerythritol triacrylate/kg body weight at a site on the back, 5 days a week for 2 weeks (Celanese, 1979; NCI, 1987). For five animals, the exposure sites were further treated by abrading the area with an inverted clipper before treatment and twice weekly thereafter. Three abraded and three nonabraded animals of each sex per group were sacrificed following the last day of treatment; the remaining animals were sacrificed after day 30. All animals treated with pentaerythritol triacrylate exhibited severe erythema with necrosis and eschar formation, fissuring, desquamation, and slight to moderate edema and atonia at 2 weeks; erythema and desquamation persisted through week 4. Treated animals also had discoloration of the lung and kidney at 2 weeks; these abnormalities were not present at week 4. Microscopically, dosed animals had severe necrosis of the epithelium and subepithelium and congestion of the dermis at 2 weeks. The epithelium was intact at 4 weeks, but there was residual evidence of earlier irritation. No evidence of systemic toxicity resulting from administration of pentaerythritol triacrylate was observed. In a similar study, with no recovery period, in which the animals were dermally administered 500 mg/kg per day for 2 weeks, six animals died during the treatment period, and all dosed animals lost weight during the study (Celanese, 1981; NCI, 1987). At day 7, all dosed animals exhibited moderate to severe erythema and edema. At the time of death (spontaneous or sacrifice), most animals exhibited necrosis, eschar formation, and atonia; a few also showed slight desquamation and/or fissuring. Histologic examination of dosed rabbits revealed extensive degeneration of the subcutis and severe epidermal necrosis and ulceration in dosed animals sacrificed at 2 weeks. All six animals that died during the study had degeneration and edema of the dermis and degeneration and inflammation of the subcutis; epidermal necrosis was seen in five of these animals.

### Humans

Pentaerythritol triacrylate has been shown to be a cutaneous sensitizer in humans. For induction, patches containing a 10% solution of pentaerythritol triacrylate were applied on the extensor surface of the arm of eight human volunteers ages 18 to 25 (Nethercott, 1978). The patch was removed each day and reapplied if there was no evidence of inflammation. For the challenge test 4 weeks later, patches containing 0.1% pentaerythritol triacrylate in petrolatum were applied to the subjects’ upper back for 48 hours. One subject had macular erythema, four exhibited a vesicular or oedematous reaction, and one subject had a severe spreading, ulcerative reaction.

A 61-year-old male painter developed eczematous dermatitis of the hands, arms, trunk, and legs within weeks after his company’s switch from oil-based paint to an acrylic-based system (Cofield et al., 1985). The new system contained 1% to 3% of a polyfunctional aziridine cross-linking hardener composed of a multifunctional acrylic monomer, trimethylolpropane triacrylate, at residual concentrations ranging from 0.03% to 0.15%. Skin patch tests using 0.2% pentaerythritol triacrylate, full strength paint primer (without cross-linker), and the full strength aziridine cross-linker, all in petrolatum, were performed. The patches were kept in place for 48 hours and the results were read 15 minutes after the patches were removed and again at one week. Positive reactions were seen to the pentaerythritol triacrylate and the full strength cross-linker at 48 hours and 1 week. Because the patient had been exposed only to a cross-linker composed of trimethylolpropane triacrylate, the reaction to pentaerythritol triacrylate could be attributed to cross-sensitization.

Four workers in a plastic floor manufacturing facility developed hand and face dermatitis a year after the introduction of a varnish with an aziridine-based hardener containing 3% to 5% trimethylolpropane triacrylate (Dahlquist et al., 1983). Although the hardener in this case was composed of trimethylolpropane triacrylate, pentaerythritol triacrylate can also be substituted as the hardener in the varnish. All four patients tested positive to skin patch tests with 0.1% hardener in acetone, and to a 0.1% solution of trimethylolpropane triacrylate in acetone. Two patients also reacted to 0.1% pentaerythritol triacrylate in acetone.

The addition of two new multifunctional acrylates, trimethylolpropane triacrylate and pentaerythritol triacrylate, as components of a radiation drying ink at an ink formulation facility, was associated with eczematous dermatitis in five of 26 employees (Emmett, 1977). Patch testing was done individually with each component of the ultraviolet-cured inks used in the plant, as wells as solutions of 0.2% pentaerythritol triacrylate in petrolatum and three ink varnish formulations containing 0.2% pentaerythritol triacrylate in petrolatum. Four of the five employees reacted positively to pentaerythritol triacrylate and the three varnish formulations containing pentaerythritol triacrylate. Although the fifth employee did not have significant reactions at 48 or 72 hours, he did exhibit an irritant dermatitis following patch testing with pentaerythritol triacrylate. All subjects sensitized to pentaerythritol triacrylate also reacted to trimethylolpropane triacrylate, a similar polyfunctional acrylate monomer. However, because all subjects had potential exposure to both compounds, it was unclear whether the multiple reactivity was a result of cross-sensitization or concomitant sensitization.

Of approximately 58 employees in one plant who were potentially exposed to an ultraviolet-cured ink manufacturing process, eight men ages 24 to 62 developed symptoms consistent with allergic contact dermatitis (Emmett and Kominsky, 1975, 1977). In six cases, the symptoms were seen 1 or 2 days after working with ultraviolet inks. Occlusive patch tests of 0.2% pentaerythritol triacrylate or trimethylolpropane triacrylate in petrolatum were conducted for 48 hours and the sites were examined 1 or 24 hours later. Four of the tested subjects had positive reactions to pentaerythritol triacrylate and, in three cases, the results were categorized as strong edematous or vesicular reactions. The authors concluded that pentaerythritol triacrylate is a strong sensitizing agent but cross-sensitization could not be evaluated in these subjects because the workers were potentially exposed to multiple agents.

In an ink manufacturing plant, 19 workers exposed to ultraviolet-cured inks developed skin and conjunctival reactions (Nethercott, 1978). Subjects were patch tested with several acrylate compounds, including a solution of 0.1% pentaerythritol triacrylate in petrolatum. Seven workers reacted positively to pentaerythritol triacrylate and were considered sensitized to the compound, which each had handled as a raw material.

Seven of 10 employees of a plastic food container manufacturing plant developed various cutaneous conditions, including eczematous dermatitis to erythematous scaling (Nethercott et al., 1983). All seven were skin patch tested with several potential allergens, including urethane acrylate and pentaerythritol triacrylate (0.1% in petrolatum). Five of the seven employees tested positive to urethane acrylate and one showed a positive reaction to pentaerythritol triacrylate at both 48 and 96 hours. Because the chemical structures of these two compounds differ, the pentaerythritol triacrylate-responsive individual had been exposed to both substances, and chemical analysis showed no contamination of urethane acrylate with pentaerythritol triacrylate, the authors concluded these reactions represented concurrent sensitization rather than cross-sensitization.

A worker developed an erythematous pruritic rash on his hands and face months after being exposed to a new printing system that used ultraviolet-cured inks; the rash would disappear when he was not exposed to the inks (Smith, 1977). Another man reported similar skin eruptions. The men were skin patch tested with three colored inks (red, black, and gold) diluted to 10% in methyl ethyl ketone and with the reducer, pentaerythritol triacrylate. Positive reactions were seen with pentaerythritol triacrylate and the black and gold inks that contained pentaerythritol triacrylate. No reaction was seen with red ink, which did not contain pentaerythritol triacrylate. A second series of patch tests using pentaerythritol triacrylate at 0.1% and 1% in methyl ethyl ketone, the other components of the inks, and two alternative acrylates was performed. Both men had positive patch tests with pentaerythritol triacrylate and the two alternative acrylates, trimethylolpropane triacrylate and tripropylene glycol triacrylate, but not with any other ink component. The author concluded that pentaerythritol triacrylate is a strong allergen capable of producing sensitization; positive reactions observed with the other two acrylates were thought to be due to cross-sensitization.

Fifty-nine cases of skin disorders of the hands were reported after the use of protective gloves made from modified polyvinyl chloride after the addition of 2.2% pentaerythritol triacrylate to the gloves’ formulation (Kalensky, 1987). Skin patch tests with 0.2% pentaerythritol triacrylate in alcohol produced intense allergic reactions and the concentration was reduced to 0.1% in Vaseline^®^. An annular reaction was seen in five subjects following patch testing with the 0.1% formulation. The author concluded that pentaerythritol triacrylate, a strong sensitizing agent, was unsuitable for use in protective gloves.

## Reproductive and Developmental Toxicity

### Experimental Animals

Uncommon malformations were seen in a small number of fetuses born to 20 female rats (strain unspecified) administered a single dermal dose of 100 mg pentaerythritol triacrylate/kg body weight during days 6 through 15 of gestation (Andrews and Clary, 1986). This dose had been determined to be the maximum at which slight maternal toxicity was observed. However, teratogenic effects were not noted in a second study in which pentaerythritol triacrylate was administered at an unspecified dose that caused minimal maternal toxicity. From these results, the authors concluded that pentaerythritol triacrylate was not a teratogen.

### Humans

No information on the reproductive or developmental toxicity of pentaerythritol triacrylate in humans was found in the literature.

## Carcinogenicity

### Experimental Animals

Male C3H/HeJ mice treated with approximately 3 mg of a mixture of 25% pentaerythritol triacrylate, 65% tetraacrylate, and 10% diacrylate applied as a 15% solution in acetone three times per week to the back for life showed no incidence of skin tumors (DePass, 1982; DePass et al., 1985).

No skin tumors were found in male C3H/HeJ mice treated with a 15% solution of pentaerythritol acrylate-HF (approximately 3 mg/mouse per application) on the back three times per week for the life of the animals (Union Carbide, 1979, 1988; NCI, 1987). Thirteen of 39 mice in the dosed group had gross hepatic tumors, but the increased incidence of these lesions was considered to be equivocal when compared to historical control data.

A group of 50 male C3H/HeJ mice was treated twice weekly with 50 mg of 5% pentaerythritol triacrylate in white mineral oil (2.5 mg/mouse) painted onto the shaved interscapular region for up to 80 weeks (Celanese, 1986). One treated mouse developed a squamous cell carcinoma of the skin, and six mice had lymphomas with spleen or lymph node involvement. To determine the toxicologic significance of these findings, the U.S. Environmental Protection Agency reviewed these results and concluded that these lesions provided limited positive evidence of carcinogenicity of pentaerythritol triacrylate in C3H/HeJ mice (NCI, 1987).

### Humans

No epidemiology studies or case reports associating pentaerythritol triacrylate exposure with cancer risk were found in a review of the literature.

## Related Compounds

Pentaerythritol triacrylate is a member of the multifunctional alkyl acrylates class. In a series of studies of eight multifunctional alkyl acrylates performed by Celanese Corporation, Inc., groups of 50 male C3H/HeJ mice were given dermal applications twice weekly for up to 80 weeks (Andrews and Clary, 1986). No increases in the incidences of skin or visceral tumors were induced by trimethylolpropane triacrylate; trimethylolpropane trimethacrylate; 1,6-hexanediol diacrylate; tripropyleneglycol diacrylate; or triethyleneglycol dimethacrylate. However, pentaerythritol triacrylate, triethyleneglycol diacrylate, and tetraethyleneglycol diacrylate showed some potential for carcinogenicity when administered at doses of 100 mg/kg in mineral oil. Pentaerythritol triacrylate induced lymphoma with spleen or lymph node involvement in six mice. However, these lesions were not verified in subsequent examinations. Triethyleneglycol diacrylate induced skin tumors in six mice and lymphomas in four mice; tetraethyleneglycol diacrylate induced skin tumors in six mice. However, in 78-week dermal carcinogenicity studies, neither triethyleneglycol diacrylate (0.05%, 0.1%, or 0.5% in acetone) nor triethyleneglycol dimethacrylate (5%, 25%, or 50% in acetone) were carcinogenic in male C3H/HeNHsd mice (Van Miller et al., 2003).

In another study, groups of 40 male C3H/HeJ mice were given dermal applications of 5 mg (approximately 200 mg/kg) neopentylglycol diacrylate or 3 mg (approximately 120 mg/kg) pentaerythritol triacrylate in acetone three times weekly for the life of the animals (DePass et al., 1985). Among mice administered neopentylglycol diacrylate, five had skin papilloma and three others had skin carcinoma. No skin neoplasms were observed in pentaerythritol triacrylate-treated mice.

## Genetic Toxicity

Pentaerythritol triacrylate, in concentrations up to 10,000 µg/plate, was not mutagenic in any of several strains of Salmonella typhimurium, with or without metabolic activation (Zeiger et al., 1987). It was tested in L5178Y mouse lymphoma TK^+/–^ cells, in the absence of exogenous metabolic activation, for induction of forward mutations at the TK locus, chromosomal aberrations, and micronuclei (Dearfield et al., 1989). Pentaerythritol triacrylate induced significant dose-related increases in all three endpoints measured in the latter study. The highest dose tested was 0.350 µg/mL, and at this dose, cell survival was reduced to 15%. No additional publications of mutagenicity test data for pentaerythritol triacrylate were found in a review of the literature.

## Study Rationale

Pentaerythritol triacrylate was nominated for dermal carcinogenicity studies by the National Cancer Institute based on its high and increasing production volume, its widespread use and potential for human exposure, the lack of adequate chronic toxicity and carcinogenicity data, and the lack of adequate structure activity and genotoxicity data on the acrylate class of chemicals. As a member of the class of multifunctional acrylates, pentaerythritol triacrylate is a suspected carcinogen; some members of this class have been shown to be carcinogenic to mice in dermal studies.

The major route of human exposure to pentaerythritol triacrylate is via the skin. At the time of study design, the Tg.AC mouse model was showing promise relative to carcinogenicity testing (hazard identification) via dermal exposure. Efforts were under way to to assess more fully the potential of the model. Therefore, it was decided to conduct initial studies in the Tg.AC mouse model and, upon completion of the studies, assess the findings in light of updated information about the model. Importantly, this process allowed assessment of studies in the Tg.AC mouse model in a completely prospective manner.