# APPENDIX K CONTACT HYPERSENSITIVITY STUDIES

## Introduction

Studies were conducted with female BALB/c mice to evaluate the potential for pentaerythritol triacrylate to induce contact hypersensitization. Primary irritancy studies of approximately 10% and 45% pentaerythritol triacrylate mixtures were performed to screen for toxicity and determine the maximal nonirritating and minimal irritating concentrations of pentaerythritol triacrylate. Mouse ear swelling tests and local lymph node assays of the two mixtures were then conducted to assess the dermal sensitizing potential of the compound. The studies were performed by the Medical College of Virginia Immunotoxicology Laboratory (Virginia Commonwealth University, Richmond, VA).

## Materials and Methods

Pentaerythritol triacrylate mixtures were obtained from Aldrich Chemical Company (Milwaukee, WI; lot 05318JW, approximately 10% pentaerythritol triacrylate) and Sartomer Company (Exton, PA; lot HCC0340, approximately 45% pentaerythritol triacrylate). Acetone was used as the vehicle. Analyses of the bulk chemicals are described in Appendix H. Dose formulations were prepared daily by mixing pentaerythritol triacrylate in acetone.

Female BALB/c mice were obtained from the National Cancer Institute (Bethesda, MD) or Charles River Laboratories (Wilmington, MA). The mice were approximately 6 to 9 weeks of age at receipt and were quarantined for at least 6 days; serology tests indicated that the animals were free of viral (mouse hepatitis and Sendai) and bacterial (Mycoplasma pulmonis) contamination. Mice received certified NIH-07 rodent feed and tap water in water bottles ad libitum. Mice were housed no more than five per cage in plastic shoe box-type cages with sawdust bedding; the cages were cleaned and sanitized twice per week.

For the irritancy studies (Figure K1), groups of four mice received 50 µL dermal applications of 0% (vehicle controls), 0.1%, 0.25%, 0.5%, 1%, 3%, or 5% (w/v) of the approximately 10% pentaerythritol triacrylate mixture or 0%, 0.025%, 0.05%, 0.075%, 0.1%, 0.25%, or 0.5% of the approximately 45% pentaerythritol triacrylate mixture in acetone; 12.5 µL were applied to each side of each ear. Doses were administered by pipette once per day for 4 consecutive days. For each study, an additional group of four animals was maintained as untreated (naive) controls. Prior to application of the first dose and 24 ± 2 hours after the last dose, the thickness of each ear was measured at two sites with a modified micrometer (Mitutoyo America Corp., Aurora, IL). Ear swelling (mean thickness after dosing/mean thickness predosing) was calculated as a percentage for each ear.

For the mouse ear swelling tests (Figure K2), groups of eight mice were sensitized with 50 µL dermal applications of 0% (two control groups), 0.01%, 0.05%, or 0.1% (w/v) of each pentaerythritol triacrylate mixture in acetone to the shaved dorsal lumbar area. Doses were administered by pipette once per day for 3 consecutive days. The animals were restrained after dosing to allow the vehicle to begin to volatilize. The mice were not dosed on days 4 through 7. On day 8, the thickness of the right ear of each animal was measured prior to dosing as described for the irritancy study. Challenge doses (25.0 µL total volume) were applied to the dorsal and ventral surfaces of the right ear pinna, divided between the two sides. The two control groups sensitized with acetone received challenges of acetone (vehicle controls) or 0.25% of the appropriate pentaerythritol triacrylate mixture (background controls). The three groups sensitized with pentaerythritol triacrylate received a challenge dose of 0.25% of the appropriate pentaerythritol triacrylate mixture. The right ears were remeasured 24 and 48 hours after the challenge doses were applied, and ear swelling was calculated as a percentage for each mouse at each time point.

For the local lymph node assays (Figure K3), groups of six mice were sensitized with 50 µL dermal applications of 0% (vehicle controls), 0.05%, 0.1%, or 0.25% (w/v) of each pentaerythritol triacrylate mixture in acetone. When a no-effect level was not determined in the first study of the approximately 10% mixture, that study was repeated using doses of 0.005%, 0.01%, and 0.05% of the approximately 10% pentaerythritol mixture in acetone. The doses (12.5 µL applied to each side of each ear) were applied by pipette once per day for 3 consecutive days. The mice were not dosed on day 4. On day 5, 0.2 mL (20 µCi) of [^3^H]-thymidine was intravenously injected (tail vein). The animals were killed approximately 5 hours after the injection, and the left and right draining (superficial cervical) lymph nodes were excised and placed in cold phosphate-buffered saline. All lymph nodes were dissociated by grinding between the frosted ends of two microscope slides. The cells were washed twice in phosphate-buffered saline and then resuspended in 3 mL 5% trichloroacetic acid in distilled water. After 18 to 60 hours at approximately 4° C, the cells were resuspended in trichloroacetic acid, transferred into 5 mL scintillation cocktail, and counted on a beta counter for 5 minutes.

The data were analyzed for homogeneity with Bartlett’s chi-square test (Bartlett, 1937). Homogeneous data were tested for significance with a one-way analysis of variance (Kruskal and Wallis, 1952) followed by Dunnett’s multiple-range t-test (Dunnett, 1955) if the analysis of variance indicated a significant main effect. For nonhomogeneous data, a nonparametric analysis of variance, Wilson’s test (Wilson, 1956), and the Wilcoxon rank sum test (Gross and Clark, 1975) were used to compare treatment groups with the controls.

## Results and Discussion

There were no deaths, body weight changes, or clinical findings related to pentaerythritol triacrylate treatment in dosed mice. Results of the irritancy studies of the approximately 10% and 45% pentaerythritol triacrylate mixtures indicated that the maximal nonirritating and minimal irritating doses were 0.1% and 0.25% pentaerythritol triacrylate, respectively, for each mixture (Figures K4 and K5).

The mouse ear swelling test did not indicate the approximately 10% pentaerythritol triacrylate mixture as a contact sensitizer in female BALB/c mice at the doses tested 24 or 48 hours after dosing (Figure K6). Testing of the approximately 45% pentaerythritol triacrylate mixture with the ear swelling test paradigm indicated pentaerythritol triacrylate as a contact sensitizer at 0.1%, with significant increases (compared to background controls) in percent ear swelling noted 24 and 48 hours postchallenge (Figure K7). In the first local lymph node assay using the approximately 10% pentaerythritol triacrylate mixture, a significant increase in lymph node cell proliferation occurred in all dosed groups of mice compared to the vehicle controls; in the second assay using lower sensitizing doses, a significant response occurred only in the 0.05% group (Figure K8). The local lymph node assay of the approximately 45% pentaerythritol triacrylate mixture yielded a positive response only with a sensitizing concentration of 0.25% (Figure K9).

In summary, for both the approximately 10% and 45% pentaerythritol triacrylate mixtures, the maximal nonirritating concentration was determined to be 0.1%, and the minimal irritating concentration to be 0.25%. The mouse ear swelling test yielded negative results for pentaerythritol triacrylate as a potential contact sensitizer when the approximately 10% pentaerythritol triacrylate mixture was used and positive results when the approximately 45% pentaerythritol triacrylate mixture was used. Positive responses were seen in local lymph node assays at concentrations of 0.05%, 0.1%, and 0.25% pentaerythritol triacrylate when the approximately 10% pentaerythritol triacrylate mixture was used and at a concentration of 0.25% pentaerythritol triacrylate when the approximately 45% pentaerythritol triacrylate mixture was used. These data indicate the potential of pentaerythritol triacrylate as a weak contact sensitizer.

## References

Bartlett, M.S. (1937). Sub-sampling for attributes. J. Royal Stat. Soc. (Suppl. 4), 131–135.
Dunnett, C.W. (1955). A multiple comparison procedure for comparing several treatments with a control. J. Am. Stat. Assoc. 50, 1096–1121.
Gross, A.J., and Clark, V.A., Eds. (1975). Gehan-Wilcoxon Test. In Survival Distribution: Reliability Applications in the Biomedical Sciences, pp. 120–123. John Wiley and Sons, New York.
Kruskal, W.H., and Wallis, W.A. (1952). Use of ranks in one-criterion variance analysis. J. Am. Stat. Assoc. 47, 583–621.
Wilson, K.V. (1956). A distribution free test of analysis of variance hypothesis. Psychol. Bull. 53, 96–101.13289969

FIGURE K1 Major Events in the Primary Irritancy Studies

FIGURE K2 Major Events in the Mouse Ear Swelling Tests

FIGURE K3 Major Events in the Local Lymph Node Assays

FIGURE K4 Primary Irritancy Response to the Approximately 10% Pentaerythritol Triacrylate Mixture in Female BALB/c Mice

* Statistically significant (P<0.05) compared to vehicle control

**P<0.01

Means for each group are shown, with bars representing the standard error.

VH=vehicle controls, NA=untreated (naive) controls,

PEA=approximately 10% pentaerythritol triacrylate mixture

FIGURE K5 Primary Irritancy Response to the Approximately 45% Pentaerythritol Triacrylate Mixture in Female BALB/c Mice

**Statistically significant (P<0.01) compared to vehicle control

Means for each group are shown, with bars representing the standard error.

VH=vehicle controls, NA=untreated (naive) controls,

PET=approximately 45% pentaerythritol triacrylate mixture

FIGURE K6 Contact Hypersensitivity Response to the Approximately 10% Pentaerythritol Triacrylate Mixture in Female BALB/c Mice (Mouse Ear Swelling Test)

Means for each group are shown, with bars representing the standard error.

VH=vehicle controls, BC=background controls,

PEA=approximately 10% pentaerythritol triacrylate mixture

FIGURE K7 Contact Hypersensitivity Response to the Approximately 45% Pentaerythritol Triacrylate Mixture in Female BALB/c Mice (Mouse Ear Swelling Test)

* Statistically significant (P<0.05) compared to background control

**P<0.01

Means for each group are shown, with bars representing the standard error.

VH=vehicle controls, BC=background controls,

PET=approximately 45% pentaerythritol triacrylate mixture

FIGURE K8 Contact Hypersensitivity Response to the Approximately 10% Pentaerythritol Triacrylate Mixture in Female BALB/c Mice (Local Lymph Node Assays)

* Statistically significant (P<0.05) compared to background control

**P<0.01

Means for each group are shown, with bars representing the standard error.

VH=vehicle controls, BC=background controls,

PEA=approximately 10% pentaerythritol triacrylate mixture

FIGURE K9 Contact Hypersensitivity Response to the Approximately 45% Pentaerythritol Triacrylate Mixture in Female BALB/c Mice (Local Lymph Node Assay)

**Statistically significant (P<0.01) compared to background control

Means for each group are shown, with bars representing the standard error.

VH=vehicle controls, PET=approximately 45% pentaerythritol triacrylate mixture