# APPENDIX J SENTINEL ANIMAL PROGRAM

## Methods

Rodents used in the Carcinogenesis Program of the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of chemical compounds. Under this program, the disease state of the rodents is monitored via serology on sera from extra (sentinel) animals in the study rooms. These animals and the study animals are subject to identical environmental conditions. The sentinel animals come from the same production source and weanling groups as the animals used for the studies of chemical compounds.

Serum samples were collected from randomly selected rats and mice during the 3- and 6-month studies. Blood from each animal was collected and allowed to clot, and the serum was separated. The samples were processed appropriately and sent to MA BioServices, Inc., or BioReliance Corporation (Rockville, MD) for determination of antibody titers. The laboratory serology methods and viral agents for which testing was performed are tabulated below; the times at which blood was collected during the studies are also listed.

[underlined: Method and Test] | [underlined: Time of Analysis]
RATS
3-Month Study
ELISA
Mycoplasma arthritidis | Study termination
Mycoplasma pulmonis | Study termination
PVM (pneumonia virus of mice) | 4 weeks, study termination
RCV/SDA
(rat coronavirus/sialodacryoadenitis virus) | 4 weeks, study termination
Sendai | 4 weeks, study termination
Immunofluorescence Assay
Helicobacter hepaticus | Study termination
Hemagglutination Inhibition
H-1 (Toolan’s H-1 virus) | 4 weeks, study termination
KRV (Kilham rat virus) | 4 weeks, study termination
MICE
3-Month Study
ELISA
Ectromelia virus | 4 weeks, study termination
EDIM (epizootic diarrhea of infant mice) | 4 weeks, study termination
GDVII (mouse encephalomyelitis virus) | 4 weeks, study termination
LCM (lymphocytic choriomeningitis virus) | 4 weeks, study termination
Mouse adenoma virus | 4 weeks, study termination
MHV (mouse hepatitis virus) | 4 weeks, study termination
M. arthritidis | Study termination
M. pulmonis | Study termination
PVM | 4 weeks, study termination
Reovirus 3 | 4 weeks, study termination
Sendai | 4 weeks, study termination
Immunofluorescence Assay
H. hepaticus | Study termination
MCMV (mouse cytomegalovirus) | Study termination
Hemagglutination Inhibition
K (papovavirus) | 4 weeks, study termination
MVM (minute virus of mice) | 4 weeks, study termination
Polyoma virus | 4 weeks, study termination
6-Month Study
ELISA
Ectromelia virus | 4 weeks, study termination
EDIM | 4 weeks, study termination
GDVII | 4 weeks, study termination
LCM | 4 weeks, study termination
Mouse adenoma virus-FL | 4 weeks, study termination
MHV | 4 weeks, study termination
M. arthritidis | Study termination
M. pulmonis | Study termination
PVM | 4 weeks, study termination
Reovirus 3 | 4 weeks, study termination
Sendai | 4 weeks, study termination
Immunofluorescence Assay
MCMV | Study termination
M. arthritidis | Study termination
Parvovirus | 4 weeks, study termination

## Results

One male and two female rats in the 3-month studies had a positive titer for H. hepaticus. Also, one male and one female rat in the 3-month studies were equivocal for H. hepaticus. For the 6-month studies in mice, all serology tests were negative.