# APPENDIX I INGREDIENTS, NUTRIENT COMPOSITION, AND CONTAMINANT LEVELS IN NTP-2000 RAT AND MOUSE RATION

TABLE I1 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground hard winter wheat | 22.26
Ground #2 yellow shelled corn | 22.18
Wheat middlings | 15.0
Oat hulls | 8.5
Alfalfa meal (dehydrated, 17% protein) | 7.5
Purified cellulose | 5.5
Soybean meal (49% protein) | 5.0
Fish meal (60% protein) | 4.0
Corn oil (without preservatives) | 3.0
Soy oil (without preservatives) | 3.0
Dried brewer’s yeast | 1.0
Calcium carbonate (USP) | 0.9
Vitamin premix^a^ | 0.5
Mineral premix^b^ | 0.5
Calcium phosphate, dibasic (USP) | 0.4
Sodium chloride | 0.3
Choline chloride (70% choline) | 0.26
Methionine | 0.2

a Wheat middlings as carrier

b Calcium carbonate as carrier

TABLE I2 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration^a^

| Amount | Source
Vitamins
A | 4,000 IU | Stabilized vitamin A palmitate or acetate
D | 1,000 IU | D-activated animal sterol
K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl acetate | 100 IU
Niacin | 23 mg
Folic acid | 1.1 mg
d-Pantothenic acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg
Thiamine | 4 mg | Thiamine mononitrate
B_12_ | 52 μg
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerais
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

a Per kg of finished product

TABLE I3 Nutrient Composition of NTP-2000 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by weight) | 13.0 ± 0.26 | 12.7 – 13.3 | 7
Crude fat (% by weight) | 8.1 ± 0.26 | 7.6 – 8.4 | 7
Crude fiber (% by weight) | 9.6 ± 0.36 | 9.2 – 10.0 | 7
Ash (% by weight) | 4.9 ± 0.11 | 4.7 – 5.0 | 7
Amino Acids (% of total diet)
Arginine | 0.731 ± 0.050 | 0.670 – 0.800 | 8
Cystine | 0.224 ± 0.012 | 0.210 – 0.240 | 8
Glycine | 0.684 ± 0.041 | 0.620 – 0.740 | 8
Histidine | 0.333 ± 0.018 | 0.310 – 0.350 | 8
Isoleucine | 0.524 ± 0.046 | 0.430 – 0.590 | 8
Leucine | 1.061 ± 0.061 | 0.960 – 1.130 | 8
Lysine | 0.708 ± 0.056 | 0.620 – 0.790 | 8
Methionine | 0.401 ± 0.035 | 0.350 – 0.460 | 8
Phenylalanine | 0.598 ± 0.036 | 0.540 – 0.640 | 8
Threonine | 0.501 ± 0.051 | 0.430 – 0.590 | 8
Tryptophan | 0.126 ± 0.014 | 0.110 – 0.150 | 8
Tyrosine | 0.390 ± 0.056 | 0.280 – 0.460 | 8
Valine | 0.640 ± 0.049 | 0.550 – 0.690 | 8
Essential Fatty Acids (% of total diet)
Linoleic | 3.97 ± 0.284 | 3.59 – 4.54 | 8
Linolenic | 0.30 ± 0.042 | 0.21 – 0.35 | 8
Vitamins
Vitamin A (IU/kg) | 6,077 ± 946 | 4,820 – 7,420 | 7
Vitamin D (IU/kg) | 1,000^a^
α-Tocopherol (ppm) | 82.2 ± 14.08 | 62.2 – 107.0 | 8
Thiamine (ppm)^b^ | 7.3 ± 1.25 | 6.1 – 9.3 | 7
Riboflavin (ppm) | 5.6 ± 1.12 | 4.20 – 7.70 | 8
Niacin (ppm) | 74.3 ± 5.94 | 66.4 – 85.8 | 8
Pantothenic acid (ppm) | 22.5 ± 3.96 | 17.4 – 29.1 | 8
Pyridoxine (ppm)^b^ | 9.04 ± 2.37 | 6.4 – 12.4 | 8
Folic acid (ppm) | 1.64 ± 0.38 | 1.26 – 2.32 | 8
Biotin (ppm) | 0.333 ± 0.15 | 0.225 – 0.704 | 8
Vitamin B_12_ (ppb) | 68.7 ± 63.0 | 18.3 – 174.0 | 8
Choline (ppm)^b^ | 3,155 ± 325 | 2,700 – 3,790 | 8
Minerals
Calcium (%) | 0.958 ± 0.015 | 0.935 – 0.979 | 7
Phosphorus (%) | 0.532 ± 0.020 | 0.505 – 0.563 | 7
Potassium (%) | 0.659 ± 0.022 | 0.627 – 0.691 | 8
Chloride (%) | 0.357 ± 0.027 | 0.300 – 0.392 | 8
Sodium (%) | 0.189 ± 0.019 | 0.160 – 0.212 | 8
Magnesium (%) | 0.199 ± 0.009 | 0.185 – 0.213 | 8
Sulfur (%) | 0.178 ± 0.021 | 0.153 – 0.209 | 8
Iron (ppm) | 160 ± 14.7 | 135 – 177 | 8
Manganese (ppm) | 50.3 ± 4.82 | 42.1 – 56.0 | 8
Zinc (ppm) | 50.7 ± 6.59 | 43.3 – 61.1 | 8
Copper (ppm) | 6.29 ± 0.828 | 5.08 – 7.59 | 8
Iodine (ppm) | 0.461 ± 0.187 | 0.233 – 0.843 | 8
Chromium (ppm) | 0.542 ± 0.128 | 0.330 – 0.707 | 7
Cobalt (ppm) | 0.23 ± 0.049 | 0.20 – 0.30 | 7

a From formulation

b As hydrochloride (thiamine and pyridoxine) or chloride (choline)

TABLE I4 Contaminant Levels in NTP-2000 Rat and Mouse Ration^a^

| Mean ± Standard Deviation^b^ | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.18 ± 0.090 | 0.10 – 0.33 | 7
Cadmium (ppm) | 0.04 ± 0.004 | 0.04 – 0.05 | 7
Lead (ppm) | 0.08 ± 0.008 | 0.07 – 0.09 | 7
Mercury (ppm) | <0.02 | | 7
Selenium (ppm) | 0.18 ± 0.024 | 0.15 – 0.23 | 7
Aflatoxins (ppb) | <5.00 | | 7
Nitrate nitrogen (ppm)^c^ | 11.2 ± 2.75 | 9.04 – 16.8 | 7
Nitrite nitrogen (ppm)^c^ | <0.61 | | 7
BHA (ppm)^d^ | <1.0 | | 7
BHT (ppm)^d^ | <1.0 | | 7
Aerobic plate count (CFU/g) | <10 | | 7
Coliform (MPN/g) | 0 | | 7
Escherichia coli (MPN/g) | <10 | | 7
Salmonella (MPN/g) | Negative | | 7
Total nitrosoamines (ppb)^e^ | 5.8 ± 1.89 | 3.2 – 8.8 | 7
N-Nitrosodimethylamine (ppb)^e^ | 2.5 ± 1.31 | 1.2 – 5.1 | 7
N-Nitrosopyrrolidine (ppb)^e^ | 3.3 ± 1.3 | 1.9 – 5.6 | 7
Pesticides (ppm)
α-BHC | <0.01 | | 7
β-BHC | <0.02 | | 7
γ-BHC | <0.01 | | 7
δ-BHC | <0.01 | | 7
Heptachlor | <0.01 | | 7
Aldrin | <0.01 | | 7
Heptachlor epoxide | <0.01 | | 7
DDE | <0.01 | | 7
DDD | <0.01 | | 7
DDT | <0.01 | | 7
HCB | <0.01 | | 7
Mirex | <0.01 | | 7
Methoxychlor | <0.05 | | 7
Dieldrin | <0.01 | | 7
Endrin | <0.01 | | 7
Telodrin | <0.01 | | 7
Chlordane | <0.05 | | 7
Toxaphene | <0.10 | | 7
Estimated PCBs | <0.20 | | 7
Ronnel | <0.01 | | 7
Ethion | <0.02 | | 7
Trithion | <0.05 | | 7
Diazinon | <0.10 | | 7
Methyl chlorpyrifos | 0.075 ± 0.081 | 0.020 – 0.253 | 7
Methyl parathion | <0.02 | | 7
Ethyl parathion | <0.02 | | 7
Malathion | 0.121 ± 0.118 | 0.020 – 0.311 | 7
Endosulfan I | <0.01 | | 7
Endosulfan II | <0.01 | | 7
Endosulfan sulfate | <0.03 | | 7

a All samples were irradiated. CFU=colony-forming units; MPN=most probable number; BHC=hexachlorocyclohexane or benzene hexachloride

b For values less than the limit of detection, the detection limit is given as the mean.

c Sources of contamination: alfalfa, grains, and fish meal

d Sources of contamination: soy oil and fish meal

e All values were corrected for percent recovery.