# APPENDIX G REPRODUCTIVE TISSUE EVALUATIONS AND ESTROUS CYCLE CHARACTERIZATION

TABLE G1 Summary of Reproductive Tissue Evaluations for Male Rats in the 3-Month Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 3 mg/kg | 6 mg/kg | 12 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 288 ± 11 | 275 ± 7 | 266 ± 5^*^ | 259 ± 5^**^
L. Cauda epididymis | 0.141 ± 0.003 | 0.140 ± 0.004 | 0.135 ± 0.008 | 0.145 ± 0.004
L. Epididymis | 0.401 ± 0.010 | 0.391 ± 0.007 | 0.391 ± 0.008 | 0.394 ± 0.009
L. Testis | 1.43 ± 0.03 | 1.40 ± 0.01 | 1.45 ± 0.02 | 1.43 ± 0.02
Spermatid measurements
Spermatid heads (10^7^/g testis) | 149 ± 4 | 148 ± 6 | 148 ± 4 | 136 ± 4
Spermatid heads (10^7^/testis) | 194 ± 6 | 191 ± 7 | 197 ± 5 | 180 ± 4
Spermatid heads (10^7^/g cauda) | 459 ± 27 | 420 ± 25 | 478 ± 69 | 440 ± 16
Spermatid heads (10^7^/cauda) | 64.5 ± 3.7 | 58.8 ± 4.1 | 61.1 ± 6.7 | 63.7 ± 3.1
Epididymal spermatozoal measurements
Motility (%) | 74.0 ± 1.0 | 72.6 ± 0.8 | 72.8 ± 1.2 | 75.1 ± 0.8

* Significantly different (P≤0.05) from the vehicle control group by Williams’ test.

** P≤0.01

a Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

TABLE G2 Estrous Cycle Characterization for Female Rats in the 3-Month Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 3 mg/kg | 6 mg/kg | 12 mg/kg
n | 10 | 10 | 10 | 10
Necropsy body wt (g) | 174 ± 3 | 171 ± 3 | 167 ± 4 | 166 ± 4_b_
Estrous cycle length (days) | 5.00 ± 0.00 | 4.90 ± 0.10 | 5.20 ± 0.20 | 5.94 ± 0.58^b^
Estrous stages (% of cycle)
Diestrus | 50.0 | 46.7 | 50.0 | 48.3
Proestrus | 19.2 | 17.5 | 17.5 | 14.2
Estrus | 17.5 | 20.0 | 17.5 | 14.2
Metestrus | 13.3 | 15.8 | 14.2 | 16.7
Uncertain diagnoses | 0.0 | 0.0 | 0.8 | 6.7

a Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weights) or Dunn’s test (estrous cycle lengths). By multivariate analysis of variance, dosed females did not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages.

b Estrous cycle was longer than 12 days or unclear in 1 of 10 animals.

TABLE G3 Summary of Reproductive Tissue Evaluations for Male B6C3F_1_ Mice in the 3-Month Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 3 mg/kg | 6 mg/kg | 12 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 33.8 ± 0.5 | 33.7 ± 1.1 | 32.8 ± 0.4 | 33.3 ± 0.5
L. Cauda epididymis | 0.014 ± 0.001 | 0.013 ± 0.001 | 0.013 ± 0.001 | 0.012 ± 0.001
L. Epididymis | 0.040 ± 0.001 | 0.039 ± 0.001 | 0.037 ± 0.001 | 0.038 ± 0.001
L. Testis | 0.11 ± 0.00 | 0.11 ± 0.00 | 0.10 ± 0.01 | 0.11 ± 0.01
Spermatid measurements
Spermatid heads (10^7^/g testis) | 198 ± 12 | 230 ± 12 | 234 ± 13 | 210 ± 14
Spermatid heads (10^7^/testis) | 19 ± 1 | 23 ± 1^*^ | 22 ± 1 | 22 ± 2
Spermatid heads (10^7^/g cauda) | 725 ± 55 | 1,140 ± 261 | 1,034 ± 67^*^ | 1,423 ± 270^*^
Spermatid heads (10^7^/cauda) | 10.0 ± 0.9 | 14.1 ± 2.6 | 13.1 ± 0.9 | 16.5 ± 3.0
Epididymal spermatozoal measurements
Motility (%) | 73.0 ± 0.5 | 72.0 ± 0.6 | 74.5 ± 1.6 | 74.8 ± 0.5

* Significantly different (P#0.05) from the vehicle control group by Dunn’s test (spermatid heads/testis) or Shirley’s test (spermatid heads/cauda).

a Data are given as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body and tissue weights) or Dunn’s test (epididymal spermatozoal measurements).

TABLE G4 Estrous Cycle Characterization for Female B6C3F_1_ Mice in the 3-Month Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 3 mg/kg | 6 mg/kg | 12 mg/kg
n | 9 | 10 | 10 | 10
Necropsy body wt (g) | 31.6 ± 0.8 | 31.3 ± 0.8 | 30.0 ± 1.0 | 29.0 ± 0.4
Estrous cycle length (days) | 4.28 ± 0.15 | 4.20 ± 0.13 | 4.25 ± 0.11 | 4.10 ± 0.10
Estrous stages (% of cycle)
Diestrus | 25.9 | 30.8 | 30.0 | 25.0
Proestrus | 23.1 | 20.8 | 19.2 | 20.8
Estrus | 26.9 | 25.8 | 29.2 | 30.0
Metestrus | 24.1 | 22.5 | 21.7 | 24.2

a Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weights) or Dunn’s test (estrous cycle lengths). By multivariate analysis of variance, dosed females did not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages.