# APPENDIX F ORGAN WEIGHTS AND ORGAN-WEIGHT-TO-BODY-WEIGHT RATIOS

TABLE F1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the 2-Week Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 12.5 mg/kg | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Necropsy body wt | 182 ± 5 | 176 ± 1 | 174 ± 2 | 171 ± 4^*^ | 173 ± 2^*^ | 157 ± 2^**^
Heart
Absolute | 0.690 ± 0.013 | 0.679 ± 0.024 | 0.678 ± 0.014 | 0.677 ± 0.018 | 0.739 ± 0.055 | 0.714 ± 0.015
Relative | 3.791 ± 0.055 | 3.853 ± 0.130 | 3.892 ± 0.067 | 3.967 ± 0.099 | 4.272 ± 0.289^*^ | 4.555 ± 0.147^**^
R. Kidney
Absolute | 0.741 ± 0.023 | 0.738 ± 0.016 | 0.723 ± 0.013 | 0.734 ± 0.019 | 0.753 ± 0.023 | 0.712 ± 0.026
Relative | 4.075 ± 0.142 | 4.189 ± 0.075 | 4.151 ± 0.043 | 4.299 ± 0.072 | 4.363 ± 0.122 | 4.529 ± 0.110^**^
Liver
Absolute | 9.055 ± 0.256 | 8.454 ± 0.170 | 8.583 ± 0.302 | 8.333 ± 0.268 | 8.789 ± 0.233 | 7.644 ± 0.159^**^
Relative | 49.8 ± 1.2 | 48.0 ± 0.8 | 49.3 ± 1.4 | 48.8 ± 1.0 | 50.9 ± 1.3 | 48.7 ± 0.7
Lung
Absolute | 1.365 ± 0.062 | 1.342 ± 0.053 | 1.239 ± 0.054 | 1.280 ± 0.050 | 1.136 ± 0.044^**^ | 1.105 ± 0.046^**^
Relative | 7.514 ± 0.392 | 7.620 ± 0.305 | 7.121 ± 0.339 | 7.509 ± 0.312 | 6.573 ± 0.209 | 7.046 ± 0.326
R. Testis
Absolute | 1.129 ± 0.029 | 1.155 ± 0.012 | 1.111 ± 0.016 | 1.147 ± 0.005 | 1.133 ± 0.008 | 1.128 ± 0.014
Relative | 6.211 ± 0.174 | 6.559 ± 0.083 | 6.382 ± 0.072 | 6.735 ± 0.152^*^ | 6.567 ± 0.038^*^ | 7.186 ± 0.096^**^
Thymus
Absolute | 0.410 ± 0.010 | 0.374 ± 0.035 | 0.399 ± 0.015 | 0.338 ± 0.031 | 0.377 ± 0.029 | 0.340 ± 0.015
Relative | 2.251 ± 0.025 | 2.120 ± 0.192 | 2.289 ± 0.084 | 1.978 ± 0.183 | 2.180 ± 0.155 | 2.164 ± 0.096
Female
Necropsy body wt | 125 ± 2 | 125 ± 2 | 124 ± 2 | 124 ± 4 | 119 ± 1 | 114 ± 3^**^
Heart
Absolute | 0.527 ± 0.018 | 0.485 ± 0.042 | 0.503 ± 0.010 | 0.525 ± 0.017 | 0.525 ± 0.008 | 0.531 ± 0.011
Relative | 4.227 ± 0.101 | 3.889 ± 0.330 | 4.076 ± 0.090 | 4.231 ± 0.071 | 4.415 ± 0.036 | 4.659 ± 0.052
R. Kidney
Absolute | 0.535 ± 0.008 | 0.550 ± 0.012 | 0.553 ± 0.010 | 0.580 ± 0.018 | 0.571 ± 0.009 | 0.566 ± 0.013
Relative | 4.288 ± 0.051 | 4.405 ± 0.059 | 4.479 ± 0.056 | 4.673 ± 0.095^**^ | 4.796 ± 0.061^**^ | 4.967 ± 0.045^**^
Liver
Absolute | 5.621 ± 0.156 | 5.810 ± 0.135 | 5.861 ± 0.137 | 5.857 ± 0.157 | 5.721 ± 0.082 | 5.655 ± 0.241
Relative | 45.1 ± 1.0 | 46.5 ± 1.0 | 47.5 ± 0.6 | 47.2 ± 0.8 | 48.1 ± 0.6^*^ | 49.5 ± 0.9^**^
Lung
Absolute | 0.911 ± 0.058 | 1.114 ± 0.098 | 0.935 ± 0.035 | 1.078 ± 0.036 | 0.887 ± 0.027 | 0.903 ± 0.055
Relative | 7.298 ± 0.419 | 8.898 ± 0.714^*^ | 7.590 ± 0.331 | 8.678 ± 0.163 | 7.460 ± 0.255 | 7.904 ± 0.351
Thymus
Absolute | 0.336 ± 0.025 | 0.373 ± 0.035 | 0.332 ± 0.015 | 0.326 ± 0.010 | 0.295 ± 0.015 | 0.320 ± 0.009
Relative | 2.696 ± 0.209 | 2.985 ± 0.256 | 2.688 ± 0.115 | 2.635 ± 0.125 | 2.481 ± 0.142 | 2.811 ± 0.053

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

TABLE F2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the 3-Month Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 288 ± 11 | 283 ± 7 | 288 ± 6 | 275 ± 7 | 266 ± 5^*^ | 259 ± 5^**^
Heart
Absolute | 0.905 ± 0.030 | 0.933 ± 0.026 | 0.923 ± 0.024 | 0.863 ± 0.016 | 0.900 ± 0.021 | 0.882 ± 0.019
Relative | 3.154 ± 0.056 | 3.301 ± 0.069 | 3.213 ± 0.075 | 3.142 ± 0.030 | 3.393 ± 0.071^**^ | 3.406 ± 0.053^**^
R. Kidney
Absolute | 1.000 ± 0.030 | 0.956 ± 0.025 | 0.997 ± 0.023 | 0.972 ± 0.022 | 0.985 ± 0.015 | 0.974 ± 0.018
Relative | 3.489 ± 0.068 | 3.381 ± 0.056 | 3.469 ± 0.048 | 3.538 ± 0.047 | 3.716 ± 0.067^**^ | 3.762 ± 0.046^**^
Liver
Absolute | 11.501 ± 0.571 | 11.260 ± 0.401 | 11.678 ± 0.435 | 11.269 ± 0.462 | 10.525 ± 0.310 | 10.448 ± 0.275
Relative | 39.9 ± 0.8 | 39.8 ± 0.9 | 40.5 ± 0.9 | 40.9 ± 0.9 | 39.6 ± 0.8 | 40.3 ± 0.5
Lung
Absolute | 1.726 ± 0.079 | 1.723 ± 0.094 | 1.821 ± 0.079 | 1.675 ± 0.059 | 1.761 ± 0.090 | 1.715 ± 0.062
Relative | 6.041 ± 0.301 | 6.097 ± 0.312 | 6.324 ± 0.209 | 6.097 ± 0.187 | 6.610 ± 0.261 | 6.639 ± 0.270
R. Testis
Absolute | 1.381 ± 0.032 | 1.386 ± 0.022 | 1.399 ± 0.016 | 1.361 ± 0.018 | 1.371 ± 0.016 | 1.386 ± 0.020
Relative | 4.828 ± 0.094 | 4.913 ± 0.092 | 4.878 ± 0.062 | 4.965 ± 0.078 | 5.175 ± 0.091^**^ | 5.359 ± 0.092^**^
Thymus
Absolute | 0.362 ± 0.019 | 0.343 ± 0.010 | 0.336 ± 0.008 | 0.314 ± 0.011^**^ | 0.289 ± 0.010^**^ | 0.290 ± 0.012^**^
Relative | 1.256 ± 0.041 | 1.216 ± 0.042 | 1.175 ± 0.041 | 1.141 ± 0.028^*^ | 1.089 ± 0.032^**^ | 1.119 ± 0.044^**^
Female
Necropsy body wt | 174 ± 4 | 174 ± 3 | 172 ± 4 | 171 ± 3 | 167 ± 4 | 166 ± 4
Heart
Absolute | 0.663 ± 0.011 | 0.692 ± 0.017 | 0.678 ± 0.019 | 0.683 ± 0.022 | 0.669 ± 0.024 | 0.652 ± 0.017
Relative | 3.816 ± 0.068 | 3.981 ± 0.053 | 3.960 ± 0.118 | 3.993 ± 0.123 | 4.009 ± 0.145 | 3.929 ± 0.068
R. Kidney
Absolute | 0.686 ± 0.011 | 0.664 ± 0.011 | 0.652 ± 0.014 | 0.681 ± 0.013 | 0.678 ± 0.014 | 0.686 ± 0.018
Relative | 3.945 ± 0.045 | 3.826 ± 0.057 | 3.800 ± 0.045 | 3.979 ± 0.053 | 4.057 ± 0.046 | 4.124 ± 0.030^*^
Liver
Absolute | 6.698 ± 0.245 | 6.655 ± 0.153 | 6.175 ± 0.236 | 6.398 ± 0.107 | 6.293 ± 0.254 | 6.332 ± 0.243
Relative | 38.4 ± 0.9 | 38.3 ± 0.5 | 35.9 ± 0.7^*^ | 37.4 ± 0.5 | 37.5 ± 0.7 | 38.0 ± 0.6
Lung
Absolute | 1.304 ± 0.077 | 1.295 ± 0.062 | 1.311 ± 0.076 | 1.309 ± 0.050 | 1.241 ± 0.072 | 1.365 ± 0.077
Relative | 7.469 ± 0.361 | 7.432 ± 0.273 | 7.609 ± 0.349 | 7.658 ± 0.285 | 7.419 ± 0.408 | 8.174 ± 0.310
Thymus
Absolute | 0.287 ± 0.012 | 0.266 ± 0.011 | 0.264 ± 0.013 | 0.253 ± 0.014 | 0.253 ± 0.011 | 0.253 ± 0.010
Relative | 1.654 ± 0.076 | 1.533 ± 0.055 | 1.537 ± 0.077 | 1.471 ± 0.064 | 1.513 ± 0.061 | 1.527 ± 0.070

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

TABLE F3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for B6C3F_1_ Mice in the 2-Week Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 12.5 mg/kg | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Necropsy body wt | 24.6 ± 0.4 | 25.3 ± 0.3 | 26.1 ± 0.2^**^ | 25.4 ± 0.4 | 24.3 ± 0.3 | 24.2 ± 0.3
Heart
Absolute | 0.133 ± 0.003 | 0.129 ± 0.003 | 0.148 ± 0.004^*^ | 0.156 ± 0.001^**^ | 0.135 ± 0.005 | 0.142 ± 0.006
Relative | 5.418 ± 0.074 | 5.075 ± 0.078 | 5.670 ± 0.164 | 6.141 ± 0.084^**^ | 5.535 ± 0.152 | 5.877 ± 0.233
R. Kidney
Absolute | 0.238 ± 0.007 | 0.237 ± 0.005 | 0.256 ± 0.004 | 0.255 ± 0.013 | 0.234 ± 0.007 | 0.231 ± 0.009
Relative | 9.684 ± 0.163 | 9.337 ± 0.143 | 9.801 ± 0.133 | 10.002 ± 0.385 | 9.614 ± 0.193 | 9.540 ± 0.374
Liver
Absolute | 1.461 ± 0.066 | 1.472 ± 0.035 | 1.549 ± 0.032 | 1.556 ± 0.053 | 1.409 ± 0.058 | 1.351 ± 0.021
Relative | 59.4 ± 2.1 | 58.1 ± 1.5 | 59.3 ± 0.8 | 61.3 ± 2.2 | 57.9 ± 1.7 | 55.8 ± 0.3
Lung
Absolute | 0.196 ± 0.011 | 0.193 ± 0.005 | 0.203 ± 0.007 | 0.184 ± 0.004 | 0.181 ± 0.008 | 0.184 ± 0.010
Relative | 7.997 ± 0.458 | 7.640 ± 0.308 | 7.777 ± 0.285 | 7.232 ± 0.141 | 7.442 ± 0.255 | 7.622 ± 0.458
R. Testis
Absolute | 0.100 ± 0.002 | 0.094 ± 0.002 | 0.100 ± 0.003 | 0.097 ± 0.004 | 0.101 ± 0.002 | 0.098 ± 0.003
Relative | 4.062 ± 0.070 | 3.709 ± 0.052^*^ | 3.820 ± 0.082 | 3.830 ± 0.117 | 4.139 ± 0.060 | 4.066 ± 0.123
Thymus
Absolute | 0.056 ± 0.003 | 0.053 ± 0.003 | 0.051 ± 0.004 | 0.041 ± 0.004^*^ | 0.034 ± 0.004^**^ | 0.030 ± 0.004^**^
Relative | 2.277 ± 0.130 | 2.113 ± 0.141 | 1.940 ± 0.149 | 1.615 ± 0.158^**^ | 1.377 ± 0.156^**^ | 1.253 ± 0.166^**^
Female
Necropsy body wt | 20.9 ± 0.6 | 21.2 ± 0.4 | 21.9 ± 0.7 | 19.6 ± 1.3 | 22.1 ± 0.6 | 21.2 ± 0.5
Heart
Absolute | 0.123 ± 0.004 | 0.126 ± 0.004 | 0.120 ± 0.005 | 0.113 ± 0.005 | 0.129 ± 0.008 | 0.123 ± 0.006
Relative | 5.865 ± 0.142 | 5.969 ± 0.204 | 5.480 ± 0.252 | 5.847 ± 0.251 | 5.815 ± 0.204 | 5.784 ± 0.148
R. Kidney
Absolute | 0.172 ± 0.006 | 0.171 ± 0.004 | 0.176 ± 0.004 | 0.175 ± 0.006 | 0.188 ± 0.006 | 0.189 ± 0.005
Relative | 8.239 ± 0.176 | 8.110 ± 0.257 | 8.064 ± 0.135 | 9.046 ± 0.390 | 8.528 ± 0.251 | 8.901 ± 0.137
Liver
Absolute | 1.268 ± 0.060 | 1.227 ± 0.019 | 1.339 ± 0.050 | 1.180 ± 0.106 | 1.386 ± 0.053 | 1.404 ± 0.155
Relative | 60.5 ± 1.7 | 58.0 ± 0.5 | 61.3 ± 1.7 | 60.0 ± 2.4 | 62.6 ± 1.2 | 65.8 ± 6.0
Lung
Absolute | 0.188 ± 0.006 | 0.164 ± 0.007 | 0.165 ± 0.005 | 0.170 ± 0.017 | 0.210 ± 0.023_b_ | 0.177 ± 0.007
Relative | 9.010 ± 0.193 | 7.782 ± 0.411 | 7.544 ± 0.273 | 8.713 ± 0.720 | 9.460 ± 0.733^b^ | 8.362 ± 0.411
Thymus
Absolute | 0.076 ± 0.002 | 0.077 ± 0.005 | 0.066 ± 0.014 | 0.059 ± 0.006 | 0.058 ± 0.008 | 0.053 ± 0.002^*^
Relative | 3.670 ± 0.180 | 3.674 ± 0.293 | 2.975 ± 0.614 | 3.004 ± 0.289 | 2.621 ± 0.330^*^ | 2.506 ± 0.038^*^

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

b n=4

TABLE F4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for B6C3F_1_ Mice in the 3-Month Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 33.8 ± 0.5 | 36.2 ± 0.8 | 35.1 ± 0.8 | 33.7 ± 1.1 | 32.8 ± 0.4 | 33.3 ± 0.5
Heart
Absolute | 0.167 ± 0.003 | 0.177 ± 0.006 | 0.182 ± 0.007 | 0.174 ± 0.007 | 0.179 ± 0.008 | 0.173 ± 0.003
Relative | 4.933 ± 0.104 | 4.881 ± 0.129 | 5.170 ± 0.135 | 5.163 ± 0.117 | 5.461 ± 0.221^*^ | 5.206 ± 0.095
R. Kidney
Absolute | 0.323 ± 0.007 | 0.355 ± 0.010 | 0.353 ± 0.013 | 0.328 ± 0.010 | 0.324 ± 0.009 | 0.324 ± 0.010
Relative | 9.556 ± 0.209 | 9.841 ± 0.291 | 10.062 ± 0.272 | 9.779 ± 0.268 | 9.885 ± 0.208 | 9.702 ± 0.205
Liver
Absolute | 1.692 ± 0.036 | 1.818 ± 0.048 | 1.745 ± 0.046 | 1.680 ± 0.055 | 1.677 ± 0.049 | 1.640 ± 0.044
Relative | 50.1 ± 1.0 | 50.3 ± 1.0 | 49.7 ± 0.7 | 50.0 ± 0.8 | 51.1 ± 1.1 | 49.2 ± 1.0
Lung
Absolute | 0.283 ± 0.015 | 0.265 ± 0.015 | 0.276 ± 0.014 | 0.277 ± 0.016 | 0.242 ± 0.008 | 0.251 ± 0.014
Relative | 8.419 ± 0.516 | 7.363 ± 0.487 | 7.911 ± 0.447 | 8.331 ± 0.618 | 7.387 ± 0.244 | 7.502 ± 0.336
R. Testis
Absolute | 0.113 ± 0.003 | 0.121 ± 0.003 | 0.115 ± 0.006 | 0.116 ± 0.003 | 0.110 ± 0.005 | 0.119 ± 0.002
Relative | 3.329 ± 0.088 | 3.357 ± 0.089 | 3.282 ± 0.158 | 3.454 ± 0.075 | 3.356 ± 0.132 | 3.571 ± 0.069
Thymus
Absolute | 0.049 ± 0.003 | 0.051 ± 0.004 | 0.047 ± 0.003 | 0.047 ± 0.002 | 0.044 ± 0.001 | 0.048 ± 0.002
Relative | 1.441 ± 0.086 | 1.426 ± 0.111 | 1.361 ± 0.099 | 1.377 ± 0.044 | 1.341 ± 0.041 | 1.440 ± 0.060
Female
n | 9 | 10 | 9 | 10 | 10 | 10
Necropsy body wt | 31.6 ± 0.8 | 31.6 ± 1.2 | 31.5 ± 0.9 | 31.3 ± 0.8 | 30.0 ± 1.0 | 29.0 ± 0.4
Heart
Absolute | 0.153 ± 0.011 | 0.166 ± 0.010 | 0.147 ± 0.003 | 0.185 ± 0.009^*^ | 0.155 ± 0.003 | 0.161 ± 0.003
Relative | 4.864 ± 0.341 | 5.267 ± 0.258 | 4.691 ± 0.115 | 5.955 ± 0.362 | 5.205 ± 0.135 | 5.542 ± 0.093
R. Kidney
Absolute | 0.216 ± 0.004 | 0.222 ± 0.005 | 0.214 ± 0.006 | 0.211 ± 0.005 | 0.223 ± 0.004 | 0.228 ± 0.004
Relative | 6.868 ± 0.197 | 7.051 ± 0.136 | 6.798 ± 0.139 | 6.754 ± 0.133 | 7.477 ± 0.189^*^ | 7.862 ± 0.139^**^
Liver
Absolute | 1.556 ± 0.031 | 1.593 ± 0.056 | 1.547 ± 0.049 | 1.591 ± 0.030 | 1.525 ± 0.051 | 1.526 ± 0.038
Relative | 49.4 ± 0.9 | 50.5 ± 0.9 | 49.1 ± 1.1 | 51.0 ± 1.2 | 50.8 ± 0.8 | 52.6 ± 0.8
Lung
Absolute | 0.326 ± 0.014 | 0.349 ± 0.018 | 0.341 ± 0.020 | 0.303 ± 0.017 | 0.313 ± 0.014_b_ | 0.280 ± 0.010
Relative | 10.399 ± 0.513 | 11.092 ± 0.544 | 10.746 ± 0.380 | 9.806 ± 0.720 | 10.427 ± 0.558^b^ | 9.690 ± 0.379
Thymus
Absolute | 0.060 ± 0.003 | 0.059 ± 0.005 | 0.056 ± 0.002 | 0.052 ± 0.002 | 0.055 ± 0.003 | 0.053 ± 0.002
Relative | 1.921 ± 0.098 | 1.849 ± 0.139 | 1.794 ± 0.077 | 1.662 ± 0.048 | 1.816 ± 0.072 | 1.836 ± 0.092

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

b n=9

TABLE F5 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Male
n | 12 | 14 | 15 | 15 | 12 | 10
Necropsy body wt | 35.5 ± 1.3 | 31.8 ± 0.7 | 32.3 ± 1.6 | 33.8 ± 0.7 | 31.0 ± 0.4^*^ | 33.5 ± 0.7
Heart
Absolute | 0.218 ± 0.011 | 0.212 ± 0.006 | 0.218 ± 0.008 | 0.232 ± 0.006 | 0.249 ± 0.014 | 0.264 ± 0.020^**^
Relative | 6.208 ± 0.320 | 6.694 ± 0.188 | 6.935 ± 0.367 | 6.911 ± 0.229 | 8.032 ± 0.448^**^ | 7.887 ± 0.544^**^
R. Kidney
Absolute | 0.318 ± 0.011 | 0.302 ± 0.014 | 0.285 ± 0.012 | 0.304 ± 0.008 | 0.307 ± 0.009 | 0.309 ± 0.008
Relative | 9.055 ± 0.361 | 9.482 ± 0.370 | 8.926 ± 0.275 | 9.061 ± 0.287 | 9.910 ± 0.300 | 9.277 ± 0.283
Liver
Absolute | 1.788 ± 0.075 | 1.663 ± 0.048 | 1.657 ± 0.093 | 1.811 ± 0.035 | 1.893 ± 0.036 | 2.071 ± 0.143^*^
Relative | 51.2 ± 2.7 | 52.3 ± 1.1 | 51.0 ± 1.1 | 53.8 ± 0.9 | 61.0 ± 1.3^**^ | 61.6 ± 3.2^**^
Lung
Absolute | 0.333 ± 0.024 | 0.340 ± 0.013 | 0.308 ± 0.013_b_ | 0.342 ± 0.013 | 0.238 ± 0.010^**^ | 0.277 ± 0.020^**^
Relative | 9.510 ± 0.673 | 10.679 ± 0.316 | 9.847 ± 0.470^b^ | 10.162 ± 0.363 | 7.685 ± 0.331^*^ | 8.273 ± 0.604^*^
R. Testis
Absolute | 0.085 ± 0.004 | 0.088 ± 0.002 | 0.089 ± 0.003 | 0.087 ± 0.003 | 0.077 ± 0.003 | 0.083 ± 0.004
Relative | 2.411 ± 0.146 | 2.760 ± 0.059 | 2.834 ± 0.143 | 2.596 ± 0.103 | 2.471 ± 0.103 | 2.490 ± 0.140
Thymus
Absolute | 0.028 ± 0.003 | 0.031 ± 0.003 | 0.026 ± 0.003 | 0.027 ± 0.002 | 0.018 ± 0.002 | 0.025 ± 0.003
Relative | 0.794 ± 0.076 | 0.956 ± 0.076 | 0.782 ± 0.072 | 0.785 ± 0.050 | 0.584 ± 0.055 | 0.750 ± 0.076
Female
n | 12 | 14 | 12 | 12 | 13 | 9
Necropsy body wt | 29.0 ± 0.9 | 27.9 ± 0.6 | 26.4 ± 1.0 | 25.8 ± 0.7^*^ | 26.6 ± 0.8 | 26.0 ± 1.1
Heart
Absolute | 0.206 ± 0.006 | 0.187 ± 0.005 | 0.176 ± 0.008 | 0.188 ± 0.007 | 0.204 ± 0.011 | 0.213 ± 0.013
Relative | 7.156 ± 0.233 | 6.736 ± 0.190 | 6.709 ± 0.241 | 7.296 ± 0.230 | 7.697 ± 0.352 | 8.324 ± 0.642
R. Kidney
Absolute | 0.212 ± 0.006 | 0.209 ± 0.004 | 0.196 ± 0.006 | 0.204 ± 0.004 | 0.226 ± 0.008 | 0.229 ± 0.010
Relative | 7.360 ± 0.219 | 7.507 ± 0.160 | 7.478 ± 0.197 | 7.921 ± 0.144 | 8.517 ± 0.235^**^ | 8.854 ± 0.358^**^
Liver
Absolute | 1.615 ± 0.054 | 1.496 ± 0.033 | 1.404 ± 0.070 | 1.415 ± 0.047 | 1.624 ± 0.060 | 1.560 ± 0.098
Relative | 55.8 ± 1.0 | 53.7 ± 1.0 | 52.9 ± 1.0 | 54.9 ± 1.2 | 60.9 ± 1.2^*^ | 59.7 ± 2.2^*^
Lung
Absolute | 0.328 ± 0.009 | 0.314 ± 0.012 | 0.305 ± 0.011 | 0.294 ± 0.014 | 0.250 ± 0.012^**^ | 0.228 ± 0.014^**^
Relative | 11.356 ± 0.250 | 11.236 ± 0.398 | 11.641 ± 0.388 | 11.427 ± 0.570 | 9.424 ± 0.415^**^ | 8.828 ± 0.525^**^
Thymus
Absolute | 0.032 ± 0.002 | 0.036 ± 0.002 | 0.030 ± 0.003 | 0.029 ± 0.003 | 0.023 ± 0.002^**^ | 0.022 ± 0.003^**^
Relative | 1.091 ± 0.056 | 1.273 ± 0.051 | 1.137 ± 0.078 | 1.109 ± 0.086 | 0.852 ± 0.057^*^ | 0.844 ± 0.096^*^

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

b n=14