# APPENDIX E CLINICAL PATHOLOGY RESULTS

TABLE E1 Hematology and Clinical Chemistry Data for Rats in the 3-Month Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Male
Hematology
n
Day 4 | 10 | 7 | 10 | 9 | 9 | 9
Day 23 | 8 | 9 | 10 | 9 | 10 | 8
Week 14 | 8 | 8 | 7 | 7 | 9 | 8
Hematocrit (%)
Day 4 | 41.1 ± 0.4 | 42.5 ± 0.5 | 41.8 ± 0.4 | 41.2 ± 0.2 | 41.9 ± 0.4 | 41.8 ± 0.5
Day 23 | 42.5 ± 0.3 | 43.4 ± 0.7 | 42.9 ± 0.3 | 43.1 ± 0.3 | 43.8 ± 0.6 | 43.8 ± 0.6
Week 14 | 44.5 ± 0.4 | 44.9 ± 0.4 | 44.7 ± 0.3 | 44.8 ± 0.3 | 45.5 ± 0.4 | 46.2 ± 0.7
Hemoglobin (g/dL)
Day 4 | 12.9 ± 0.1 | 13.3 ± 0.1 | 13.0 ± 0.1 | 12.9 ± 0.1 | 13.1 ± 0.1 | 13.0 ± 0.2
Day 23 | 13.8 ± 0.1 | 14.2 ± 0.2 | 13.9 ± 0.1 | 14.1 ± 0.1 | 14.1 ± 0.2 | 14.2 ± 0.1
Week 14 | 15.1 ± 0.1 | 15.2 ± 0.1 | 15.1 ± 0.1 | 15.2 ± 0.1 | 15.5 ± 0.1^*^ | 15.7 ± 0.2^*^
Erythrocytes (10^6^/μL)
Day 4 | 6.50 ± 0.08 | 6.77 ± 0.09 | 6.70 ± 0.07 | 6.60 ± 0.04 | 6.69 ± 0.08 | 6.68 ± 0.09
Day 23 | 7.41 ± 0.05 | 7.61 ± 0.12 | 7.53 ± 0.05 | 7.55 ± 0.06 | 7.67 ± 0.13 | 7.69 ± 0.10
Week 14 | 8.67 ± 0.07 | 8.79 ± 0.06 | 8.81 ± 0.05 | 8.73 ± 0.06 | 8.92 ± 0.06^**^ | 9.03 ± 0.14^*^
Reticulocytes (10^6^/μL)
Day 4 | 0.34 ± 0.02 | 0.38 ± 0.04 | 0.37 ± 0.04 | 0.39 ± 0.04 | 0.37 ± 0.03 | 0.35 ± 0.03
Day 23 | 0.16 ± 0.02 | 0.15 ± 0.01 | 0.14 ± 0.01 | 0.16 ± 0.02 | 0.16 ± 0.01 | 0.17 ± 0.01
Week 14 | 0.10 ± 0.01 | 0.12 ± 0.02 | 0.10 ± 0.01 | 0.11 ± 0.01 | 0.11 ± 0.01 | 0.11 ± 0.01
Nucleated erythrocytes (10^3^/μL)
Day 4 | 0.03 ± 0.03 | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.00 ± 0.00
Day 23 | 0.02 ± 0.02 | 0.03 ± 0.03 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.01 ± 0.01
Mean cell volume (fL)
Day 4 | 63.3 ± 0.3 | 62.8 ± 0.3 | 62.3 ± 0.5 | 62.5 ± 0.3 | 62.7 ± 0.3 | 62.6 ± 0.3
Day 23 | 57.3 ± 0.2 | 57.1 ± 0.1 | 57.0 ± 0.2 | 57.1 ± 0.1 | 57.1 ± 0.2 | 56.9 ± 0.3
Week 14 | 51.4 ± 0.1 | 51.1 ± 0.1 | 50.7 ± 0.2 | 51.4 ± 0.4 | 51.0 ± 0.2 | 51.2 ± 0.2
Mean cell hemoglobin (pg)
Day 4 | 19.8 ± 0.2 | 19.7 ± 0.2 | 19.5 ± 0.1 | 19.6 ± 0.2 | 19.6 ± 0.1 | 19.5 ± 0.1
Day 23 | 18.7 ± 0.1 | 18.7 ± 0.1 | 18.5 ± 0.1 | 18.6 ± 0.1 | 18.5 ± 0.1 | 18.5 ± 0.1
Week 14 | 17.4 ± 0.1 | 17.3 ± 0.1 | 17.1 ± 0.0 | 17.4 ± 0.1 | 17.3 ± 0.1 | 17.4 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 4 | 31.3 ± 0.2 | 31.4 ± 0.2 | 31.2 ± 0.1 | 31.3 ± 0.2 | 31.3 ± 0.1 | 31.2 ± 0.1
Day 23 | 32.6 ± 0.2 | 32.8 ± 0.2 | 32.5 ± 0.1 | 32.6 ± 0.1 | 32.3 ± 0.2 | 32.5 ± 0.2
Week 14 | 33.8 ± 0.2 | 33.9 ± 0.1 | 33.8 ± 0.1 | 33.9 ± 0.2 | 34.0 ± 0.1 | 33.9 ± 0.1
Platelets (10^3^/μL)
Day 4 | 962.8 ± 21.9 | 876.7 ± 17.0 | 967.1 ± 22.7 | 955.9 ± 27.6 | 927.2 ± 20.0 | 984.0 ± 20.3
Day 23 | 826.3 ± 10.2 | 773.3 ± 10.7^*^ | 757.7 ± 26.1 | 802.3 ± 18.1 | 790.7 ± 12.3 | 785.0 ± 14.6
Week 14 | 734.1 ± 18.7 | 647.5 ± 20.2^*^ | 694.6 ± 40.3 | 662.0 ± 24.3 | 639.9 ± 24.5^*^ | 693.8 ± 9.7
Leukocytes (10^3^/μL)
Day 4 | 7.41 ± 0.32 | 7.33 ± 0.33 | 7.49 ± 0.34 | 7.14 ± 0.22 | 7.34 ± 0.44 | 7.08 ± 0.50
Day 23 | 11.93 ± 0.29^b^ | 11.97 ± 0.47 | 11.28 ± 0.49 | 11.97 ± 0.61 | 11.34 ± 0.45 | 12.13 ± 0.59
Week 14 | 9.80 ± 0.58 | 9.98 ± 0.81 | 11.36 ± 0.51 | 9.59 ± 0.44 | 11.11 ± 0.54 | 10.74 ± 0.78
Segmented neutrophils (10^3^/μL)
Day 4 | 1.22 ± 0.12 | 1.00 ± 0.12 | 1.25 ± 0.11 | 1.20 ± 0.09 | 1.21 ± 0.11 | 1.51 ± 0.15
Day 23 | 1.01 ± 0.06^b^ | 1.02 ± 0.11 | 1.02 ± 0.07 | 1.00 ± 0.10 | 1.28 ± 0.09 | 2.07 ± 0.20^**^
Week 14 | 1.67 ± 0.26 | 2.12 ± 0.34 | 2.39 ± 0.29 | 1.51 ± 0.17 | 2.66 ± 0.25^*^ | 2.52 ± 0.27
Bands (10^3^/μL)
Day 4 | 0.01 ± 0.01 | 0.02 ± 0.01 | 0.01 ± 0.01 | 0.02 ± 0.01 | 0.00 ± 0.00 | 0.01 ± 0.01
Day 23 | 0.00 ± 0.00^b^ | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL)
Day 4 | 6.09 ± 0.30 | 6.10 ± 0.36 | 6.03 ± 0.27 | 5.70 ± 0.28 | 5.89 ± 0.38 | 5.35 ± 0.45
Day 23 | 10.73 ± 0.25^b^ | 10.84 ± 0.44 | 10.08 ± 0.44 | 10.82 ± 0.54 | 9.92 ± 0.46 | 9.90 ± 0.54
Week 14 | 7.88 ± 0.38 | 7.57 ± 0.47 | 8.71 ± 0.47 | 7.86 ± 0.42 | 8.18 ± 0.48 | 7.89 ± 0.61
Monocytes (10^3^/μL)
Day 4 | 0.10 ± 0.01 | 0.21 ± 0.04 | 0.19 ± 0.05 | 0.20 ± 0.04 | 0.19 ± 0.03 | 0.20 ± 0.05
Day 23 | 0.09 ± 0.03^b^ | 0.09 ± 0.03 | 0.09 ± 0.03 | 0.13 ± 0.03 | 0.04 ± 0.02 | 0.11 ± 0.03
Week 14 | 0.18 ± 0.03 | 0.21 ± 0.01 | 0.18 ± 0.03 | 0.15 ± 0.04 | 0.22 ± 0.05 | 0.23 ± 0.04
Basophils (10^3^/μL)
Day 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Day 23 | 0.000 ± 0.000^b^ | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 14 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL)
Day 4 | 0.00 ± 0.00 | 0.01 ± 0.01 | 0.01 ± 0.01 | 0.04 ± 0.02 | 0.05 ± 0.02^*^ | 0.01 ± 0.01
Day 23 | 0.10 ± 0.03^b^ | 0.03 ± 0.02 | 0.08 ± 0.02 | 0.03 ± 0.02 | 0.09 ± 0.03 | 0.03 ± 0.02
Week 14 | 0.06 ± 0.03 | 0.08 ± 0.04 | 0.08 ± 0.03 | 0.06 ± 0.02 | 0.05 ± 0.02 | 0.10 ± 0.02
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 10.0 ± 0.4 | 10.8 ± 0.6 | 10.9 ± 0.5 | 9.3 ± 0.4 | 9.7 ± 0.5 | 9.5 ± 0.3
Day 23 | 11.6 ± 0.3 | 12.4 ± 0.6 | 10.8 ± 0.4 | 11.0 ± 0.4 | 11.5 ± 0.3 | 11.3 ± 0.3
Week 14 | 16.8 ± 0.5 | 16.8 ± 0.7 | 18.2 ± 0.4 | 16.7 ± 0.4 | 16.1 ± 0.5 | 17.5 ± 1.8
Creatinine (mg/dL)
Day 4 | 0.45 ± 0.03 | 0.44 ± 0.02 | 0.36 ± 0.04 | 0.48 ± 0.05 | 0.44 ± 0.02 | 0.47 ± 0.06
Day 23 | 0.43 ± 0.02 | 0.43 ± 0.02 | 0.42 ± 0.01 | 0.43 ± 0.02 | 0.42 ± 0.01 | 0.43 ± 0.02
Week 14 | 0.56 ± 0.02 | 0.59 ± 0.01 | 0.58 ± 0.01 | 0.58 ± 0.01 | 0.58 ± 0.01 | 0.56 ± 0.02
Total protein (g/dL)
Day 4 | 5.4 ± 0.1 | 5.6 ± 0.1 | 5.5 ± 0.1 | 5.5 ± 0.1 | 5.5 ± 0.1 | 5.4 ± 0.1
Day 23 | 5.7 ± 0.1 | 5.7 ± 0.0 | 5.6 ± 0.1 | 5.7 ± 0.1 | 5.7 ± 0.1 | 5.8 ± 0.1
Week 14 | 6.9 ± 0.1 | 6.9 ± 0.1 | 6.9 ± 0.0 | 6.8 ± 0.1 | 6.9 ± 0.1 | 6.8 ± 0.1
Albumin (g/dL)
Day 4 | 4.0 ± 0.0 | 4.2 ± 0.1 | 4.1 ± 0.0 | 4.1 ± 0.0 | 4.2 ± 0.0^*^ | 4.1 ± 0.1
Day 23 | 4.1 ± 0.1 | 4.2 ± 0.0 | 4.1 ± 0.0 | 4.2 ± 0.1 | 4.2 ± 0.1 | 4.3 ± 0.0
Week 14 | 4.6 ± 0.1 | 4.6 ± 0.1 | 4.6 ± 0.1 | 4.6 ± 0.0 | 4.6 ± 0.1 | 4.7 ± 0.1
Alanine aminotransferase (IU/L)
Day 4 | 98 ± 3 | 92 ± 5 | 96 ± 3 | 100 ± 4 | 99 ± 3 | 88 ± 4
Day 23 | 71 ± 3 | 72 ± 2 | 65 ± 2 | 66 ± 2 | 70 ± 1 | 71 ± 2
Week 14 | 92 ± 5 | 114 ± 16 | 99 ± 5 | 90 ± 3 | 93 ± 3 | 104 ± 5
Alkaline phosphatase (IU/L)
Day 4 | 827 ± 20 | 878 ± 25 | 833 ± 13 | 827 ± 28 | 881 ± 36 | 822 ± 23
Day 23 | 518 ± 14 | 523 ± 8 | 502 ± 10 | 508 ± 10 | 506 ± 13 | 526 ± 10
Week 14 | 294 ± 6 | 302 ± 6 | 316 ± 5 | 306 ± 7 | 289 ± 7 | 323 ± 6^*^
Creatine kinase (IU/L)
Day 4 | 403 ± 72 | 440 ± 69 | 436 ± 99 | 412 ± 84 | 296 ± 47 | 642 ± 106
Day 23 | 398 ± 139 | 338 ± 44 | 241 ± 45 | 192 ± 27 | 205 ± 24 | 287 ± 52
Week 14 | 177 ± 28 | 175 ± 18 | 242 ± 64 | 242 ± 44 | 201 ± 23 | 166 ± 25^c^
Sorbitol dehydrogenase (IU/L)
Day 4 | 17 ± 1 | 17 ± 1 | 18 ± 1 | 18 ± 1 | 18 ± 1 | 17 ± 1
Day 23 | 17 ± 1 | 18 ± 1 | 16 ± 1 | 16 ± 1 | 16 ± 1 | 15 ± 1
Week 14 | 29 ± 1 | 43 ± 9 | 29 ± 2 | 27 ± 2 | 25 ± 2 | 29 ± 3
Bile acids (μmol/L)
Day 4 | 23.1 ± 2.6 | 19.5 ± 0.7 | 20.5 ± 1.4 | 27.1 ± 4.1 | 25.7 ± 2.7 | 27.5 ± 3.4
Day 23 | 30.7 ± 3.5 | 32.5 ± 3.2 | 30.4 ± 2.8 | 28.4 ± 2.2 | 29.6 ± 3.2 | 31.9 ± 3.0
Week 14 | 26.2 ± 2.5 | 23.2 ± 4.5 | 23.5 ± 2.7 | 22.0 ± 1.9 | 27.8 ± 4.2 | 26.5 ± 3.1
Female
Hematology
n
Day 4 | 9 | 10 | 10 | 8 | 9 | 8
Day 23 | 9 | 10 | 9 | 9 | 10 | 10
Week 14 | 8 | 9 | 8 | 6 | 8 | 9
Hematocrit (%)
Day 4 | 42.9 ± 0.4 | 43.2 ± 0.5 | 43.0 ± 0.5 | 42.8 ± 0.5 | 42.3 ± 0.3 | 42.1 ± 0.6
Day 23 | 46.0 ± 0.5 | 46.5 ± 0.4 | 47.1 ± 0.7 | 46.4 ± 0.4 | 46.1 ± 0.4 | 46.4 ± 0.5
Week 14 | 43.9 ± 0.5 | 44.9 ± 0.6 | 45.2 ± 0.5 | 44.4 ± 0.4 | 43.8 ± 0.4 | 44.6 ± 0.3
Hemoglobin (g/dL)
Day 4 | 13.9 ± 0.1 | 14.1 ± 0.1 | 14.1 ± 0.2 | 14.0 ± 0.1 | 13.9 ± 0.1 | 13.9 ± 0.2
Day 23 | 14.8 ± 0.2 | 15.1 ± 0.1 | 15.3 ± 0.2 | 15.0 ± 0.1 | 14.9 ± 0.1 | 15.0 ± 0.2
Week 14 | 14.9 ± 0.1 | 15.1 ± 0.1 | 15.3 ± 0.2^*^ | 15.3 ± 0.1 | 15.0 ± 0.1 | 15.2 ± 0.1
Erythrocytes (10^6^/μL)
Day 4 | 7.25 ± 0.07 | 7.29 ± 0.10 | 7.27 ± 0.10 | 7.24 ± 0.08 | 7.17 ± 0.04 | 7.19 ± 0.11
Day 23 | 7.96 ± 0.10 | 8.09 ± 0.08 | 8.19 ± 0.13 | 8.03 ± 0.07 | 7.98 ± 0.08 | 8.07 ± 0.11
Week 14 | 8.04 ± 0.07 | 8.21 ± 0.08 | 8.31 ± 0.09 | 8.22 ± 0.11 | 8.13 ± 0.07 | 8.21 ± 0.08
Reticulocytes (10^6^/μL)
Day 4 | 0.16 ± 0.03 | 0.23 ± 0.03 | 0.19 ± 0.03 | 0.21 ± 0.03 | 0.20 ± 0.02 | 0.18 ± 0.03
Day 23 | 0.10 ± 0.01 | 0.09 ± 0.01 | 0.09 ± 0.01 | 0.10 ± 0.01 | 0.09 ± 0.01 | 0.10 ± 0.01
Week 14 | 0.11 ± 0.01 | 0.09 ± 0.01 | 0.11 ± 0.02 | 0.11 ± 0.01 | 0.10 ± 0.01 | 0.12 ± 0.02
Nucleated erythrocytes (10^3^/μL)
Day 4 | 0.00 ± 0.00 | 0.01 ± 0.01 | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Day 23 | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.03 ± 0.02 | 0.03 ± 0.02 | 0.03 ± 0.02 | 0.00 ± 0.00 | 0.04 ± 0.04 | 0.04 ± 0.02
Mean cell volume (fL)
Day 4 | 59.1 ± 0.2 | 59.2 ± 0.2 | 59.2 ± 0.2 | 59.0 ± 0.1 | 59.0 ± 0.2 | 58.6 ± 0.4
Day 23 | 57.8 ± 0.2 | 57.5 ± 0.1 | 57.6 ± 0.2 | 57.8 ± 0.1 | 57.7 ± 0.1 | 57.6 ± 0.2
Week 14 | 54.6 ± 0.2 | 54.7 ± 0.3 | 54.4 ± 0.1 | 54.0 ± 0.4 | 53.9 ± 0.3 | 54.3 ± 0.2
Mean cell hemoglobin (pg)
Day 4 | 19.2 ± 0.1 | 19.4 ± 0.1 | 19.3 ± 0.1 | 19.3 ± 0.1 | 19.3 ± 0.1 | 19.3 ± 0.1
Day 23 | 18.6 ± 0.1 | 18.7 ± 0.1 | 18.6 ± 0.1 | 18.7 ± 0.0 | 18.6 ± 0.1 | 18.6 ± 0.1
Week 14 | 18.6 ± 0.1 | 18.4 ± 0.1 | 18.5 ± 0.1 | 18.6 ± 0.1 | 18.5 ± 0.1 | 18.5 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 4 | 32.5 ± 0.2 | 32.7 ± 0.2 | 32.7 ± 0.1 | 32.7 ± 0.1 | 32.8 ± 0.1 | 33.0 ± 0.2
Day 23 | 32.3 ± 0.2 | 32.6 ± 0.1 | 32.4 ± 0.1 | 32.3 ± 0.1 | 32.3 ± 0.1 | 32.4 ± 0.2
Week 14 | 34.0 ± 0.3 | 33.6 ± 0.2 | 34.0 ± 0.2 | 34.4 ± 0.2 | 34.3 ± 0.2 | 34.1 ± 0.1
Platelets (10^3^/μL)
Day 4 | 815.2 ± 21.9 | 791.6 ± 33.8 | 783.3 ± 35.3 | 802.6 ± 38.4 | 838.4 ± 22.0 | 808.5 ± 51.4
Day 23 | 732.1 ± 29.5 | 639.3 ± 42.4 | 689.0 ± 31.9 | 737.6 ± 6.9 | 701.2 ± 27.4 | 704.0 ± 22.4
Week 14 | 619.9 ± 31.2 | 588.6 ± 22.8 | 638.6 ± 44.5 | 582.5 ± 38.4 | 653.6 ± 26.4 | 644.3 ± 30.2
Leukocytes (10^3^/μL)
Day 4 | 9.50 ± 0.38 | 10.05 ± 0.34 | 9.39 ± 0.18 | 9.23 ± 0.32 | 8.99 ± 0.41 | 9.16 ± 0.43
Day 23 | 11.70 ± 0.57 | 12.01 ± 0.63 | 12.63 ± 0.34 | 11.48 ± 0.51 | 11.52 ± 0.60 | 13.13 ± 0.50
Week 14 | 10.89 ± 0.75 | 10.51 ± 0.56 | 11.74 ± 0.94 | 10.83 ± 0.54 | 9.19 ± 0.71 | 11.19 ± 0.75
Segmented neutrophils (10^3^/μL)
Day 4 | 1.26 ± 0.14 | 1.21 ± 0.11 | 1.12 ± 0.09 | 1.16 ± 0.13 | 1.15 ± 0.14 | 1.59 ± 0.09
Day 23 | 1.03 ± 0.13 | 1.23 ± 0.12 | 1.13 ± 0.09 | 1.07 ± 0.10 | 0.99 ± 0.12 | 2.01 ± 0.14^**^
Week 14 | 1.84 ± 0.32 | 1.75 ± 0.22 | 1.88 ± 0.25 | 1.67 ± 0.18 | 2.06 ± 0.34 | 2.22 ± 0.29
Bands (10^3^/μL)
Day 4 | 0.03 ± 0.02 | 0.03 ± 0.03 | 0.06 ± 0.03 | 0.01 ± 0.01 | 0.02 ± 0.01 | 0.01 ± 0.01
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL)
Day 4 | 7.79 ± 0.35 | 8.56 ± 0.24 | 7.87 ± 0.17 | 7.75 ± 0.28 | 7.43 ± 0.35 | 7.22 ± 0.37
Day 23 | 10.34 ± 0.58 | 10.53 ± 0.56 | 11.34 ± 0.37 | 10.17 ± 0.53 | 10.23 ± 0.52 | 10.80 ± 0.45
Week 14 | 8.56 ± 0.46 | 8.39 ± 0.52 | 9.21 ± 0.83 | 8.80 ± 0.50 | 6.78 ± 0.51 | 8.42 ± 0.58
Monocytes (10^3^/μL)
Day 4 | 0.39 ± 0.07 | 0.23 ± 0.06 | 0.31 ± 0.03 | 0.27 ± 0.07 | 0.37 ± 0.07 | 0.28 ± 0.05
Day 23 | 0.18 ± 0.02 | 0.12 ± 0.03 | 0.10 ± 0.02 | 0.15 ± 0.03 | 0.21 ± 0.03 | 0.17 ± 0.04
Week 14 | 0.37 ± 0.08 | 0.30 ± 0.09 | 0.49 ± 0.09 | 0.28 ± 0.11 | 0.25 ± 0.04 | 0.43 ± 0.05
Basophils (10^3^/μL)
Day 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Day 23 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 14 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL)
Day 4 | 0.03 ± 0.02 | 0.03 ± 0.02 | 0.02 ± 0.01 | 0.02 ± 0.02 | 0.03 ± 0.02 | 0.06 ± 0.02
Day 23 | 0.15 ± 0.04 | 0.12 ± 0.04 | 0.07 ± 0.02 | 0.09 ± 0.04 | 0.09 ± 0.03 | 0.15 ± 0.04
Week 14 | 0.12 ± 0.03 | 0.07 ± 0.03 | 0.16 ± 0.05 | 0.08 ± 0.03 | 0.09 ± 0.03 | 0.13 ± 0.03
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 12.6 ± 0.6 | 12.1 ± 0.6 | 11.2 ± 0.5 | 11.4 ± 0.4 | 10.9 ± 0.4 | 11.5 ± 0.4
Day 23 | 15.7 ± 0.5 | 15.5 ± 0.4 | 14.9 ± 0.7 | 14.9 ± 0.5 | 15.3 ± 0.4 | 14.4 ± 0.4
Week 14 | 17.8 ± 0.4 | 17.9 ± 0.6 | 16.8 ± 0.6 | 16.8 ± 0.6 | 16.3 ± 0.6 | 17.0 ± 0.6
Creatinine (mg/dL)
Day 4 | 0.40 ± 0.02 | 0.40 ± 0.00 | 0.41 ± 0.01 | 0.40 ± 0.00 | 0.41 ± 0.01 | 0.40 ± 0.02
Day 23 | 0.40 ± 0.00 | 0.40 ± 0.00 | 0.38 ± 0.01 | 0.39 ± 0.01 | 0.40 ± 0.00 | 0.38 ± 0.01
Week 14 | 0.51 ± 0.01 | 0.50 ± 0.00 | 0.51 ± 0.01 | 0.51 ± 0.02 | 0.49 ± 0.02 | 0.51 ± 0.01
Total protein (g/dL)
Day 4 | 5.6 ± 0.0 | 5.7 ± 0.1 | 5.6 ± 0.1 | 5.7 ± 0.0 | 5.6 ± 0.0 | 5.7 ± 0.1
Day 23 | 5.6 ± 0.1 | 5.4 ± 0.1 | 5.6 ± 0.1 | 5.6 ± 0.1 | 5.5 ± 0.1 | 5.6 ± 0.1
Week 14 | 6.4 ± 0.1 | 6.6 ± 0.1 | 6.6 ± 0.1 | 6.5 ± 0.1 | 6.3 ± 0.1 | 6.4 ± 0.1
Albumin (g/dL)
Day 4 | 4.3 ± 0.0 | 4.4 ± 0.0 | 4.3 ± 0.0 | 4.4 ± 0.0 | 4.3 ± 0.0 | 4.4 ± 0.1
Day 23 | 4.2 ± 0.0 | 4.2 ± 0.0 | 4.2 ± 0.0 | 4.2 ± 0.0 | 4.2 ± 0.0 | 4.3 ± 0.0
Week 14 | 4.5 ± 0.1 | 4.6 ± 0.1 | 4.6 ± 0.1 | 4.6 ± 0.1 | 4.5 ± 0.1 | 4.5 ± 0.1
Alanine aminotransferase (IU/L)
Day 4 | 70 ± 2 | 68 ± 2 | 77 ± 2 | 76 ± 2 | 71 ± 2 | 76 ± 1
Day 23 | 63 ± 2 | 64 ± 1 | 67 ± 1 | 62 ± 2 | 65 ± 2 | 71 ± 2
Week 14 | 90 ± 3 | 101 ± 7 | 108 ± 9 | 96 ± 5 | 95 ± 5 | 92 ± 4
Alkaline phosphatase (IU/L)
Day 4 | 629 ± 10 | 626 ± 12 | 627 ± 13 | 619 ± 12 | 638 ± 15 | 625 ± 15
Day 23 | 445 ± 9 | 440 ± 9 | 462 ± 10 | 461 ± 9 | 429 ± 6 | 440 ± 5
Week 14 | 292 ± 4 | 310 ± 6 | 301 ± 8 | 306 ± 11 | 294 ± 6 | 316 ± 7
Creatine kinase (IU/L)
Day 4 | 511 ± 84 | 449 ± 68 | 361 ± 41 | 649 ± 163 | 531 ± 101 | 761 ± 11c
Day 23 | 380 ± 60 | 281 ± 29^c^ | 457 ± 94 | 221 ± 26^c^ | 278 ± 42^c^ | 250 ± 47^c^
Week 14 | 248 ± 29 | 337 ± 87 | 427 ± 70 | 275 ± 49 | 293 ± 53 | 252 ± 50
Sorbitol dehydrogenase (IU/L)
Day 4 | 19 ± 0 | 19 ± 1 | 18 ± 0 | 18 ± 0 | 18 ± 0 | 19 ± 1
Day 23 | 18 ± 1 | 19 ± 1 | 18 ± 1 | 17 ± 1 | 17 ± 1 | 15 ± 1
Week 14 | 23 ± 1 | 25 ± 2 | 27 ± 2 | 24 ± 2 | 22 ± 1 | 21 ± 1
Bile acids (μmol/L)
Day 4 | 18.5 ± 1.5 | 19.1 ± 0.9 | 21.1 ± 1.1 | 21.9 ± 1.3 | 22.6 ± 2.3 | 20.9 ± 1.7
Day 23 | 25.3 ± 3.0 | 25.2 ± 2.0 | 22.1 ± 2.8 | 25.9 ± 2.6 | 21.4 ± 1.6 | 23.4 ± 2.9
Week 14 | 30.7 ± 5.1 | 23.2 ± 1.3 | 30.7 ± 2.6 | 23.5 ± 2.2 | 28.3 ± 3.7 | 28.6 ± 3.2

* Significantly different (P≤0.05) from the vehicle control group by Dunn’s or Shirley’s test

** P≤0.01

a Data are given as mean ± standard error. Statistical tests were performed on unrounded data.

b n=7

c n=9

TABLE E2 Hematology Data for B6C3F_1_ Mice in the 3-Month Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (%) | 46.0 ± 0.4 | 45.7 ± 0.4 | 45.3 ± 0.7 | 45.1 ± 0.6 | 44.2 ± 0.3^**^ | 43.3 ± 0.3^**^
Hemoglobin (g/dL) | 16.0 ± 0.1 | 16.0 ± 0.1 | 15.8 ± 0.2 | 15.6 ± 0.1^*^ | 15.5 ± 0.1^**^ | 15.1 ± 0.1^**^
Erythrocytes (10^6^/μL) | 10.02 ± 0.09 | 9.97 ± 0.11 | 9.85 ± 0.15 | 9.82 ± 0.11 | 9.62 ± 0.08^**^ | 9.51 ± 0.09^**^
Reticulocytes (10^6^/μL) | 0.05 ± 0.01 | 0.08 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.04 ± 0.01 | 0.05 ± 0.01
Nucleated erythrocytes (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 46.0 ± 0.2 | 45.9 ± 0.1 | 46.0 ± 0.2 | 45.9 ± 0.2 | 45.9 ± 0.1 | 45.6 ± 0.2
Mean cell hemoglobin (pg) | 16.0 ± 0.1 | 16.1 ± 0.0 | 16.1 ± 0.1 | 15.8 ± 0.1 | 16.1 ± 0.1 | 15.9 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 34.8 ± 0.1 | 35.0 ± 0.1 | 35.0 ± 0.2 | 34.5 ± 0.1 | 35.0 ± 0.1 | 34.9 ± 0.1
Platelets (10^3^/μL) | 772.3 ± 35.6 | 816.3 ± 37.5 | 845.5 ± 31.9 | 842.1 ± 26.7 | 902.5 ± 28.4^**^ | 947.7 ± 30.0^**^
Leukocytes (10^3^/μL) | 3.72 ± 0.49 | 3.54 ± 0.54 | 3.08 ± 0.39 | 3.39 ± 0.33 | 4.43 ± 0.22 | 5.98 ± 1.13
Segmented neutrophils (10^3^/μL) | 0.62 ± 0.07 | 0.64 ± 0.15 | 0.50 ± 0.07 | 0.57 ± 0.07 | 1.14 ± 0.12^*^ | 3.31 ± 0.98^**^
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 2.98 ± 0.44 | 2.80 ± 0.42 | 2.49 ± 0.35 | 2.71 ± 0.27 | 3.17 ± 0.19 | 2.54 ± 0.20
Monocytes (10^3^/μL) | 0.08 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.09 ± 0.03
Basophils (10^3^/μL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL) | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.03 ± 0.01 | 0.04 ± 0.01 | 0.05 ± 0.01 | 0.05 ± 0.02
Female
n | 9 | 10 | 9 | 10 | 10 | 10
Hematocrit (%) | 46.5 ± 0.3 | 46.8 ± 0.8 | 46.5 ± 0.7 | 46.2 ± 0.3 | 44.6 ± 0.3^**^ | 44.2 ± 0.3^**^
Hemoglobin (g/dL) | 16.3 ± 0.1 | 16.3 ± 0.2 | 16.3 ± 0.2 | 16.0 ± 0.1 | 15.6 ± 0.1^**^ | 15.4 ± 0.1^**^
Erythrocytes (10^6^/μL) | 10.17 ± 0.08 | 10.07 ± 0.19 | 10.03 ± 0.18 | 9.94 ± 0.08 | 9.58 ± 0.08^**^ | 9.65 ± 0.08^**^
Reticulocytes (10^6^/μL) | 0.08 ± 0.01 | 0.07 ± 0.01 | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.05 ± 0.01
Nucleated erythrocytes (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 45.8 ± 0.1 | 46.4 ± 0.1^**^ | 46.3 ± 0.2 | 46.5 ± 0.2^**^ | 46.6 ± 0.1^**^ | 45.8 ± 0.3
Mean cell hemoglobin (pg) | 16.0 ± 0.1 | 16.1 ± 0.1 | 16.2 ± 0.1 | 16.1 ± 0.1 | 16.2 ± 0.1 | 16.0 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 35.0 ± 0.1 | 34.8 ± 0.2 | 34.9 ± 0.1 | 34.7 ± 0.2 | 34.9 ± 0.1 | 34.9 ± 0.1
Platelets (10^3^/μL) | 655.3 ± 29.4 | 652.7 ± 47.4 | 592.8 ± 38.4 | 722.9 ± 36.7 | 730.2 ± 18.0 | 798.2 ± 22.3^**^
Leukocytes (10^3^/μL) | 4.60 ± 0.29 | 4.50 ± 0.31 | 4.34 ± 0.26 | 4.57 ± 0.30 | 4.63 ± 0.42 | 6.35 ± 0.54^*^
Segmented neutrophils (10^3^/μL) | 0.57 ± 0.08 | 0.43 ± 0.05 | 0.46 ± 0.05 | 0.54 ± 0.06 | 0.63 ± 0.08 | 1.37 ± 0.32^**^
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 3.92 ± 0.21 | 3.98 ± 0.27 | 3.81 ± 0.25 | 3.94 ± 0.26 | 3.91 ± 0.36 | 4.86 ± 0.26
Monocytes (10^3^/μL) | 0.08 ± 0.02 | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.07 ± 0.02 | 0.09 ± 0.02
Basophils (10^3^/μL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL) | 0.04 ± 0.01 | 0.03 ± 0.01 | 0.02 ± 0.01 | 0.04 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.01

* Significantly different (P≤0.05) from the vehicle control group by Dunn’s or Shirley’s test

** P≤0.01

a Data are given as mean ± standard error. Statistical tests were performed on unrounded data.