# APPENDIX D SUMMARY OF NONNEOPLASTIC LESIONS IN RATS AND B6C3F_1_ MICE IN THE 3-MONTH DERMAL STUDIES OF PENTAERYTHRITOL TRIACRYLATE

TABLE D1 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the 3-Month Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal sacrifice | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (4) | (2) | (2) | (2) | (10)
Hepatodiaphragmatic nodule | 3 (30%) | 4 (100%) | 1 (50%) | 2 (100%) | 1 (50%) | 3 (30%)
Tongue | | | (1)
Cyst | | | 1 (100%)
Cardiovascular System
Heart | (10) | | | | | (10)
Cardiomyopathy | 2 (20%) | | | | | 2 (20%)
Endocrine System
None
General Body System
None
Genital System
Preputial gland | (10) | | | | | (10)
Inflammation, chronic active | 1 (10%) | | | | | 1 (10%)
Prostate | (10) | | | | | (10)
Inflammation, chronic active | 1 (10%)
Hematopoietic System
Lymph node, mesenteric | (10) | | | | | (10)
Hyperplasia | | | | | | 1 (10%)
Integumentary System
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Dermis, skin, site of application, inflammation, chronic active | | 1 (10%) | 3 (30%) | 10 (100%) | 10 (100%) | 9 (90%)
Epidermis, skin, site of application, degeneration | | 1 (10%) | 6 (60%) | 7 (70%) | 7 (70%) | 5 (50%)
Epidermis, skin, site of application, hyperplasia | 1 (10%) | 2 (20%) | 7 (70%) | 9 (90%) | 10 (100%) | 7 (70%)
Epidermis, skin, site of application, inflammation, suppurative | | | | | 6 (60%) | 3 (30%)
Epidermis, skin, site of application, necrosis | | | 1 (10%) | 1 (10%) | 5 (50%) | 2 (20%)
Sebaceous gland, skin, site of application, hyperplasia | | 2 (20%) | 9 (90%) | 9 (90%) | 10 (100%) | 9 (90%)
Skin, site of application, degeneration | | | | 1 (10%)
Skin, site of application, hyperkeratosis | 2 (20%) | 8 (80%) | 10 (100%) | 10 (100%) | 10 (100%) | 9 (90%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (10) | | | | | (10)
Inflammation, chronic active | 7 (70%) | | | | | 8 (80%)
Nose | (10) | | | | | (10)
Inflammation, acute | 1 (10%)
Special Senses System
None
Urinary System
Kidney | (10) | | | | | (10)
Nephropathy | 4 (40%) | | | | | 6 (60%)

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE D2 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the 3-Month Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal sacrifice | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (1) | (4) | (1) | (1) | (10)
Hepatodiaphragmatic nodule | | 1 (100%) | 3 (75%) | 1 (100%) | 1 (100%) | 2 (20%)
Inflammation, chronic active | 9 (90%) | | | | | 4 (40%)
Cardiovascular System
Heart | (10) | | | | | (10)
Cardiomyopathy | 2 (20%) | | | | | 1 (10%)
Endocrine System
Thyroid gland | (10) | | | | | (10)
Ultimobranchial cyst | 1 (10%) | | | | | 2 (20%)
General Body System
None
Genital System
Clitoral gland | (10) | | | | (1) | (10)
Atrophy | | | | | | 1 (10%)
Cyst | 1 (10%) | | | | 1 (100%) | 1 (10%)
Ovary | (10) | (1) | | | (1) | (10)
Cyst | | 1 (100%) | | | 1 (100%)
Uterus | (10) | | | | | (10)
Hydrometra | 1 (10%) | | | | | 5 (50%)
Hematopoietic System
Lymph node, mesenteric | (10) | | | | | (10)
Hyperplasia | | | | | | 1 (10%)
Integumentary System
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Dermis, skin, site of application, fibrosis | | | | | | 1 (10%)
Dermis, skin, site of application, inflammation, chronic active | | | 3 (30%) | 4 (40%) | 9 (90%) | 10 (100%)
Epidermis, skin, site of application, degeneration | | | 4 (40%) | 5 (50%) | 5 (50%) | 6 (60%)
Epidermis, skin, site of application, hyperplasia | | | 3 (30%) | 8 (80%) | 8 (80%) | 9 (90%)
Epidermis, skin, site of application, inflammation, suppurative | | | | | 4 (40%)
Epidermis, skin, site of application, necrosis | | | | | 3 (30%)
Sebaceous gland, skin, site of application, hyperplasia | | | 8 (80%) | 8 (80%) | 10 (100%) | 9 (90%)
Skin, site of application, hyperkeratosis | | 4 (40%) | 8 (80%) | 9 (90%) | 10 (100%) | 10 (100%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (10) | | | | | (10)
Inflammation, chronic active | 4 (40%) | | | | | 7 (70%)
Special Senses System
None
Urinary System
None

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE D3 Summary of the Incidence of Nonneoplastic Lesions in Male B6C3F_1_ Mice in the 3-Month Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal sacrifice | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | | | | | (10)
Inflammation, chronic active | | | | | | 1 (10%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (10) | | | | | (10)
Subcapsular, hyperplasia | 1 (10%)
General Body System
None
Genital System
None
Hematopoietic System
None
Integumentary System
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Hyperkeratosis | | | | | 1 (10%)
Dermis, skin, site of application, fibrosis | | | | | 6 (60%) | 10 (100%)
Dermis, skin, site of application, inflammation, chronic active | | | 8 (80%) | 8 (80%) | 10 (100%) | 10 (100%)
Epidermis, hyperplasia | | | | | 1 (10%)
Epidermis, inflammation, suppurative | | | | | 1 (10%)
Epidermis, skin, site of application, degeneration | | | 5 (50%) | 5 (50%) | 2 (20%) | 4 (40%)
Epidermis, skin, site of application, hyperplasia | | | 3 (30%) | 8 (80%) | 9 (90%) | 10 (100%)
Epidermis, skin, site of application, inflammation, suppurative | | | | 2 (20%)
Epidermis, skin, site of application, necrosis | | | 2 (20%) | 3 (30%) | 7 (70%) | 7 (70%)
Sebaceous gland, skin, site of application, hyperplasia | | | 7 (70%) | 9 (90%) | 10 (100%) | 10 (100%)
Skin, site of application, hyperkeratosis | | | 5 (50%) | 7 (70%) | 8 (80%) | 6 (60%)
Skin, site of application, necrosis | | | | | 1 (10%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
None
Special Senses System
None
Urinary System
Kidney | (10) | | | | | (10)
Nephropathy | 1 (10%)
Urinary bladder | (10) | | | | | (10)
Edema | | | | | | 1 (10%)

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE D4 Summary of the Incidence of Nonneoplastic Lesions in Female B6C3F_1_ Mice in the 3-Month Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Moribund | 1
Natural death | | | 1
Survivors
Terminal sacrifice | 9 | 10 | 9 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | | (1) | | | (10)
Hepatodiaphragmatic nodule | | | 1 (100%)
Inflammation, chronic active | 1 (10%) | | | | | 1 (10%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (10) | | | | | (10)
Accessory adrenal cortical nodule | 1 (10%)
Vacuolization cytoplasmic | 6 (60%) | | | | | 7 (70%)
Subcapsular, hyperplasia | 8 (80%) | | | | | 7 (70%)
General Body System
None
Genital System
Ovary | (10) | | | | (1) | (9)
Inflammation, chronic active | | | | | 1 (100%) | 1 (11%)
Uterus | (10) | | | | | (9)
Hydrometra | | | | | | 1 (11%)
Hematopoietic System
None
Integumentary System
Skin | (9) | (10) | (10) | (10) | (10) | (10)
Dermis, skin, site of application, fibrosis | | | | | 9 (90%) | 10 (100%)
Dermis, skin, site of application, inflammation, chronic active | | 2 (20%) | 5 (50%) | 9 (90%) | 9 (90%) | 10 (100%)
Epidermis, skin, site of application, hyperplasia | | 1 (10%) | 2 (20%) | 6 (60%) | 8 (80%) | 10 (100%)
Epidermis, skin, site of application, necrosis | | | | | 2 (20%) | 3 (30%)
Sebaceous gland, skin, site of application, hyperplasia | | | 9 (90%) | 9 (90%) | 8 (80%) | 10 (100%)
Skin, site of application, hyperkeratosis | | 1 (10%) | 2 (20%) | 7 (70%) | 7 (70%) | 7 (70%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
None
Special Senses System
None
Urinary System
Kidney | (10) | | | | | (10)
Nephropathy | 3 (30%)
Urinary bladder | (10) | | | | | (10)
Edema | 1 (10%) | | | | | 2 (20%)

a Number of animals examined microscopically at the site and the number of animals with lesion