# APPENDIX C GENETIC TOXICOLOGY

## Salmonella typhimurium Mutagenicity Test Protocol

Testing was performed as reported by Zeiger et al. (1987). Pentaerythritol triacrylate was sent to the laboratory as a coded aliquot from Radian Corporation (Austin, TX). It was incubated with the Salmonella typhimurium tester strains TA98, TA100, TA1535, and TA1537 either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague-Dawley rat or Syrian hamster liver) for 20 minutes at 37° C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37° C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and at least five doses of pentaerythritol triacrylate. In the absence of toxicity, 10,000 µg/plate was selected as the high dose. All trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive.

## Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al. (1990). At the end of the 3-month and 6-month studies, peripheral blood samples were obtained from male and female B6C3F_1_ (3-month) or Tg.AC hemizygous (6-month) mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic erythrocytes (NCEs) per animal. In addition, the PCE/NCE ratio in 1,000 total erythrocytes per animal was determined to provide a measure of chemical-induced bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over dose groups with a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each dosed group and the control group (ILS, 1990). In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single dosed group is less than or equal to 0.025 divided by the number of dosed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects.

## Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple aliquots of a chemical were tested in the same assay, and different results were obtained among aliquots and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Report presents a result that represents a scientific judgement of the overall evidence for activity of the chemical in an assay.

## Results

Pentaerythritol triacrylate (33-10,000 µg/plate) was not mutagenic in S. typhimurium strain TA98, TA100, TA1535, or TA1537 with or without Aroclor-induced rat or hamster S9 enzymes (Zeiger et al., 1987; Table C1). No increase in the frequency of micronucleated NCEs was observed in peripheral blood samples from male or female B6C3F_1_ mice treated dermally with pentaerythritol triacrylate for 3 months (Table C2). In contrast, treatment of Tg.AC hemizygous female mice administered pentaerythritol triacrylate dermally for 6 months induced a significant increase in micronucleated NCEs; the trend test analysis was highly significant (P#0.001), and the two highest dose groups showed mean values significantly elevated over the vehicle control frequency (Table C3). In Tg.AC hemizygous male mice treated with pentaerythritol triacrylate for 6 months, a small increase in micronucleated NCEs was detected; however, the response was judged to be equivocal, due to a positive trend test (P=0.001) without any one dose group being significantly elevated over the vehicle control frequency. In both micronucleus studies, the dose range tested was 0.75 to 12 mg pentaerythritrol triacrylate/kg body weight. The NCE/PCE ratios in peripheral blood were not significantly altered by chemical treatment in the 3-month study, indicating an absence of induced bone marrow toxicity in this group of animals. However, the NCE/PCE ratios in peripheral blood of Tg.AC mice treated for 6-months were significantly altered at 6 and 12 mg/kg. Male and female mice in these dosed groups had markedly elevated levels of immature PCEs in their blood, implying a stimulation of erythropoiesis, which was perhaps in response to pentaerythritol triacrylate-induced toxicity.

TABLE C1 Mutagenicity of Pentaerythritol Triacrylate in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Revertants/Plate^b^
Strain | Dose (μg/plate) | −S9 | | +10% hamster S9 | | +10% rat S9
Strain | Dose (μg/plate) | Trial 1 | Trial 2 | Trial 1 | Trial 2 | Trial 1 | Trial 2
TA100
| 0 | 156 ± 8.7 | 76 ± 5.0 | 235 ± 12.5 | 174 ± 10.7 | 198 ± 20.5 | 150 ± 5.0
| 100 | 170 ± 15.3 | 70 ± 4.7 | 218 ± 7.2 | 131 ± 2.3 | 203 ± 12.2 | 141 ± 10.7
| 333 | 121 ± 23.8 | 67 ± 3.0 | 232 ± 7.4 | 124 ± 9.6 | 196 ± 3.1 | 140 ± 9.8
| 1,000 | 160 ± 5.8 | 58 ± 3.0 | 222 ± 10.7 | 118 ± 2.2 | 188 ± 5.0 | 123 ± 5.6
| 3,333 | 142 ± 22.9 | 57 ± 1.2 | 223 ± 1.3 | 110 ± 10.8 | 191 ± 1.7 | 106 ± 10.5
| 10,000 | 153 ± 7.9 | 53 ± 5.5 | 194 ± 14.6 | 93 ± 5.6 | 203 ± 7.8 | 97 ± 8.5
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control^c^ | | 479 ± 14.1 | 791 ± 38.1 | 835 ± 146.6 | 1,014 ± 63.5 | 1,858 ± 131.6 | 2,719 ± 75.4
| | −S9 | | +10% hamster S9
| | Trial 1 | Trial 2 | Trial 1 | Trial 2 | Trial 3
TA1535
| 0 | 22 ± 2.9 | 7 ± 0.6 | 24 ± 3.0 | 10 ± 0.9 | 9 ± 0.6
| 33 | | | | | 7 ± 0.3
| 100 | 20 ± 1.5 | 6 ± 1.2 | 42 ± 3.2 | 12 ± 2.5 | 11 ± 0.3
| 333 | 24 ± 3.0 | 9 ± 0.7 | 39 ± 3.4 | 13 ± 2.0 | 13 ± 0.3
| 1,000 | 24 ± 0.6 | 7 ± 0.9 | 40 ± 3.1 | 9 ± 1.2 | 8 ± 2.4
| 3,333 | 22 ± 1.2 | 7 ± 0.9 | 46 ± 2.6 | 9 ± 2.2 | 9 ± 0.0
| 10,000 | 18 ± 1.3 | 6 ± 0.3 | 33 ± 5.8 | 10 ± 1.8 | 7 ± 1.5
Trial summary | | Negative | Negative | Equivocal | Negative | Negative
Positive control | | 1,127 ± 2.1 | 821 ± 34.0 | 529 ± 56.4 | 772 ± 15.1 | 799 ± 16.3
TA1535 (continued)
| | +10% rat S9
| | Trial 1 | Trial 2 | Trial 3
| 0 | 25 ± 4.4 | 10 ± 1.7 | 9 ± 1.2
| 33 | | | 12 ± 1.7
| 100 | 31 ± 2.6 | 11 ± 1.2 | 10 ± 0.9
| 333 | 19 ± 3.6 | 12 ± 2.0 | 12 ± 0.6
| 1,000 | 35 ± 1.5 | 14 ± 2.9 | 9 ± 1.5
| 3,333 | 39 ± 4.0 | 7 ± 1.5 | 7 ± 1.0
| 10,000 | 24 ± 6.3 | 6 ± 0.3 | 6 ± 1.5
Trial summary | | Negative | Negative | Negative
Positive control | | 997 ± 51.3 | 704 ± 42.9 | 834 ± 41.4
| | −S9 | | +10% hamster S9 | | +10% rat S9
| | Trial 1 | Trial 2 | Trial 1 | Trial 2 | Trial 1 | Trial 2
TA1537
| 0 | 6 ± 1.5 | 7 ± 0.6 | 9 ± 1.5 | 8 ± 0.7 | 9 ± 1.2 | 8 ± 1.7
| 100 | 6 ± 1.5 | 6 ± 1.8 | 10 ± 1.5 | 8 ± 1.3 | 11 ± 1.2 | 10 ± 0.7
| 333 | 7 ± 1.5 | 6 ± 1.5 | 13 ± 1.5 | 9 ± 1.7 | 9 ± 3.2 | 7 ± 0.7
| 1,000 | 8 ± 1.5 | 5 ± 0.0 | 13 ± 3.8 | 6 ± 1.5 | 11 ± 3.4 | 7 ± 1.8
| 3,333 | 5 ± 0.7 | 3 ± 2.0 | 12 ± 2.7 | 6 ± 0.9 | 11 ± 0.7 | 4 ± 0.9
| 10,000 | 8 ± 3.8 | 1 ± 0.6 | 11 ± 3.0 | 7 ± 0.9 | 7 ± 0.7 | 7 ± 0.9
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 939 ± 81.5 | 784 ± 147.4 | 380 ± 34.1 | 141 ± 25.1 | 114 ± 11.0 | 161 ± 8.0
| | −S9 | | +10% hamster S9 | | +10% rat S9
| | Trial 1 | Trial 2 | Trial 1 | Trial 2 | Trial 1 | Trial 2
TA98
| 0 | 33 ± 5.6 | 18 ± 5.8 | 45 ± 3.5 | 36 ± 9.4 | 50 ± 4.0 | 32 ± 2.0
| 100 | 23 ± 1.2 | 17 ± 1.2 | 49 ± 3.5 | 23 ± 0.7 | 41 ± 3.2 | 22 ± 2.6
| 333 | 26 ± 2.5 | 15 ± 2.3 | 39 ± 1.8 | 29 ± 5.0 | 31 ± 1.3 | 19 ± 2.1
| 1,000 | 24 ± 3.6 | 14 ± 1.2 | 39 ± 4.5 | 23 ± 2.2 | 39 ± 4.4 | 23 ± 4.7
| 3,333 | 17 ± 2.3 | 17 ± 2.7 | 28 ± 5.2 | 19 ± 0.7 | 33 ± 2.9 | 18 ± 2.3
| 10,000 | 11 ± 3.9 | 15 ± 2.1 | 17 ± 4.4 | 15 ± 3.3 | 20 ± 2.0 | 18 ± 4.4
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 362 ± 8.4 | 287 ± 9.1 | 703 ± 68.6 | 768 ± 56.4 | 1,410 ± 181.0 | 1,790 ± 71.2

a Study was performed at Case Western Reserve University. The detailed protocol and these data are presented by Zeiger et al. (1987). 0 μg/plate was the solvent control.

b Revertants are presented as mean ± standard error from three plates.

c The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535), 9-aminoacridine (TA1537), and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracene.

TABLE C2 Frequency of Micronuclei in Peripheral Blood Normochromatic Erythrocytes of B6C3F_1_ Mice Following Dermal Application of Pentaerythritol Triacrylate for 3 Months^a^

Compound | Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | NCEs^b^ (%)
Male
Acetone^d^ | | 10 | 1.20 ± 0.21 | | 98.2 ± 0.1
Pentaerythritol triacrylate | 0.75 | 10 | 0.75 ± 0.15 | 0.9253 | 98.1 ± 0.1
Pentaerythritol triacrylate | 1.5 | 10 | 1.00 ± 0.15 | 0.7269 | 98.4 ± 0.1
Pentaerythritol triacrylate | 3 | 10 | 0.90 ± 0.19 | 0.8229 | 98.3 ± 0.1
Pentaerythritol triacrylate | 6 | 10 | 1.05 ± 0.22 | 0.6727 | 98.4 ± 0.1
Pentaerythritol triacrylate | 12 | 10 | 1.05 ± 0.16 | 0.6727 | 98.2 ± 0.1
Pentaerythritol triacrylate | | | P=0.394^e^
Female
Acetone | | 9 | 0.72 ± 0.15 | | 98.2 ± 0.1
Pentaerythritol triacrylate | 0.75 | 10 | 0.65 ± 0.15 | 0.6060 | 98.1 ± 0.1
Pentaerythritol triacrylate | 1.5 | 9 | 0.78 ± 0.19 | 0.4237 | 98.3 ± 0.1
Pentaerythritol triacrylate | 3 | 10 | 0.65 ± 0.17 | 0.6060 | 98.3 ± 0.1
Pentaerythritol triacrylate | 6 | 10 | 0.90 ± 0.18 | 0.2722 | 98.3 ± 0.1
Pentaerythritol triacrylate | 12 | 10 | 0.85 ± 0.11 | 0.3290 | 98.4 ± 0.1
Pentaerythritol triacrylate | | | P=0.210

a Study was performed at SITEK Research Laboratories, Inc. The detailed protocol is presented by MacGregor et al. (1990). NCE=normochromatic erythrocyte

b Mean ± standard error

c Pairwise comparison with the vehicle controls, significant at P≤0.005 (ILS, 1990)

d Vehicle control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed Cochran-Armitage trend test, significant at P≤0.025 (ILS, 1990)

TABLE C3 Frequency of Micronuclei in Peripheral Blood Normochromatic Erythrocytes of Tg.AC Hemizygous Mice Following Dermal Application of Pentaerythritol Triacrylate for 6 Months^a^

Compound | Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)
Male
Acetone^d^ | | 12 | 0.58 ± 0.17 | | 3.3
Pentaerythritol triacrylate | 0.75 | 14 | 0.50 ± 0.14 | 0.6585 | 2.2
Pentaerythritol triacrylate | 1.5 | 15 | 0.63 ± 0.16 | 0.4076 | 2.1
Pentaerythritol triacrylate | 3 | 15 | 0.73 ± 0.16 | 0.2511 | 2.1
Pentaerythritol triacrylate | 6 | 12 | 0.96 ± 0.17 | 0.0694 | 11.7^*^
Pentaerythritol triacrylate | 12 | 10 | 1.15 ± 0.36 | 0.0206 | 8.1^*^
Pentaerythritol triacrylate | | | P=0.001^e^
Female
Acetone | | 12 | 0.75 ± 0.21 | | 2.2
Pentaerythritol triacrylate | 0.75 | 14 | 0.61 ± 0.16 | 0.7344 | 2.0
Pentaerythritol triacrylate | 1.5 | 12 | 0.88 ± 0.21 | 0.3154 | 2.2
Pentaerythritol triacrylate | 3 | 12 | 1.04 ± 0.13 | 0.1428 | 2.5
Pentaerythritol triacrylate | 6 | 13 | 1.96 ± 0.31 | 0.0001 | 9.8^*^
Pentaerythritol triacrylate | 12 | 9 | 2.28 ± 0.49 | 0.0000 | 7.3^*^
Pentaerythritol triacrylate | | | P≤0.001

* Significantly increased over the vehicle control.

a Study was performed at SITEK Research Laboratories, Inc. The detailed protocol is presented by MacGregor et al. (1990). NCE=normochromatic erythrocyte; PCE=polychromatic erythrocyte.

b Mean ± standard error

c Pairwise comparison with the vehicle controls, significant at P≤0.005 (ILS, 1990)

d Vehicle control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed Cochran-Armitage trend test, significant at P≤0.025 (ILS, 1990)