# APPENDIX B SUMMARY OF LESIONS IN FEMALE Tg.AC HEMIZYGOUS MICE IN THE 6-MONTH DERMAL STUDY OF PENTAERYTHRITOL TRIACRYLATE

TABLE B1 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animais initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | 1 | 1 | | | | 3
Natural deaths | 2 | | 3 | 3 | 2 | 3
Survivors
Terminal sacrifice | 12 | 14 | 12 | 12 | 13 | 9
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (15) | (15)
Salivary glands | | | | | | (1)
Carcinoma | | | | | | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15) | (15) | (15)
Squamous cell papilloma | 2 (13%) | 4 (27%) | 5 (33%) | 4 (27%) | 6 (40%) | 3 (20%)
Squamous cell papilloma, multiple | 3 (20%) | | | 3 (20%) | 1 (7%) | 1 (7%)
Tooth | (4) | | (3) | (3) | (1)
Odontogenic tumor | 4 (100%) | | 3 (100%) | 2 (67%) | 1 (100%)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15) | (15)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15) | (15) | (15)
Adrenal medulla | (15) | (15) | (15) | (14) | (15) | (15)
Pheochromocytoma benign | | | 1 (7%)
Pituitary gland | (15) | (15) | (14) | (15) | (15) | (15)
General Body System
None
Genital System
Ovary | (15) | (15) | (15) | (15) | (15) | (15)
Uterus | (15) | (15) | (15) | (15) | (15) | (15)
Vagina | | | | | (1)
Squamous cell papilloma | | | | | 1 (100%)
Hematopoietic System
Lymph node | (15) | (14) | (13) | (12) | (15) | (14)
Lymph node, mandibular | (15) | (15) | (15) | (15) | (15) | (13)
Lymph node, mesenteric | (14) | (15) | (15) | (14) | (15) | (15)
Spleen | (15) | (15) | (15) | (15) | (15) | (15)
Thymus | (15) | (15) | (15) | (14) | (14) | (15)
Integumentary System
Skin | (15) | (15) | (15) | (15) | (15) | (15)
Squamous cell papilloma, multiple | | | | | 1 (7%)
Site of application, squamous cell carcinoma | | | | | | 1 (7%)
Site of application, squamous cell papilloma | | | | 3 (20%)
Site of application, squamous cell papilloma, multiple | | | 1 (7%) | 7 (47%) | 12 (80%) | 13 (87%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15) | (15)
Special Senses System
None
Urinary System
Kidney | (15) | (15) | (15) | (15) | (15) | (15)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15) | (15)
Leukemia erythrocytic | 1 (7%) | | | | | 1 (7%)
Lymphoma malignant | | | | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 9 | 4 | 6 | 13 | 13 | 14
Total primary neoplasms | 10 | 4 | 10 | 20 | 22 | 20
Total animals with benign neoplasms | 5 | 4 | 6 | 11 | 13 | 13
Total benign neoplasms | 5 | 4 | 7 | 17 | 21 | 17
Total animals with malignant neoplasms | 1 | | | 1 | | 3
Total malignant neoplasms | 1 | | | 1 | | 3
Total animals with uncertain neoplasms-benign or malignant | 4 | | 3 | 2 | 1
Total uncertain neoplasms | 4 | | 3 | 2 | 1

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B2

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate: Vehicle Control

Number of Days on Study | 0 | 0 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 6 | 7 | 7 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Number of Days on Study | 3 | 0 | 7 | 6 | 6 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Carcass ID Number | 1 | 1 | 1 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 0 | 0 | 0 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 9 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 1 | 4 | 0 | 7 | 8 | 1 | 2 | 3 | 4 | 5 | 6 | 9 | 2 | 3 | 5 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | | | | | | | | | X | | X | 2
Squamous cell papilloma, multiple | | | | | X | | | | | | | X | | X | | 3
Tooth | | | + | | | | | | | + | + | | | | + | 4
Odontogenic tumor | | | X | | | | | | | X | X | | | | X | 4
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | I | + | + | + | + | + | + | + | + | + | + | + | + | 14
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Leukemia erythrocytic | | X | | | | | | | | | | | | | | 1

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate: 0.75 mg/kg

Number of Days on Study | 0 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 6 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Number of Days on Study | 7 | 6 | 6 | 6 | 6 | 6 | 6 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 1 | 0 | 1 | 1 | 1 | 1 | 2 | 0 | 0 | 0 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 4 | 8 | 1 | 2 | 6 | 8 | 0 | 6 | 7 | 9 | 0 | 3 | 5 | 7 | 9 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | X | | | X | | | | | X | | | | X | 4
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | + | + | + | + | M | + | + | + | + | + | + | + | + | + | 14
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate: 1.5 mg/kg

Number of Days on Study | 0 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 0 | 0 | 4 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Number of Days on Study | 5 | 9 | 9 | 6 | 6 | 6 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 3 | 2 | 2 | 2 | 3 | 3 | 2 | 2 | 2 | 2 | 2 | 2 | 3 | 3 | 3 | Total Tissues/Tumors
Carcass ID Number | 4 | 4 | 1 | 7 | 1 | 5 | 2 | 3 | 5 | 6 | 8 | 9 | 0 | 2 | 3 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | | | | | X | X | X | X | X | | | 5
Tooth | | | | | | | | | + | + | + | | | | | 3
Odontogenic tumor | | | | | | | | | X | X | X | | | | | 3
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pheochromocytoma benign | | | | | | | | | | | | | | | X | 1
Pituitary gland | + | I | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | + | + | + | + | + | + | + | M | + | + | M | + | + | + | 13
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Site of application, squamous cell papilloma, multiple | | | | | | | | | | X | | | | | | 1
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate: 3 mg/kg

Number of Days on Study | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 6 | 7 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Number of Days on Study | 7 | 7 | 0 | 6 | 6 | 6 | 6 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 4 | 3 | 4 | 3 | 4 | 4 | 4 | 3 | 3 | 4 | 4 | 4 | 4 | 4 | 5 | Total Tissues/Tumors
Carcass ID Number | 9 | 6 | 2 | 9 | 0 | 3 | 5 | 7 | 8 | 1 | 4 | 6 | 7 | 8 | 0 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | X | | X | | X | | | X | | | | | 4
Squamous cell papilloma, multiple | | | | | X | | | | X | X | | | | | | 3
Tooth | + | + | | | | | | | | | | | | + | | 3
Odontogenic tumor | X | X | | | | | | | | | | | | | | 2
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | M | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | + | + | + | + | + | M | + | M | + | + | M | + | + | + | 12
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | M | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | M | + | 14
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Site of application, squamous cell papilloma | | X | | | X | | | | | | | | | X | | 3
Site of application, squamous cell papilloma, multiple | | | | | | X | X | X | X | X | X | X | | | | 7
Musculoskeletal System
Bone | + | | | | | | | | | | | | | | | 1
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymphoma malignant | | | X | | | | | | | | | | | | | 1

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate: 6 mg/kg

Number of Days on Study | 0 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Number of Days on Study | 5 | 2 | 6 | 6 | 6 | 6 | 6 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 5 | 5 | 5 | 5 | 6 | 6 | 6 | 5 | 5 | 5 | 5 | 5 | 6 | 6 | 6 | Total Tissues/Tumors
Carcass ID Number | 1 | 7 | 4 | 5 | 0 | 3 | 5 | 2 | 3 | 6 | 8 | 9 | 1 | 2 | 4 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | X | | | X | X | | X | | | X | | | | | X | 6
Squamous cell papilloma, multiple | | | | | | | | | | | | X | | | | 1
Tooth | | | | | + | | | | | | | | | | | 1
Odontogenic tumor | | | | | X | | | | | | | | | | | 1
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Vagina | | | | | + | | | | | | | | | | | 1
Squamous cell papilloma | | | | | X | | | | | | | | | | | 1
Hematopoietic System
Lymph node | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | M | + | + | + | + | + | + | + | + | + | + | 14
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma, multiple | | | | | X | | | | | | | | | | | 1
Site of application, squamous cell papilloma, multiple | | X | X | X | X | X | X | | | X | X | X | X | X | X | 12
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate: 12 mg/kg

Number of Days on Study | 0 | 0 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 2 | 9 | 1 | 2 | 3 | 6 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Number of Days on Study | 7 | 8 | 3 | 6 | 4 | 2 | 6 | 6 | 7 | 7 | 7 | 7 | 7 | 7 | 7
Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tissues/Tumors
Carcass ID Number | 7 | 6 | 7 | 7 | 6 | 7 | 6 | 7 | 6 | 7 | 7 | 7 | 7 | 7 | 8 | Total Tissues/Tumors
Carcass ID Number | 1 | 9 | 0 | 6 | 6 | 3 | 7 | 2 | 8 | 4 | 5 | 7 | 8 | 9 | 0 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | | | | + | | | | | | | | | | | | 1
Carcinoma | | | | X | | | | | | | | | | | | 1
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | | | X | | | | | X | | | X | 3
Squamous cell papilloma, multiple | | | | | | | | | X | | | | | | | 1
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Ovary | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Uterus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | M | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mandibular | + | + | + | M | M | + | + | + | + | + | + | + | + | + | + | 13
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Mammary gland | | | | + | | | | | | | | | | | | 1
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Site of application, squamous cell carcinoma | | | | | | | | | | | | | | | X | 1
Site of application, squamous cell papilloma, multiple | | X | X | X | X | X | X | X | X | X | | X | X | X | X | 13
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Leukemia erythrocytic | X | | | | | | | | | | | | | | | 1

+: Tissue examined microscopically | M: Missing tissue | X: Lesion present
A: Autolysis precludes examination | I: Insufficient tissue | Blank: Not examined

TABLE B3 Statistical Analysis of Primary Neoplasms in Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Skin: Squamous Cell Papilloma
Overall rate_a_ | 0/15 (0%) | 0/15 (0%) | 1/15 (7%) | 10/15 (67%) | 12/15 (80%) | 13/15 (87%)
Adjusted rate^b^ | 0.0% | 0.0% | 7.9% | 68.4% | 85.1% | 92.8%
Terminal rate^c^ | 0/12 (0%) | 0/14 (0%) | 1/12 (8%) | 9/12 (75%) | 11/13 (85%) | 8/9 (89%)
First incidence (days) | —^e^ | — | 186 (T) | 177 | 182 | 98
Poly-3 test^d^ | P<0.001 | —^f^ | P=0.496 | P<0.001 | P<0.001 | P<0.001
Skin: Squamous Cell Carcinoma
Overall rate | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 1/15 (7%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 0.0% | 0.0% | 9.3%
Terminal rate | 0/12 (0%) | 0/14 (0%) | 0/12 (0%) | 0/12 (0%) | 0/13 (0%) | 1/9 (11%)
First incidence (days) | — | — | — | — | — | 186 (T)
Poly-3 test | P=0.090 | — | — | — | — | P=0.462
Skin: Squamous Cell Papilloma or Squamous Cell Carcinoma
Overall rate | 0/15 (0%) | 0/15 (0%) | 1/15 (7%) | 10/15 (67%) | 12/15 (80%) | 13/15 (87%)
Adjusted rate | 0.0% | 0.0% | 7.9% | 68.4% | 85.1% | 92.8%
Terminal rate | 0/12 (0%) | 0/14 (0%) | 1/12 (8%) | 9/12 (75%) | 11/13 (85%) | 8/9 (89%)
First incidence (days) | — | — | 186 (T) | 177 | 182 | 98
Poly-3 test | P<0.001 | — | P=0.496 | P<0.001 | P<0.001 | P<0.001
Stomach (Forestomach): Squamous Cell Papilloma
Overall rate | 5/15 (33%) | 4/15 (27%) | 5/15 (33%) | 7/15 (47%) | 7/15 (47%) | 4/15 (27%)
Adjusted rate | 38.6% | 28.5% | 39.3% | 48.3% | 46.9% | 37.3%
Terminal rate | 5/12 (42%) | 4/14 (29%) | 5/12 (42%) | 7/12 (58%) | 6/13 (46%) | 4/9 (44%)
First incidence (days) | 186 (T) | 186 (T) | 186 (T) | 186 (T) | 85 | 186 (T)
Poly-3 test | P=0.409 | P=0.442N | P=0.640 | P=0.451 | P=0.478 | P=0.637N
Tooth: Odontogenic Tumor
Overall rate | 4/15 (27%) | 0/15 (0%) | 3/15 (20%) | 2/15 (13%) | 1/15 (7%) | 0/15 (0%)
Adjusted rate | 30.6% | 0.0% | 23.6% | 13.4% | 7.1% | 0.0%
Terminal rate | 3/12 (25%) | 0/14 (0%) | 3/12 (25%) | 0/12 (0%) | 1/13 (8%) | 0/9 (0%)
First incidence (days) | 177 | — | 186 (T) | 167 | 186 (T) | —
Poly-3 test | P=0.077N | P=0.036N | P=0.518N | P=0.264N | P=0.139N | P=0.070N
All Organs: Benign Neoplasms
Overall rate | 5/15 (33%) | 4/15 (27%) | 6/15 (40%) | 11/15 (73%) | 13/15 (87%) | 13/15 (87%)
Adjusted rate | 38.6% | 28.5% | 47.2% | 75.2% | 86.7% | 92.8%
Terminal rate | 5/12 (42%) | 4/14 (29%) | 6/12 (50%) | 10/12 (83%) | 11/13 (85%) | 8/9 (89%)
First incidence (days) | 186 (T) | 186 (T) | 186 (T) | 177 | 85 | 98
Poly-3 test | P<0.001 | P=0.442N | P=0.484 | P=0.052 | P=0.006 | P<0.001
All Organs: Malignant Neoplasms
Overall rate | 1/15 (7%) | 0/15 (0%) | 0/15 (0%) | 1/15 (7%) | 0/15 (0%) | 3/15 (20%)
Adjusted rate | 7.2% | 0.0% | 0.0% | 6.9% | 0.0% | 24.2%
Terminal rate | 0/12 (0%) | 0/14 (0%) | 0/12 (0%) | 0/12 (0%) | 0/13 (0%) | 1/9 (11%)
First incidence (days) | 70 | — | — | 180 | — | 27
Poly-3 test | P=0.028 | P=0.498N | P=0.518N | P=0.750N | P=0.498N | P=0.254
All Organs: Benign or Malignant Neoplasms
Overall rate | 9/15 (60%) | 4/15 (27%) | 6/15 (40%) | 13/15 (87%) | 13/15 (87%) | 14/15 (93%)
Adjusted rate | 64.1% | 28.5% | 47.2% | 86.7% | 86.7% | 93.3%
Terminal rate | 7/12 (58%) | 4/14 (29%) | 6/12 (50%) | 10/12 (83%) | 11/13 (85%) | 8/9 (89%)
First incidence (days) | 70 | 186 (T) | 186 (T) | 167 | 85 | 27
Poly-3 test | P<0.001 | P=0.059N | P=0.314N | P=0.162 | P=0.162 | P=0.063

(T)Terminal sacrifice

a Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for skin; for all other tissues, denominator is number of animals necropsied.

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal sacrifice. A negative trend or a lower incidence in a dosed group is indicated by N.

e Not applicable; no neoplasms in animal group

f Value of statistic cannot be computed.

TABLE B4 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | 1 | 1 | | | | 3
Natural deaths | 2 | | 3 | 3 | 2 | 3
Survivors
Terminal sacrifice | 12 | 14 | 12 | 12 | 13 | 9
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | | | 1 (7%) | 1 (7%) | 6 (40%)
Infiltration cellular | | | | | 3 (20%) | 2 (13%)
Inflammation, chronic active | 12 (80%) | 14 (93%) | 11 (73%) | 14 (93%) | 13 (87%) | 11 (73%)
Necrosis | | | | | | 1 (7%)
Pigmentation | 11 (73%) | 11 (73%) | 9 (60%) | 13 (87%) | 5 (33%) | 2 (13%)
Bile duct, hyperplasia | | | | | 1 (7%)
Hepatocyte, necrosis | 2 (13%) | 2 (13%) | 2 (13%) | 3 (20%) | 4 (27%) | 2 (13%)
Stomach, forestomach | (15) | (15) | (15) | (15) | (15) | (15)
Hyperkeratosis | 1 (7%) | | 3 (20%) | 3 (20%) | 4 (27%) | 4 (27%)
Inflammation | | | | | 2 (13%)
Epithelium, hyperplasia | 1 (7%) | | | | 2 (13%)
Epithelium, ulcer | | | | | 1 (7%)
Tooth | (4) | | (3) | (3) | (1)
Inflammation, chronic active | | | | 1 (33%)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15) | (15)
Infiltration cellular | | | | | | 1 (7%)
Inflammation, chronic active | | 1 (7%) | | | | 1 (7%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | | | | | 1 (7%)
Necrosis | | | | | | 1 (7%)
Capsule, hyperplasia | 1 (7%) | 4 (27%) | 7 (47%) | 2 (13%) | 1 (7%) | 2 (13%)
Pituitary gland | (15) | (15) | (14) | (15) | (15) | (15)
Pars distalis, cyst | 3 (20%) | | 2 (14%) | 2 (13%) | 4 (27%) | 2 (13%)
General Body System
None
Genital System
Ovary | (15) | (15) | (15) | (15) | (15) | (15)
Cyst | 1 (7%) | | | 1 (7%) | 2 (13%)
Uterus | (15) | (15) | (15) | (15) | (15) | (15)
Hydrometra | 1 (7%) | | | | | 2 (13%)
Endometrium, hyperplasia, cystic | 11 (73%) | 9 (60%) | 7 (47%) | 10 (67%) | 11 (73%) | 7 (47%)
Hematopoietic System
Lymph node | (15) | (14) | (13) | (12) | (15) | (14)
Hematopoietic cell proliferation | | | | | | 2 (14%)
Inguinal, hematopoietic cell proliferation | | | | | | 1 (7%)
Inguinal, hyperplasia | | | | | | 1 (7%)
Inguinal, infiltration cellular | | | | | | 1 (7%)
Inguinal, infiltration cellular, plasma cell | | | | | | 1 (7%)
Mediastinal, hematopoietic cell proliferation | | | | | | 1 (7%)
Mediastinal, hyperplasia | | | | | | 1 (7%)
Mediastinal, infiltration cellular | | | | | 3 (20%) | 1 (7%)
Mediastinal, infiltration cellular, plasma cell | | | | | | 1 (7%)
Mediastinal, necrosis, lymphoid | | | 1 (8%)
Lymph node, mandibular | (15) | (15) | (15) | (15) | (15) | (13)
Hematopoietic cell proliferation | | | | | 1 (7%) | 8 (62%)
Hyperplasia | 3 (20%) | | 1 (7%) | 5 (33%) | 3 (20%) | 1 (8%)
Infiltration cellular | | | | 1 (7%) | 2 (13%) | 2 (15%)
Infiltration cellular, plasma cell | | | | | 1 (7%) | 1 (8%)
Necrosis, lymphoid | | 1 (7%) | 1 (7%)
Lymph node, mesenteric | (14) | (15) | (15) | (14) | (15) | (15)
Infiltration cellular | | | | | 4 (27%)
Necrosis, lymphoid | | 1 (7%)
Spleen | (15) | (15) | (15) | (15) | (15) | (15)
Depletion cellular | 2 (13%) | 1 (7%) | 2 (13%) | 1 (7%) | 2 (13%) | 3 (20%)
Hematopoietic cell proliferation | | | | 2 (13%) | 11 (73%) | 11 (73%)
Infiltration cellular | | | | | 1 (7%) | 1 (7%)
Necrosis, lymphoid | | 1 (7%) | 1 (7%) | | 1 (7%)
Thymus | (15) | (15) | (15) | (14) | (14) | (15)
Atrophy | 3 (20%) | | 2 (13%) | 2 (14%) | 3 (21%) | 6 (40%)
Pigmentation | | | | 1 (7%)
Thymocyte, necrosis | | 1 (7%) | 2 (13%) | 2 (14%) | | 5 (33%)
Integumentary System
Skin | (15) | (15) | (15) | (15) | (15) | (15)
Epidermis, site of application, hyperplasia | | | 5 (33%) | 14 (93%) | 14 (93%) | 14 (93%)
Epidermis, site of application, ulcer | | | | | | 1 (7%)
Sebaceous gland, site of application, hyperplasia, adenomatous | | | | | 1 (7%)
Site of application, cyst epithelial inclusion | | | | | 1 (7%) | 1 (7%)
Site of application, hyperkeratosis | 1 (7%) | | 4 (27%) | 14 (93%) | 11 (73%) | 13 (87%)
Site of application, inflammation, chronic active | | | 1 (7%) | 9 (60%) | 10 (67%) | 15 (100%)
Subcutaneous tissue, hemorrhage | | | | 1 (7%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15) | (15)
Infiltration cellular | | | | | | 1 (7%)
Infiltration cellular, mononuclear cell | | | 1 (7%)
Inflammation, chronic active | | | | 1 (7%) | | 1 (7%)
Alveolar epithelium, hyperplasia | | | | | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (15) | (15) | (15) | (15) | (15) | (15)
Inflammation, chronic active | 1 (7%) | 2 (13%) | 1 (7%) | 1 (7%) | 1 (7%) | 1 (7%)
Nephropathy | 3 (20%) | | | | | 2 (13%)
Polyarteritis | 1 (7%)
Cortex, cyst | | | | | | 2 (13%)
Papilla, necrosis | | | 1 (7%)
Renal tubule, degeneration | | | | | | 1 (7%)
Renal tubule, hyperplasia | | | 1 (7%) | 1 (7%)
Renal tubule, necrosis | | | | | | 2 (13%)
Renal tubule, regeneration | 1 (7%) | 1 (7%) | | 2 (13%) | 1 (7%)

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE B5

In-Life Observation of Skin Papilloma at the Site of Application in Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate: 3 mg/kg^a^

Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tumors | Animals with Tumors
Carcass ID Number | 3 | 3 | 3 | 3 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 4 | 5 | Total Tumors | Animals with Tumors
Carcass ID Number | 6 | 7 | 8 | 9 | 0 | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | Total Tumors | Animals with Tumors
Week
17 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 1
18 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 2 | 2
19 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 2 | 2
20 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 3 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 3 | 1
21 | 0 | 1 | 0 | 0 | 0 | 2 | 0 | 3 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 6 | 3
22 | 0 | 1 | 0 | 0 | 0 | 2 | 0 | 5 | 0 | 2 | 0 | 0 | 1 | 0 | 0 | 11 | 5
23 | 0 | 1 | 0 | 0 | 0 | 4 | 0 | 5 | 0 | 3 | 0 | 0 | 1 | 0 | 0 | 14 | 5
24 | 0 | 1 | 0 | 0 | 1 | 5 | 0 | 5 | 2 | 4 | 0 | 0 | 1 | 0 | 0 | 19 | 7
25 | 0 | 3 | 0 | 0 | 0 | 7 | 0 | 4 | 2 | 4 | 0 | 0 | 1 | X | 0 | 21 | 6
26 | 1 | 3 | 0 | 0 | 1 | 7 | 0 | 6 | 5 | 4 | 0 | 0 | 1 | | 0 | 28 | 8
27 | X | 3 | 0 | 0 | 1 | 8 | X | 4 | 5 | 4 | 0 | 0 | 1 | | 0 | 26 | 7
Necropsy | 1 | 2 | 2 | 0 | 1 | 7 | 0 | 4 | 5 | 4 | 5 | 2 | 1 | 0 | 0 | 34 | 11

X=Animal died

In-Life Observation of Skin Papilloma at the Site of Application in Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate: 6 mg/kg

Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tumors | Animals with Tumors
Carcass ID Number | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 6 | 6 | 6 | 6 | 6 | 6 | Total Tumors | Animals with Tumors
Carcass ID Number | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | 1 | 2 | 3 | 4 | 5 | Total Tumors | Animals with Tumors
Week
11 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 0 | 3 | 4 | 2
12 | 1 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 1 | 2 | 0 | 0 | 8 | 0 | 5 | 18 | 6
13 | 0 | 0 | 0 | 4 | 1 | 0 | 0 | 0 | 3 | 2 | 0 | 2 | 10 | 0 | 5 | 27 | 7
14 | X | 0 | 0 | 4 | 5 | 0 | 0 | 0 | 4 | 2 | 7 | 2 | 10 | 1 | 7 | 42 | 9
15 | | 0 | 0 | 8 | 7 | 0 | 6 | 0 | 4 | 8 | 9 | 4 | 10 | 2 | 9 | 67 | 10
16 | | 0 | 0 | 8 | 7 | 0 | 5 | 0 | 6 | 7 | 12 | 4 | 14 | 6 | 8 | 77 | 10
17 | | 0 | 0 | 7 | 10 | 0 | 10 | 12 | 20 | 15 | 15 | 7 | 20 | 6 | 9 | ≥131 | 11
18 | | 0 | 0 | 10 | 12 | 0 | 20 | 20 | 20 | 13 | 17 | 8 | 20 | 20 | 11 | ≥171 | 11
19 | | 0 | 0 | 13 | 13 | 8 | 18 | 20 | 20 | 10 | 20 | 17 | 20 | 17 | 13 | ≥189 | 12
20 | | 0 | 0 | 14 | 14 | 9 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 13 | ≥210 | 12
21 | | 0 | 0 | 15 | 20 | 10 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 15 | ≥220 | 12
22 | | 0 | 0 | 20 | 20 | 11 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 13 | ≥224 | 12
23 | | 0 | 0 | 20 | 20 | 12 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | ≥232 | 12
24 | | 0 | 0 | 20 | 20 | 14 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | ≥234 | 12
25 | | 0 | 0 | 20 | 20 | 14 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | ≥234 | 12
26 | | 0 | 0 | 20 | 20 | 17 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | ≥237 | 12
27 | | 0 | 0 | 20 | 20 | 16 | X | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | ≥216 | 12
Necropsy | 0 | 0 | 0 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | ≥240 | 12

X=Animal died

In-Life Observation of Skin Papilloma at the Site of Application in Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate: 12 mg/kg

Carcass ID Number | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | Total Tumors | Animals with Tumors
Carcass ID Number | 6 | 6 | 6 | 6 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 7 | 8 | Total Tumors | Animals with Tumors
Carcass ID Number | 6 | 7 | 8 | 9 | 0 | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | Total Tumors | Animals with Tumors
Week
5 | 0 | 0 | 0 | 0 | 0 | X | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0
6 | 0 | 0 | 0 | 0 | 0 | | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0
7 | 0 | 0 | 0 | 0 | 0 | | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0
8 | 0 | 0 | 0 | 0 | 0 | | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0
9 | 0 | 0 | 0 | 0 | 0 | | 0 | 0 | 0 | 0 | 4 | 0 | 0 | 1 | 0 | 5 | 2
10 | 5 | 0 | 0 | 0 | 0 | | 0 | 3 | 2 | 0 | 5 | 0 | 5 | 3 | 0 | 23 | 6
11 | 4 | 0 | 0 | 0 | 0 | | 3 | 4 | 3 | 0 | 5 | 2 | 6 | 4 | 5 | 36 | 9
12 | 5 | 9 | 6 | 13 | 10 | | 10 | 6 | 4 | 0 | 6 | 5 | 8 | 4 | 11 | 97 | 13
13 | 6 | 12 | 5 | 15 | 11 | | 10 | 8 | 5 | 0 | 4 | 8 | 9 | 4 | 10 | 107 | 13
14 | 10 | 12 | 10 | 15 | 15 | | 13 | 8 | 6 | 0 | 10 | 8 | 9 | 5 | 13 | 134 | 13
15 | 13 | 15 | 17 | X | 15 | | 18 | 13 | 11 | 0 | 11 | 15 | 11 | 5 | 20 | ≥164 | 12
16 | 13 | 20 | 16 | | 20 | | 20 | 15 | 10 | 0 | 9 | 17 | 13 | 5 | 20 | ≥178 | 12
17 | 17 | 20 | 20 | | X | | 20 | 20 | 15 | 0 | 9 | 20 | 13 | 5 | 20 | ≥179 | 11
18 | 20 | 20 | 20 | | | | 20 | 20 | 20 | 0 | 14 | 20 | 20 | 6 | 20 | ≥200 | 11
19 | 20 | 20 | 20 | | | | 20 | 20 | 20 | 0 | X | 20 | 20 | 6 | 20 | ≥186 | 10
20 | 20 | 20 | 20 | | | | 20 | 20 | 20 | 0 | | 20 | 20 | 10 | 20 | ≥190 | 10
21 | X | 20 | 20 | | | | 20 | 20 | 20 | 0 | | 20 | 20 | 9 | 20 | ≥169 | 9
22 | | 20 | 20 | | | | 20 | 20 | 20 | 0 | | 20 | 20 | 20 | 20 | ≥180 | 9
23 | | 20 | 20 | | | | 20 | 20 | 20 | 0 | | 20 | 20 | 15 | 20 | ≥175 | 9
24 | | 20 | 20 | | | | 20 | X | 20 | 0 | | 20 | 20 | 20 | 20 | ≥160 | 8
25 | | 20 | 20 | | | | 20 | | 20 | 0 | | 20 | 20 | 17 | 20 | ≥157 | 8
26 | | 20 | 20 | | | | 20 | | 20 | 0 | | 20 | 20 | 20 | 20 | ≥160 | 8
27 | | 20 | 20 | | | | 20 | | 20 | 0 | | 20 | 20 | 20 | 20 | ≥160 | 8
Necropsy | 20 | 20 | 20 | 18 | 20 | 0 | 20 | 20 | 20 | 0 | 12 | 20 | 20 | 20 | 20 | ≥250 | 13

X=Animal died

a No papillomas occurred in the vehicle control or 0.75 mg/kg groups. In the 1.5 mg/kg group, animal 126 had two papillomas first observed at necropsy. The maximum number of papillomas reported in the 6 and 12 mg/kg groups was 20, although some mice in these groups had more than 20 papillomas.