# APPENDIX A SUMMARY OF LESIONS IN MALE Tg.AC HEMIZYGOUS MICE IN THE 6-MONTH DERMAL STUDY OF PENTAERYTHRITOL TRIACRYLATE

TABLE A1 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | | 1 | | | 1
Natural deaths | 3 | | | | 2 | 5
Survivors
Terminal sacrifice | 12 | 14 | 15 | 15 | 12 | 10
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (15) | (15)
Salivary glands | (1) | (1) | | (1) | | (2)
Carcinoma | 1 (100%) | 1 (100%) | | 1 (100%) | | 1 (50%)
Stomach, forestomach | (15) | (15) | (15) | (15) | (15) | (15)
Squamous cell papilloma | 2 (13%) | 3 (20%) | 5 (33%) | 5 (33%) | 5 (33%) | 3 (20%)
Squamous cell papilloma, multiple | 4 (27%) | 1 (7%) | | 3 (20%) | | 2 (13%)
Tooth | (2) | | (3) | (1) | (3) | (2)
Odontogenic tumor | 2 (100%) | | 3 (100%) | 1 (100%) | 3 (100%) | 2 (100%)
Cardiovascular System
None
Endocrine System
None
General Body System
None
Genital System
None
Hematopoietic System
Spleen | (15) | (15) | (15) | (15) | (15) | (15)
Integumentary System
Skin | (15) | (15) | (15) | (15) | (15) | (15)
Squamous cell papilloma, multiple | | | | | | 1 (7%)
Site of application, squamous cell carcinoma | | | | 2 (13%) | | 2 (13%)
Site of application, squamous cell carcinoma, multiple | | | | | | 1 (7%)
Site of application, squamous cell papilloma | 1 (7%) | | 4 (27%) | 4 (27%)
Site of application, squamous cell papilloma, multiple | | | | 11 (73%) | 15 (100%) | 13 (87%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15) | (15)
Alveolar/bronchiolar adenoma | 2 (13%) | 1 (7%)
Carcinoma, metastatic, salivary glands | | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (15) | (15) | (15) | (15) | (15) | (15)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15) | (15)
Leukemia erythrocytic | | | | | | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 9 | 5 | 9 | 15 | 15 | 13
Total primary neoplasms | 12 | 6 | 12 | 27 | 23 | 26
Total animals with benign neoplasms | 7 | 5 | 8 | 15 | 15 | 13
Total benign neoplasms | 9 | 5 | 9 | 23 | 20 | 19
Total animals with malignant neoplasms | 1 | 1 | | 3 | | 5
Total malignant neoplasms | 1 | 1 | | 3 | | 5
Total animals with metastatic neoplasms | | 1
Total metastatic neoplasms | | 1
Total animals with uncertain neoplasms-benign or malignant | 2 | | 3 | 1 | 3 | 2
Total uncertain neoplasms | 2 | | 3 | 1 | 3 | 2

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A2

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate: Vehicle Control

Number of Days on Study | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 3 | 4 | 5 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Number of Days on Study | 2 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 6 | 6 | 6 | 6
Carcass ID Number | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 0 | 1 | 1 | 0 | 0 | 0 | 0 | 0 | 1 | 1 | 1 | 0 | 0 | 0 | 1 | Total Tissues/Tumors
Carcass ID Number | 6 | 2 | 5 | 1 | 2 | 3 | 5 | 7 | 0 | 3 | 4 | 4 | 8 | 9 | 1 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | | | | | | | + | | | | | | | | | 1
Carcinoma | | | | | | | X | | | | | | | | | 1
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | | | | | | X | | | | X | | 2
Squamous cell papilloma, multiple | | X | | | X | | | X | | | | | X | | | 4
Tooth | | | + | | + | | | | | | | | | | | 2
Odontogenic tumor | | | X | | X | | | | | | | | | | | 2
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | M | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 14
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | M | M | + | + | + | + | M | + | + | + | + | + | + | + | + | 12
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Site of application, squamous cell papilloma | | | | | | | | | | | | | X | | | 1
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Alveolar/bronchiolar adenoma | | X | | X | | | | | | | | | | | | 2
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate: 0.75 mg/kg

Number of Days on Study | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 2 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Number of Days on Study | 9 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 6 | 6 | 6 | 6 | 6 | 6 | 6
Carcass ID Number | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 2 | 1 | 1 | 2 | 2 | 2 | 2 | 3 | 1 | 1 | 2 | 2 | 2 | 2 | 2 | Total Tissues/Tumors
Carcass ID Number | 5 | 8 | 9 | 0 | 3 | 4 | 6 | 0 | 6 | 7 | 1 | 2 | 7 | 8 | 9 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | + | | | | | | | | | | | | | | | 1
Carcinoma | X | | | | | | | | | | | | | | | 1
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | X | X | | | | | | | | | | | | X | | 3
Squamous cell papilloma, multiple | | | | | | | | | | X | | | | | | 1
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | I | + | + | + | + | + | + | + | 14
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | | 14
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Alveolar/bronchiolar adenoma | | | | | | | | | | | | | | | X | 1
Carcinoma, metastatic, salivary glands | X | | | | | | | | | | | | | | | 1
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Urinary bladder | + | | | | | | | | | | | | | | | 1
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate: 1.5 mg/kg

Number of Days on Study | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Number of Days on Study | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 6 | 6 | 6 | 6 | 6
Carcass ID Number | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 3 | 3 | 3 | 3 | 3 | 3 | 4 | 4 | 4 | 4 | 3 | 3 | 3 | 4 | 4 | Total Tissues/Tumors
Carcass ID Number | 1 | 2 | 3 | 4 | 8 | 9 | 0 | 3 | 4 | 5 | 5 | 6 | 7 | 1 | 2 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | X | X | | | | | | X | | | | X | | X | | 5
Tooth | | + | | | | | | | + | | | | | | + | 3
Odontogenic tumor | | X | | | | | | | X | | | | | | X | 3
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | + | + | + | + | + | + | + | + | M | + | + | + | + | + | 14
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Site of application, squamous cell papilloma | | X | X | | | X | | | X | | | | | | | 4
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate: 3 mg/kg

Number of Days on Study | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Number of Days on Study | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 6 | 6 | 6 | 6 | 6 | 6 | 6
Carcass ID Number | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 4 | 4 | 4 | 5 | 5 | 5 | 5 | 5 | 4 | 5 | 5 | 5 | 5 | 5 | 6 | Total Tissues/Tumors
Carcass ID Number | 6 | 7 | 8 | 2 | 3 | 6 | 7 | 8 | 9 | 0 | 1 | 4 | 5 | 9 | 0 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | | | | | | | | | | | + | | | | | 1
Carcinoma | | | | | | | | | | | X | | | | | 1
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | X | | | | X | | | | X | X | | | X | 5
Squamous cell papilloma, multiple | | | | | | | | | X | X | | | X | | | 3
Tooth | | | | | | + | | | | | | | | | | 1
Odontogenic tumor | | | | | | X | | | | | | | | | | 1
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | + | + | + | + | + | + | + | + | + | + | M | M | + | + | 13
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Site of application, squamous cell carcinoma | | | | | X | | | X | | | | | | | | 2
Site of application, squamous cell papilloma | | X | | X | | | | | | | | | X | | X | 4
Site of application, squamous cell papilloma, multiple | X | | X | | X | X | X | X | X | X | X | X | | X | | 11
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate: 6 mg/kg

Number of Days on Study | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 6 | 6 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Number of Days on Study | 3 | 6 | 4 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 6 | 6 | 6 | 6 | 6
Carcass ID Number | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 7 | 7 | 6 | 7 | 7 | 7 | 7 | Total Tissues/Tumors
Carcass ID Number | 3 | 1 | 2 | 4 | 6 | 7 | 8 | 9 | 0 | 1 | 5 | 2 | 3 | 4 | 5 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | | X | | | | | X | X | X | X | | 5
Tooth | | | + | | | | + | | | | | | | | + | 3
Odontogenic tumor | | | X | | | | X | | | | | | | | X | 3
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | + | + | + | + | + | + | + | M | + | + | + | + | 14
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Site of application, squamous cell papilloma, multiple | X | X | X | X | X | X | X | X | X | X | X | X | X | X | X | 15
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15

Individual Animal Tumor Pathology of Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate: 12 mg/kg

Number of Days on Study | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1 | 1
Number of Days on Study | 3 | 6 | 6 | 7 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Number of Days on Study | 8 | 0 | 7 | 0 | 2 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 6 | 6
Carcass ID Number | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | Total Tissues/Tumors
Carcass ID Number | 8 | 9 | 8 | 8 | 7 | 7 | 7 | 8 | 8 | 8 | 8 | 8 | 8 | 7 | 8 | Total Tissues/Tumors
Carcass ID Number | 8 | 0 | 9 | 7 | 9 | 6 | 7 | 0 | 1 | 3 | 4 | 5 | 6 | 8 | 2 | Total Tissues/Tumors
Alimentary System
Liver | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Salivary glands | | | + | | | | | | | | | | | | | 1
Carcinoma | | | X | | | | | | | | | | | | | 1
Stomach, forestomach | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma | | | | | | | X | | | X | | X | | | | 3
Squamous cell papilloma, multiple | | | | | | | | X | X | | | | | | | 2
Tooth | | | | + | | | | | | | + | | | | | 2
Odontogenic tumor | | | | X | | | | | | | X | | | | | 2
Cardiovascular System
Heart | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Endocrine System
Adrenal cortex | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Adrenal medulla | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Pituitary gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thyroid gland | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
General Body System
None
Genital System
Epididymis | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Preputial gland | | | | | | | + | | | | | | | | | 1
Testes | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Hematopoietic System
Lymph node | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mandibular | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Lymph node, mesenteric | + | + | + | + | M | + | + | + | + | + | + | + | + | + | + | 14
Spleen | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Thymus | + | + | + | M | + | + | + | + | + | + | + | + | + | + | + | 14
Integumentary System
Skin | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Squamous cell papilloma, multiple | | | | | | | | | X | | | | | | | 1
Site of application, squamous cell carcinoma | | | | | | X | | | | | | X | | | | 2
Site of application, squamous cell carcinoma, multiple | | | | | X | | | | | | | | | | | 1
Site of application, squamous cell papilloma, multiple | X | X | X | X | X | X | X | X | X | X | X | X | X | | | 13
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Special Senses System
None
Urinary System
Kidney | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Systemic Lesions
Multiple organs | + | + | + | + | + | + | + | + | + | + | + | + | + | + | + | 15
Leukemia erythrocytic | X | | | | | | | | | | | | | | | 1

+: Tissue examined microscopically | M: Missing tissue | X: Lesion present
A: Autolysis precludes examination | I: Insufficient tissue | Blank: Not examined

TABLE A3 Statistical Analysis of Primary Neoplasms in Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Lung: Alveolar/bronchiolar Adenoma
Overall rate^a^ | 2/15 (13%) | 1/15 (7%) | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 0/15 (0%)
Adjusted rate^b^ | 14.3% | 7.0% | 0.0% | 0.0% | 0.0% | 0.0%
Terminal rate^c^ | 1/12 (8%) | 1/14 (7%) | 0/15 (0%) | 0/15 (0%) | 0/12 (0%) | 0/10 (0%)
First incidence (days) | 145 | 185 (T) | –^e^ | – | – | –
Poly-3 test^d^ | P=0.133N | P=0.490N | P=0.215N | P=0.215N | P=0.224N | P=0.238N
Skin: Squamous Cell Papilloma
Overall rate | 1/15 (7%) | 0/15 (0%) | 4/15 (27%) | 15/15 (100%) | 15/15 (100%) | 13/15 (87%)
Adjusted rate | 7.4% | 0.0% | 26.7% | 100.0% | 100.0% | 86.7%
Terminal rate | 1/12 (8%) | 0/14 (0%) | 4/15 (27%) | 15/15 (100%) | 12/12 (100%) | 8/10 (80%)
First incidence (days) | 185 (T) | – | 185 (T) | 185 (T) | 163 | 138
Poly-3 test | P<0.001 | P=0.487N | P=0.198 | P<0.001 | P<0.001 | P<0.001
Skin: Squamous Cell Carcinoma
Overall rate | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 2/15 (13%) | 0/15 (0%) | 3/15 (20%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 13.3% | 0.0% | 22.1%
Terminal rate | 0/12 (0%) | 0/14 (0%) | 0/15 (0%) | 2/15 (13%) | 0/12 (0%) | 2/10 (20%)
First incidence (days) | – | – | – | 185 (T) | – | 182
Poly-3 test | P=0.011 | –^f^ | – | P=0.257 | – | P=0.106
Skin: Squamous Cell Papilloma or Squamous Cell Carcinoma
Overall rate | 1/15 (7%) | 0/15 (0%) | 4/15 (27%) | 15/15 (100%) | 15/15 (100%) | 13/15 (87%)
Adjusted rate | 7.4% | 0.0% | 26.7% | 100.0% | 100.0% | 86.7%
Terminal rate | 1/12 (8%) | 0/14 (0%) | 4/15 (27%) | 15/15 (100%) | 12/12 (100%) | 8/10 (80%)
First incidence (days) | 185 (T) | – | 185 (T) | 185 (T) | 163 | 138
Poly-3 test | P<0.001 | P=0.487N | P=0.198 | P<0.001 | P<0.001 | P<0.001
Stomach (Forestomach): Squamous Cell Papilloma
Overall rate | 6/15 (40%) | 4/15 (27%) | 5/15 (33%) | 8/15 (53%) | 5/15 (33%) | 5/15 (33%)
Adjusted rate | 43.0% | 26.7% | 33.3% | 53.3% | 34.8% | 37.0%
Terminal rate | 5/12 (42%) | 3/14 (21%) | 5/15 (33%) | 8/15 (53%) | 5/12 (42%) | 5/10 (50%)
First incidence (days) | 145 | 129 | 185 (T) | 185 (T) | 185 (T) | 185 (T)
Poly-3 test | P=0.550 | P=0.300N | P=0.441N | P=0.429 | P=0.474N | P=0.526N
Tooth: Odontogenic Tumor
Overall rate | 2/15 (13%) | 0/15 (0%) | 3/15 (20%) | 1/15 (7%) | 3/15 (20%) | 2/15 (13%)
Adjusted rate | 14.5% | 0.0% | 20.0% | 6.7% | 20.8% | 14.6%
Terminal rate | 1/12 (8%) | 0/14 (0%) | 3/15 (20%) | 1/15 (7%) | 2/12 (17%) | 1/10 (10%)
First incidence (days) | 155 | – | 185 (T) | 185 (T) | 184 | 170
Poly-3 test | P=0.358 | P=0.223N | P=0.538 | P=0.472N | P=0.519 | P=0.697
All Organs: Benign Neoplasms
Overall rate | 7/15 (47%) | 5/15 (33%) | 8/15 (53%) | 15/15 (100%) | 15/15 (100%) | 13/15 (87%)
Adjusted rate | 50.2% | 33.3% | 53.3% | 100.0% | 100.0% | 86.7%
Terminal rate | 6/12 (50%) | 4/14 (29%) | 8/15 (53%) | 15/15 (100%) | 12/12 (100%) | 8/10 (80%)
First incidence (days) | 145 | 129 | 185 (T) | 185 (T) | 163 | 138
Poly-3 test | P<0.001 | P=0.297N | P=0.578 | P<0.001 | P<0.001 | P=0.033
All Organs: Malignant Neoplasms
Overall rate | 1/15 (7%) | 1/15 (7%) | 0/15 (0%) | 3/15 (20%) | 0/15 (0%) | 5/15 (33%)
Adjusted rate | 7.4% | 6.7% | 0.0% | 20.0% | 0.0% | 34.7%
Terminal rate | 1/12 (8%) | 0/14 (0%) | 0/15 (0%) | 3/15 (20%) | 0/12 (0%) | 2/10 (20%)
First incidence (days) | 185 (T) | 129 | – | 185 (T) | – | 138
Poly-3 test | P=0.008 | P=0.736N | P=0.478N | P=0.340 | P=0.486N | P=0.094
All Organs: Benign or Malignant Neoplasms
Overall rate | 9/15 (60%) | 5/15 (33%) | 9/15 (60%) | 15/15 (100%) | 15/15 (100%) | 13/15 (87%)
Adjusted rate | 62.7% | 33.3% | 60.0% | 100.0% | 100.0% | 86.7%
Terminal rate | 7/12 (58%) | 4/14 (29%) | 9/15 (60%) | 15/15 (100%) | 12/12 (100%) | 8/10 (80%)
First incidence (days) | 145 | 129 | 185 (T) | 185 (T) | 163 | 138
Poly-3 test | P<0.001 | P=0.108N | P=0.589N | P=0.008 | P=0.008 | P=0.137

(T)Terminal sacrifice

a Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for lung and skin; for other tissues, denominator is number of animals necropsied.

b Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

c Observed incidence at terminal kill

d Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal sacrifice. A negative trend or a lower incidence in a dosed group is indicated by N.

e Not applicable; no neoplasms in animal group

f Value of statistic cannot be computed.

TABLE A4 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | | 1 | | | 1
Natural deaths | 3 | | | | 2 | 5
Survivors
Terminal sacrifice | 12 | 14 | 15 | 15 | 12 | 10
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (15) | (15)
Atrophy | 1 (7%)
Hematopoietic cell proliferation | | | | | 2 (13%)
Infiltration cellular | | | | | 5 (33%) | 3 (20%)
Inflammation, chronic active | 5 (33%) | 11 (73%) | 10 (67%) | 13 (87%) | 13 (87%) | 5 (33%)
Mineralization | 1 (7%)
Myelodysplasia | | | | | | 5 (33%)
Pigmentation | | 1 (7%) | 1 (7%)
Hepatocyte, necrosis | 1 (7%) | | 1 (7%) | | 1 (7%) | 1 (7%)
Hepatocyte, vacuolization cytoplasmic | | | 1 (7%)
Salivary glands | (1) | (1) | | (1) | | (2)
Parotid gland, infiltration cellular | | | | | | 1 (50%)
Stomach, forestomach | (15) | (15) | (15) | (15) | (15) | (15)
Hyperkeratosis | 2 (13%) | | 1 (7%) | | 3 (20%) | 4 (27%)
Epithelium, hyperplasia | | | 1 (7%)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15) | (15)
Infiltration cellular | | | | | | 3 (20%)
Inflammation, chronic active | | 3 (20%) | | | 1 (7%)
Myelodysplasia | | | | | | 3 (20%)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15) | (15) | (15)
Hypertrophy | 7 (47%) | 10 (67%) | 3 (20%) | 5 (33%) | 1 (7%) | 3 (20%)
Myelodysplasia | | | | | | 2 (13%)
Adrenal medulla | (15) | (15) | (15) | (15) | (15) | (15)
Infiltration cellular | | | | | | 2 (13%)
Myelodysplasia | | | | | | 2 (13%)
Pituitary gland | (15) | (14) | (15) | (15) | (15) | (15)
Pars distalis, cyst | 1 (7%) | | | | 3 (20%)
Thyroid gland | (15) | (15) | (15) | (15) | (15) | (15)
Inflammation, chronic active | | | | | 1 (7%)
Myelodysplasia | | | | | | 1 (7%)
General Body System
None
Genital System
Epididymis | (15) | (14) | (15) | (15) | (15) | (15)
Infiltration cellular | | | | | 5 (33%) | 5 (33%)
Inflammation, chronic active | | 1 (7%) | | | | 4 (27%)
Myelodysplasia | | | | | | 5 (33%)
Bilateral, hypospermia | | | | | | 1 (7%)
Unilateral, hypospermia | 1 (7%) | 1 (7%) | | | | 2 (13%)
Preputial gland | | | | | | (1)
Duct, ectasia | | | | | | 1 (100%)
Testes | (15) | (15) | (15) | (15) | (15) | (15)
Cyst | 2 (13%) | 1 (7%) | | 1 (7%) | 1 (7%)
Bilateral, germinal epithelium, degeneration | | | | | 1 (7%)
Unilateral, germinal epithelium, degeneration | 1 (7%) | 1 (7%) | | 2 (13%) | 1 (7%) | 4 (27%)
Hematopoietic System
Bone marrow | | | | | | (1)
Myeloid cell, hyperplasia | | | | | | 1 (100%)
Lymph node | (14) | (15) | (14) | (13) | (15) | (14)
Hyperplasia | | | | | 1 (7%)
Infiltration cellular, plasma cell | | | | | 1 (7%)
Inflammation, chronic active | | | | | 1 (7%)
Myelodysplasia | | | | | | 1 (7%)
Axillary, hyperplasia, lymphoid | | | | | | 1 (7%)
Axillary, infiltration cellular | | | | | 1 (7%) | 1 (7%)
Axillary, infiltration cellular, plasma cell | | | | | 1 (7%) | 1 (7%)
Axillary, infiltration cellular, histiocyte | | | | | | 1 (7%)
Inguinal, myelodysplasia | | | | | | 1 (7%)
Mediastinal, hyperplasia | | | | | 1 (7%)
Mediastinal, infiltration cellular | | | | | 4 (27%) | 2 (14%)
Mediastinal, myelodysplasia | | | | | | 1 (7%)
Lymph node, mandibular | (15) | (15) | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | | | | 3 (20%)
Hyperplasia | | | 2 (13%) | 1 (7%) | 2 (13%)
Hyperplasia, plasma cell | | | | | | 1 (7%)
Infiltration cellular | | | | | 5 (33%) | 6 (40%)
Infiltration cellular, plasma cell | | | | | 1 (7%) | 6 (40%)
Myelodysplasia | | | | | | 2 (13%)
Necrosis, lymphoid | | | | | 2 (13%)
Lymph node, mesenteric | (12) | (15) | (15) | (15) | (15) | (14)
Hematopoietic cell proliferation | | | | | 1 (7%) | 1 (7%)
Infiltration cellular | | | | | 4 (27%) | 2 (14%)
Myelodysplasia | | | | | | 3 (21%)
Necrosis, lymphoid | | | | | 1 (7%)
Spleen | (15) | (15) | (15) | (15) | (15) | (15)
Atrophy | 1 (7%)
Depletion cellular | | | | | 2 (13%) | 2 (13%)
Hematopoietic cell proliferation | 1 (7%) | 2 (13%) | 1 (7%) | 2 (13%) | 9 (60%) | 8 (53%)
Infiltration cellular | | | | | 1 (7%) | 4 (27%)
Myelodysplasia | | | | | | 4 (27%)
Necrosis, lymphoid | | | | | 2 (13%) | 1 (7%)
Thymus | (15) | (15) | (15) | (15) | (14) | (14)
Atrophy | 4 (27%) | 1 (7%) | 2 (13%) | | 4 (29%) | 5 (36%)
Myelodysplasia | | | | | | 3 (21%)
Thymocyte, necrosis | | | | | 2 (14%)
Integumentary System
Skin | (15) | (15) | (15) | (15) | (15) | (15)
Dermis, site of application, necrosis | | | | | | 1 (7%)
Epidermis, site of application, hyperplasia | | | 3 (20%) | 8 (53%) | 10 (67%) | 14 (93%)
Epidermis, site of application, ulcer | | | | | 1 (7%)
Site of application, cyst epithelial inclusion | | | | | | 1 (7%)
Site of application, hyperkeratosis | 1 (7%) | | 2 (13%) | 6 (40%) | 10 (67%) | 13 (87%)
Site of application, inflammation, chronic active | | | | 2 (13%) | 5 (33%) | 12 (80%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15) | (15)
Infiltration cellular | | | | | 1 (7%) | 3 (20%)
Inflammation, chronic active | | | | | 1 (7%) | 2 (13%)
Myelodysplasia | | | | | | 3 (20%)
Alveolar epithelium, hyperplasia | | | 1 (7%)
Mediastinum, infiltration cellular | | | | | | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (15) | (15) | (15) | (15) | (15) | (15)
Hydronephrosis | | | | | | 1 (7%)
Infarct | | | 1 (7%) | 2 (13%)
Infiltration cellular | | | | | 2 (13%) | 3 (20%)
Inflammation, chronic active | 1 (7%) | | 4 (27%) | 4 (27%) | 3 (20%)
Mineralization | | | | | 1 (7%)
Myelodysplasia | | | | | | 4 (27%)
Nephropathy | 6 (40%) | 1 (7%)
Pigmentation | 1 (7%)
Cortex, cyst | | 1 (7%) | | 1 (7%) | 1 (7%) | 1 (7%)
Renal tubule, dilatation | | | | 1 (7%)
Renal tubule, regeneration | 1 (7%) | 2 (13%) | | 3 (20%)

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A5

In-Life Observation of Skin Papilloma at the Site of Application in Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate: 3 mg/kg^a^

Carcass ID Number | 4 | 4 | 4 | 4 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 6 | Total Tumors | Animals with Tumors
Carcass ID Number | 6 | 7 | 8 | 9 | 0 | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | Total Tumors | Animals with Tumors
Week
14 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 1 | 1
15 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 2 | 2
16 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 2 | 0 | 0 | 0 | 2 | 3 | 1 | 0 | 8 | 4
17 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 2 | 2 | 1 | 0 | 6 | 4
18 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 4 | 2 | 2 | 1 | 0 | 10 | 5
19 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 3 | 2 | 2 | 1 | 1 | 9 | 5
20 | 0 | 0 | 1 | 4 | 0 | 0 | 0 | 0 | 0 | 0 | 3 | 2 | 2 | 1 | 1 | 14 | 7
21 | 0 | 0 | 2 | 5 | 2 | 0 | 0 | 0 | 3 | 0 | 2 | 4 | 1 | 1 | 1 | 21 | 9
22 | 0 | 0 | 2 | 6 | 9 | 3 | 0 | 0 | 3 | 0 | 3 | 4 | 1 | 1 | 1 | 33 | 10
23 | 0 | 0 | 2 | 6 | 9 | 3 | 0 | 0 | 2 | 0 | 4 | 5 | 1 | 1 | 1 | 34 | 10
24 | 0 | 0 | 1 | 7 | 11 | 4 | 0 | 0 | 5 | 0 | 5 | 8 | 1 | 1 | 1 | 44 | 10
25 | 2 | 0 | 2 | 6 | 11 | 4 | 0 | 0 | 5 | 0 | 9 | 7 | 1 | 2 | 1 | 50 | 11
26 | 2 | 0 | 3 | 8 | 12 | 3 | 1 | 0 | 5 | 0 | 10 | 9 | 1 | 3 | 1 | 58 | 12
27 | 2 | 0 | 3 | 7 | 10 | 6 | 1 | 0 | 5 | 0 | 11 | 11 | 2 | 3 | 1 | 62 | 12
Necropsy | 2 | 1 | 3 | 8 | 14 | 8 | 1 | 6 | 7 | 2 | 10 | 13 | 3 | 3 | 1 | 89 | 15

In-Life Observation of Skin Papilloma at the Site of Application in Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate: 6 mg/kg

Carcass ID Number | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 6 | 7 | 7 | 7 | 7 | 7 | 7 | Total Tumors | Animals with Tumors
Carcass ID Number | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | 1 | 2 | 3 | 4 | 5 | Total Tumors | Animals with Tumors
Week
9 | 2 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 2 | 1
10 | 2 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 3 | 2
11 | 2 | 0 | 2 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 5 | 3
12 | 2 | 0 | 2 | 2 | 4 | 0 | 0 | 0 | 0 | 2 | 1 | 0 | 0 | 0 | 0 | 13 | 6
13 | 6 | 3 | 3 | 2 | 5 | 0 | 0 | 2 | 0 | 4 | 1 | 2 | 1 | 0 | 0 | 29 | 10
14 | 6 | 3 | 5 | 6 | 3 | 2 | 0 | 2 | 3 | 7 | 1 | 3 | 4 | 4 | 0 | 49 | 13
15 | 7 | 3 | 6 | 7 | 3 | 3 | 5 | 2 | 2 | 9 | 2 | 5 | 4 | 7 | 5 | 70 | 15
16 | 9 | 3 | 7 | 7 | 4 | 4 | 6 | 3 | 3 | 7 | 4 | 8 | 5 | 4 | 8 | 82 | 15
17 | 17 | 3 | 13 | 9 | 6 | 8 | 9 | 6 | 2 | 12 | 3 | 6 | 5 | 10 | 10 | 119 | 15
18 | 20 | 5 | 15 | 11 | 13 | 10 | 9 | 6 | 5 | 15 | 5 | 16 | 6 | 11 | 20 | ≥167 | 15
19 | 20 | 5 | 16 | 13 | 14 | 15 | 11 | 7 | 5 | 20 | 6 | 20 | 5 | 13 | 18 | ≥188 | 15
20 | 20 | 6 | 20 | 17 | 14 | 17 | 12 | 11 | 4 | 20 | 12 | 20 | 9 | 11 | 20 | ≥213 | 15
21 | 20 | 6 | 20 | 15 | 18 | 20 | 16 | 11 | 4 | 20 | 12 | 20 | 14 | 15 | 20 | ≥231 | 15
22 | 20 | 8 | 20 | 20 | 17 | 20 | 20 | 12 | 10 | 20 | 15 | 20 | 15 | 20 | 20 | ≥257 | 15
23 | 20 | 15 | 20 | 20 | 20 | 20 | 20 | 15 | 13 | 20 | 14 | 20 | 14 | 20 | 20 | ≥271 | 15
24 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 16 | 20 | 20 | 20 | 20 | 20 | 20 | ≥296 | 15
25 | X | 20 | X | 20 | 20 | 20 | 20 | 17 | 17 | 20 | 20 | 20 | 15 | 20 | 20 | ≥249 | 13
26 | | 20 | | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | ≥260 | 13
27 | | 20 | | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | ≥260 | 13
Necropsy | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | ≥300 | 15

In-Life Observation of Skin Papilloma at the Site of Application in Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Pentaerythritol Triacrylate: 12 mg/kg

Carcass ID Number | 7 | 7 | 7 | 7 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 9 | Total Tumors | Animals with Tumors
Carcass ID Number | 6 | 7 | 8 | 9 | 0 | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 0 | Total Tumors | Animals with Tumors
Week
9 | 4 | 0 | 0 | 0 | 0 | 3 | 0 | 0 | 4 | 4 | 1 | 2 | 0 | 0 | 0 | 18 | 6
10 | 4 | 0 | 0 | 2 | 3 | 5 | 0 | 0 | 8 | 13 | 1 | 2 | 0 | 8 | 0 | 46 | 9
11 | 4 | 0 | 0 | 4 | 6 | 4 | 0 | 3 | 9 | 15 | 1 | 2 | 3 | 10 | 0 | 61 | 11
12 | 6 | 0 | 0 | 9 | 10 | 10 | 0 | 4 | 14 | 20 | 4 | 2 | 7 | 15 | 13 | ≥114 | 12
13 | 7 | 7 | 0 | 10 | 11 | 14 | 0 | 6 | 14 | 20 | 5 | 2 | 6 | 20 | 20 | ≥142 | 13
14 | 7 | 10 | 0 | 11 | 12 | 9 | 0 | 6 | 14 | 20 | 4 | 2 | 7 | 20 | 20 | ≥142 | 13
15 | 11 | 12 | 0 | 20 | 20 | 10 | 0 | 6 | 15 | 20 | 4 | 3 | 13 | 20 | 20 | ≥174 | 13
16 | 10 | 13 | 0 | 20 | 16 | 15 | 0 | 6 | 16 | 20 | 6 | 3 | 16 | 20 | 20 | ≥181 | 13
17 | 18 | 15 | 0 | 18 | 20 | 20 | 0 | 7 | 20 | 20 | 10 | 4 | 20 | 20 | 20 | ≥212 | 13
18 | 20 | 20 | 0 | 20 | 20 | 20 | 0 | 12 | 20 | 20 | 17 | 4 | 20 | 20 | 20 | ≥233 | 13
19 | 20 | 20 | 0 | 20 | 20 | 20 | 0 | 15 | 20 | 20 | 12 | 7 | 20 | 20 | 20 | ≥234 | 13
20 | 20 | 20 | 0 | 20 | 20 | 20 | 0 | 15 | 20 | 20 | 15 | 12 | 20 | 20 | 20 | ≥242 | 13
21 | 20 | 20 | 0 | 20 | 20 | 20 | 0 | 20 | 20 | 20 | 20 | 14 | X | 20 | 20 | ≥234 | 12
22 | 20 | 20 | 0 | 20 | 20 | 20 | 0 | 20 | 20 | 20 | 20 | 20 | | 20 | 20 | ≥240 | 12
23 | 20 | 20 | 0 | 20 | 20 | 20 | 0 | 20 | 20 | 20 | 20 | 20 | | 20 | 20 | ≥240 | 12
24 | 20 | 20 | 0 | 20 | 20 | 20 | 0 | 20 | 20 | 20 | 20 | 20 | | 20 | X | ≥220 | 11
25 | 20 | 20 | 0 | 20 | 20 | 20 | 0 | 20 | 20 | 20 | 20 | 20 | | X | | ≥200 | 10
26 | 20 | 20 | 0 | 20 | 20 | 20 | 0 | 20 | 20 | 20 | 20 | X | | | | ≥180 | 9
27 | 20 | 20 | 0 | X | 20 | 20 | 0 | 20 | 20 | 20 | 20 | | | | | ≥160 | 8
Necropsy | 20 | 20 | 0 | 20 | 20 | 20 | 0 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | 20 | ≥260 | 13

X=Animal died

a Animal 8 in the vehicle control group had a single papilloma first observed at necropsy. No papillomas occurred in the 0.75 mg/kg group. In the 1.5 mg/kg group, animal 32 had a single papilloma observed only at week 21, and animal 39 had a single papilloma observed from week 20 through necropsy. The maximum number of papillomas reported in the 6 and 12 mg/kg groups was 20, although some mice in these groups had more than 20 papillomas. Animal 62 in the 6 mg/kg group was sacrificed one day before study termination.