# REFERENCES

Albert, R.E., French, J.E., Maronpot, R., Spalding, J., and Tennant, R. (1996). Mechanism of skin tumorigenesis by contact sensitizers: The effect of the corticosteroid fluocinolone acetonide on inflammation and tumor induction by 2,4 dinitro-1-fluorobenzene in the skin of the TG.AC (v-Ha-ras) mouse. Environ. Health Perspect. 104, 1062–1068.8930547
The Aldrich Library of FT-IR Spectra (1985). Spectra Nos. 1:405A and 1:640A. 1st ed. (C.J. Pouchert, Ed.). Aldrich Chemical Company, Inc., Milwaukee, WI.
Alfa (1990). Alfa Catalog: Research Chemicals and Accessories Catalog, p. 415. Johnson Matthey, Ward Hill, MA.
American Industrial Hygiene Association (AIHA) (1981). Workplace environmental exposure level guide: Trimethylolpropane triacrylate. Am. Ind. Hyg. Assoc. J. 42, B53–B54.7315736
Andrews, L.S., and Clary, J.J. (1986) Review of the toxicity of multifunctional acrylates. J. Toxicol. Environ. Health 19, 149–164.3531535
Anonymous (1985). Dermatitis from trimethylol propane triacrylate. Food Chem. Toxicol. 23, 124–126.3156077
ARCO Chemical Company (ARCO) (1989). ARCO Specialty Chemical Product Catalog. ARCO Chemical Company, Newton Square, PA.
Argyris, T.S. (1980). Tumor promotion by abrasion-induced epidermal hyperplasia in the skin of mice. J. Invest. Dermatol. 75, 360–362.6776204
Argyris, T.S. (1981). The regulation of epidermal hyper plastic growth. Crit. Rev. Toxicol. 9, 151–200.7026175
Bailer, A.J., and Portier, C.J. (1988). Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics 44, 417–431.3390507
Bauluz, C., Larcher, F., Ballestin, C., Grande, T., and Jorcano, J. (1994). Augmented expression of cytokines in mouse epidermal tumor cells and its possible involvement in the induction of hematopoietic alterations. Mol. Carcinog. 11, 155–163.7945804
Bieler, G.S., and Williams, R.L. (1993). Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics 49, 793–801.8241374
Björkner, B. (1984). The sensitizing capacity of multi functional acrylates in the guinea pig. Contact Dermatitis 11, 236–246.6499426
Björkner, B., Dahlquist, I., and Fregert, S. (1980). Allergic contact dermatitis from acrylates in ultraviolet curing inks. Contact Dermatitis 6, 405–409.6449348
Boorman, G.A., Montgomery, C.A., Jr., Eustis, S.L., Wolfe, M.J., McConnell, E.E., and Hardisty, J.F. (1985). Quality assurance in pathology for rodent carcinogenicity studies. In Handbook of Carcinogen Testing (H.A. Milman and E.K. Weisburger, Eds.), pp. 345–357. Noyes Publications, Park Ridge, NJ.
Bull, J.E., Parker, D., and Turk, J.L. (1985). Predictive value of assessment of lymph node weight and T-lymphocyte proliferation in contact sensitivity in acrylates. J. Invest. Dermatol. 85, 403–406.3877123
Bull, J.E., Henderson, D.C., and Turk, J.L. (1987). Immunogenicity of acrylate chemicals as assessed by antibody induction. Int. Arch. Allergy Appl. Immunol. 83, 310–314.3596820
Cameron, T.P., Rogers-Back, A.M., Lawlor, T.E., Harbell, J.W., Seifried, H.E., and Dunkel, V.C. (1991). Genotoxicity of multifunctional acrylates in the Salmonella/mammalian-microsome assay and mouse lymphoma TK+/− assay. Environ. Mol. Mutagen. 17, 264–271.2050134
Cannon, R.E., Spalding, J.W., Trempus, C.S., Szczesniak, C.J., Virgil, K.M., Humble, M.C., and Tennant, R.W. (1997). Kinetics of wound-induced v-Ha-ras transgene expression and papilloma in transgenic Tg.AC mice. Mol. Carcinog. 20, 108–114.9328441
Carpenter, C.P., Weil, C.S., and Smyth, H.F., Jr. (1974). Range-finding toxicity data: List VIII. Toxicol. Appl. Pharmacol. 28, 313–319.4854023
Celanese Chemical Company, Inc. (1982). Multifunctional Acrylates. Safety and Handling Manual. Celanese Chemical Company, New York.
Clemmensen, S. (1984). Cross-reaction patterns in guinea pigs sensitized to acrylic monomers. Drug Chem. Toxicol. 7, 527–540.6534730
Code of Federal Regulations (CFR) 21, Part 58.
Cofield, B.G., Storrs, F.J., and Strawn, C.B. (1985). Contact allergy to aziridine paint hardener. Arch. Dermatol. 121, 373–376.3156563
Cox, D.R. (1972). Regression models and life-tables. J. R. Stat. Soc. B34, 187–220.
Crawford, B.D. (1985). Perspectives on the somatic mutation model of carcinogenesis. In Advances in Modern Environmental Toxicology. Mechanisms and Toxicity of Chemical Carcinogens and Mutagens (M.A. Mehlman, W.G. Flamm, and R.J. Lorentzen, Eds.), pp. 13–59. Princeton Scientific Publishing Co., Inc., Princeton, NJ.
Dahlquist, I., Fregert, S., and Trulson, L. (1983). Contact allergy to trimethylolpropane triacrylate (TMPTA) in an aziridine plastic hardener. Contact Dermatitis 9, 122–124.6221863
Dearfield, K.L., Millis, C.S., Harrington-Brock, K., Doerr, C.L., and Moore, M.M. (1989). Analysis of the genotoxicity of nine acrylate/methacrylate compounds in L5178Y mouse lymphoma cells. Mutagenesis 4, 381–393.2687634
DePass, L.R., Maronpot, R.R., and Weil, C.S. (1985). Dermal oncogenicity bioassays of monofunctional and multifunctional acrylates and acrylate-based oligomers. J. Toxicol. Environ. Health 16, 55–60.4068056
DiGiovanni, J. (1991). Modification of multistage skin carcinogenesis in mice. Prog. Exp. Tumor Res. 33, 192–229.1902960
Dixon, W.J., and Massey, F.J., Jr. (1951). Introduction to Statistical Analysis, 1st ed., pp. 145–147. McGraw-Hill Book Company, Inc., New York.
Dunn, O.J. (1964). Multiple comparisons using rank sums. Technometrics 6, 241–252.
Dunnett, C.W. (1955). A multiple comparison procedure for comparing several treatments with a control. J. Am. Stat. Assoc. 50, 1096–1121.
Dunson, D.B., Haseman, J.K., van Birgelen, A.P.J.M., Stasiewicz, S., and Tennant, R.W. (2000). Statistical analysis of skin tumor data from Tg.AC mouse bioas says. Toxicol. Sci. 55, 293–302.10828260
Eastin, W.C., Haseman, J.K., Mahler, J.F., and Bucher, J.R. (1998). The National Toxicology Program evaluation of genetically altered mice as predictive models for identifying carcinogens. Toxicol. Pathol. 26, 461–473.9715504
Eastin, W.C., Mennear, J.H., Tennant, R.W., Stoll, R.E., Branstetter, D.G., Bucher, J.R., McCullough, B., Binder, R.L., Spalding, J.W., and Mahler, J.F. (2001). Tg.AC genetically altered mouse: Assay working group overview of available data. Toxicol. Pathol. 29, 60–80.11695563
Emmett, E.A. (1977). Contact dermatitis from poly-functional acrylic monomers. Contact Dermatitis 3, 245–248.145343
Enzmann, H., Bomhard, E., Iatropoulos, M., Ahr, H.J., Schlueter, G., and Williams, G.M. (1998). Short- and intermediate-term carcinogenicity testing – a review. Part 1: The prototypes mouse skin tumour assay and rat liver focus assay. Food Chem. Toxicol. 36, 979–995.9771562
Garabrant, D.H. (1985). Dermatitis from aziridine hardener in printing ink. Contact Dermatitis 12, 209–212.3160531
Hennings, H., Glick, A.B., Greenhalgh, D.A., Morgan, D.L., Strickland, J.E., Tennenbaum, T., and Yuspa, S.H. (1993). Critical aspects of initiation, promotion, and progression in multistage epidermal carcinogenesis. Proc. Soc. Exp. Biol. Med. 202, 1–18.8424089
Hollander, M., and Wolfe, D.A. (1973). Nonparametric Statistical Methods, pp. 120–123. John Wiley and Sons, New York.
Honchel, R., Rosenzweig, B.A., Thompson, K.L., Blanchard, K.T., Furst, S.M., Stoll, R.E., and Sistare, F.D. (2001). Loss of palindromic symmetry in Tg.AC mice with a nonresponder phenotype. Mol. Carcinog. 30, 99–100.11241757
Integrated Laboratory Systems (ILS) (1990). Micronucleus Data Management and Statistical Analysis Software, Version 1.4. ILS, P.O. Box 13501, Research Triangle Park, NC 27707.
Jonckheere, A.R. (1954). A distribution-free k-sample test against ordered alternatives. Biometrika 41, 133–145.
Kaplan, E.L., and Meier, P. (1958). Nonparametric estimation from incomplete observations. J. Am. Stat. Assoc. 53, 457–481.
Kirk-Othmer Encyclopedia of Chemical Technology (1978). 3rd ed. (M. Grayson and D. Eckroth, Eds.), Vol. 3, pp. 789–790. John Wiley and Sons, New York.
Leder, A., Kuo, A., Cardiff, R.D., Sinn, E., and Leder, P. (1990). v-Ha-ras transgene abrogates the initiation step in mouse skin tumorigenesis: Effects of phorbol esters and retinoic acid. Proc. Natl. Acad. Sci. U.S.A. 87, 9178–9182.2251261
Lenga, R.E., Ed. (1988). The Sigma-Aldrich Library of Chemical Safety Data, ed. 2, Vol. II, p. 2700. Sigma-Aldrich Corporation, Milwaukee.
Liu, E.T. (1990). The role of ras gene mutations in myeloproliferative disorders. Clin. Lab. Med. 10, 797–807.2272174
Long, R.E., Knutsen, G., and Robinson, M. (1986). Myeloid hyperplasia in the SENCAR mouse: Differentiation from granulocytic leukemia. Environ. Health Perspect. 68, 117–123.3465532
McConnell, E.E., Solleveld, H.A., Swenberg, J.A., and Boorman, G.A. (1986). Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. JNCI 76, 283–289.3456066
MacGregor, J.T., Wehr, C.M., Henika, P.R., and Shelby, M.D. (1990). The in vivo erythrocyte micronucleus test: Measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam. Appl. Toxicol. 14, 513–522.2111256
Mahler, J.F., Flagler, N.D., Malarkey, D.E., Mann, P.C., Haseman, J.K., and Eastin, W. (1998). Spontaneous and chemically induced proliferative lesions in Tg.AC transgenic and p53-heterozygous mice. Toxicol. Pathol. 26, 501–511.9715509
Maronpot, R.R., and Boorman, G.A. (1982). Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol. Pathol. 10, 71–80.28094716
Maurice, P.D.L., and Rycroft, R.J.G. (1986). Allergic contact dermatitis from UV-curing acrylate in the manufacture of optical fibres. Contact Dermatitis 15, 92–93.
Miller, J.A., and Miller, E.C. (1977). Ultimate chemical carcinogens as reactive mutagenic electrophiles. In Origins of Human Cancer (H.H. Hiatt, J.D. Watson, and J.A. Winsten, Eds.), pp. 605–627. Cold Spring Harbor Laboratory, Cold Spring Harbor, NY.
Moore, M.M., Harrington-Brock, K., Doerr, C.L., and Dearfield, K.L. (1989). Differential mutant quantitation at the mouse lymphoma tk and CHO hgprt loci. Mutagenesis 4, 394–403.2687635
Morrison, D.F. (1976). Multivariate Statistical Methods, 2nd ed., pp. 170–179. McGraw-Hill Book Company, New York.
Nagase, H., Bryson, S., Fee, F., and Balmain, A. (1996). Multigenic control of skin tumour development in mice. In 1996 Variation in the Human Genome (Ciba Foundation Symposium 197), pp. 156–180. Wiley, Chichester, England.
National Institute for Occupational Safety and Health (NIOSH) (1987). Health Hazard Evaluation Report (HETA 83-458-1800), for Tropicana Products, Bradenton, FL.
National Institute for Occupational Safety and Health (NIOSH) (1990). National Occupational Exposure Survey (1981-1983), unpublished provisional data as of July 1, 1990. NIOSH, Cincinnati, OH.
National Toxicology Program (NTP) (1986a). Carcinogenesis Studies of Ethyl Acrylate (CAS No. 140-88-5) in F344/N Rats and B6C3F_1_ Mice (Gavage Studies). Technical Report Series No. 259. NIH Publication No. 87-2515. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (1986b). Toxicology and Carcinogenesis Studies of Methyl Methacrylate (CAS No. 80-62-6) in F344/N Rats and B6C3F_1_ Mice (Inhalation Studies). Technical Report Series No. 314. NIH Publication No. 87-2570. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (1992). Toxicology and Carcinogenesis Studies of Resorcinol (CAS No. 108-46-3) in F344/N Rats and B6C3F_1_ Mice (Gavage Studies). Technical Report Series No. 403. NIH Publication No. 92-2858. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (2005). Toxicology Studies of Pentaerythritol Triacrylate (Technical Grade) (CAS No. 3524-68-3) in F344/N Rats, B6C3F_1_ Mice, and Genetically Modified (FVB Tg.AC Hemizygous) Mice (Dermal Studies). GMM Report Series No. 4. NIH Publication No. 06-4451. U.S. Department of Health and Human Services, Public Heath Service, National Institutes of Health, Research Triangle Park, NC.
Nessel, C.S., Freeman, J.J., Forgash, R.C., and McKee, R.H. (1999). The role of dermal irritation in the skin tumor promoting activity of petroleum middle distillates. Toxicol. Sci. 49, 48–55.10367341
Nethercott, J.R. (1978). Skin problems associated with multifunctional acrylic monomers in ultraviolet curing inks. Br. J. Dermatol. 98, 541–552.148898
Nethercott, J.R., Jakubovic, H.R., Pilger, C., and Smith, J.W. (1983). Allergic contact dermatitis due to urethane acrylate in ultraviolet cured inks. Br. J. Ind. Med. 40, 241–250.6223656
Nylander-French, L.A., and French, J.E. (1998). Tripropylene glycol diacrylate but not ethyl acrylate induces skin tumors in a twenty-week short-term tumorigenesis study in Tg.AC (v-Ha-ras) mice. Toxicol. Pathol. 26, 476–483.9715506
Parker, D., and Turk, J.L. (1983). Contact sensitivity to acrylate compounds in guinea pigs. Contact Dermatitis 9, 55–60.6839739
Parker, D., Long, P.V., Bull, J.E., and Turk, J.L. (1985). Epicutaneous induction of tolerance with acrylates and related compounds. Contact Dermatitis 12, 146–154.3995943
Piegorsch, W.W., and Bailer, A.J. (1997). Statistics for Environmental Biology and Toxicology, Section 6.3.2. Chapman and Hall, London.
Portier, C.J., and Bailer, A.J. (1989). Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam. Appl. Toxicol. 12, 731–737.2744275
Portier, C.J., Hedges, J.C., and Hoel, D.G. (1986). Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 46, 4372–4378.3731095
Pritchard, J.B., French, J.E., Davis, B.J., and Haseman, J.K. (2003). The role of transgenic mouse models in carcinogen identification. Environ. Health Perspect. 111, 444–454.12676597
Radak, W. (1990). Radiation curing: New market Rx. Chem. Business 12, 19–36.
Shelby, M.D. (1988). The genetic toxicity of human carcinogens and its implications. Mutat. Res. 204, 3–15.3277048
Shelby, M.D., and Zeiger, E. (1990). Activity of human carcinogens in the Salmonella and rodent bone marrow cytogenetics tests. Mutat. Res. 234, 257–261.2366790
Shirley, E. (1977). A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics 33, 386–389.884197
Sistare, F.D., Thompson, K.L., Honchel, R., and DeGeorge, J. (2002). Evaluation of the Tg.AC transgenic mouse assay for testing the human carcinogenic potential of pharmaceuticals — practical pointers, mechanistic clues, and new questions. Int. J. Toxicol. 21, 65–79.11936901
Slaga, T.J., DiGiovanni, J., Winberg, L.D., and Budunova, I.V. (1995). Skin carcinogenesis: Characteristics, mechanisms, and prevention. Prog. Clin. Biol. Res. 391, 1–20.8532708
Spalding, J.W., Momma, J., Elwell, M.R., and Tennant, R.W. (1993). Chemically induced skin carcinogenesis in a transgenic mouse line (Tg.AC) carrying a v-Ha-ras gene. Carcinogenesis 14, 1335–1341.8330346
Spalding, J.W., French, J.E., Tice, R.R., Furedi-Machacek, M., Haseman, J.K., and Tennant, R.W. (1999). Development of a transgenic mouse model for carcinogenesis bioassays: Evaluation of chemically induced skin tumors in Tg.AC mice. Toxicol. Sci. 49, 241–254.10416269
Spalding, J.W., French, J.E., Stasiewicz, S., Furedi-Machacek, M., Conner, F., Tice, R.R., and Tennant, R.W. (2000). Responses of transgenic mouse lines p53(+/−) and Tg.AC to agents tested in conventional carcinogenicity bioassays. Toxicol. Sci. 53, 213–223.10696769
Straus, D.S. (1981). Somatic mutation, cellular differentiation, and cancer causation. JNCI 67, 233–241.7021938
Tarone, R.E. (1975). Tests for trend in life table analysis. Biometrika 62, 679–682.
Tennant, R.W., Stasiewicz, S., Mennear, J., French, J.E., and Spalding, J.W. (1999). Genetically altered mouse models for identifying carcinogens. IARC Sci. Publ. 146, 123–150.
Tennant, R.W., Stasiewicz, S., Eastin, W.C., Mennear, J.H., and Spalding, J.W. (2001). The Tg.AC (v-Ha-ras) transgenic mouse: Nature of the model. Toxicol. Pathol. 29, 51–59.11695562
Thompson, E.D., Seymour, J.L., Aardema, M.J., LeBoeuf, R.A., Evans, B.L.B., and Cody, D.B. (1991). Lack of genotoxicity of cross-linked acrylate polymers in four short-term genotoxicity assays. Environ. Mol. Mutagen. 18, 184–199.1915313
Thompson, K.L, Rosenzweig, B.A., and Sistare, F.D. (1998). An evaluation of the hemizygous transgenic Tg.AC mouse for carcinogenicity testing of pharmaceuticals. II. A genotypic marker that predicts tumorigenic responsiveness. Toxicol. Pathol. 26, 548–555.9715514
Thompson, K.L., Rosenzweig, B.A., Honchel, R., Cannon, R.E., Blanchard, K.T., Stoll, R.E, and Sistare, F.D. (2001). Loss of critical palindromic trans-gene promoter sequence in chemically induced Tg.AC mouse skin papillomas expressing transgene-derived mRNA. Mol. Carcinog. 32, 176–186.11746829
Trempus, C.S., Mahler, J.F., Ananthaswamy, H.N., Loughlin, S.M., French, J.E., and Tennant, R.W. (1998). Photocarcinogenesis and susceptibility to UV radiation in the v-Ha-ras transgenic Tg.AC mouse. J. Invest. Dermatol. 111, 445–451.9740239
U.S. Environmental Protection Agency (USEPA) (1990). TSCAPP: 1983 Production Statistics for Chemicals in the Nonconfidential Initial TSCA Chemical Substances Inventory. Office of Pesticides and Toxic Substances, Washington, D.C.
Van Miller, J.P., Garman, R.H., Hermansky, S.J., Mirsalis, J.C., and Frederick, C.B. (2003). Skin irritation, basal epithelial cell proliferation, and carcinogenicity evaluations of a representative specialty acrylate and methacrylate. Regul. Toxicol. Pharmacol. 37, 54–65.12662909
Williams, D.A. (1971). A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics 27, 103–117.5547548
Williams, D.A. (1972). The comparison of several dose levels with a zero dose control. Biometrics 28, 519–531.5037867
Witt, K.L., Knapton, A., Wehr, C.M., Hook, G.J., Mirsalis, J., Shelby, M.D., and MacGregor, J.T. (2000). Micronucleated erythrocyte frequency in peripheral blood of B6C3F_1_ mice from short-term, prechronic, and chronic studies of the NTP Carcinogenesis Bioassay Program. Environ. Mol. Mutagen. 36, 163–194.11044899
Yamamoto, S., Urano, K., and Nomura, T. (1998). Validation of transgenic mice harboring the human prototype C-Ha-ras gene as a bioassay model for rapid carcinogenicity testing. Toxicol. Lett. 102-103, 473–478.10022298