# NATIONAL TOXICOLOGY PROGRAM BOARD OF SCIENTIFIC COUNSELORS TECHNICAL REPORTS REVIEW SUBCOMMITTEE

The members of the Technical Reports Review Subcommittee who evaluated the draft NTP Report on trimethylolpropane triacrylate on September 6, 2002, are listed below. Subcommittee members serve as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, subcommittee members have five major responsibilities in reviewing the NTP studies:

- to ascertain that all relevant literature data have been adequately cited and interpreted,
- to determine if the design and conditions of the NTP studies were appropriate,
- to ensure that the Report presents the experimental results and conclusions fully and clearly,
- to judge the significance of the experimental results by scientific criteria, and
- to assess the evaluation of the evidence of carcinogenic activity and other observed toxic responses.

- Norman R. Drinkwater, Ph.D., Chairperson
  McArdle Laboratory for Cancer Research
  University of Wisconsin-Madison
  Madison, WI
- Kim Boekelheide, M.D., Ph.D.
  Division of Biology and Medicine
  Department of Pathology and Laboratory Medicine
  Brown University
  Providence, RI
- Michael R. Elwell, D.V.M., Ph.D., Principal Reviewer
  Pfizer, Inc.
  Groton, CT
- Shuk-Mei Ho, Ph.D.
  Department of Surgery, Division of Urology
  University of Massachusetts Medical School
  Worcester, MA
- James E. Klaunig, Ph.D.
  Division of Toxicology
  Department of Pharmacology and Toxicology
  Indiana University School of Medicine
  Indianapolis, IN
- Walter W. Piegorsch, Ph.D., Principal Reviewer
  Department of Statistics
  University of South Carolina
  Columbia, SC
- Stephen M. Roberts, Ph.D.
  Department of Physiological Sciences
  College of Veterinary Medicine
  University of Florida
  Gainesville, FL
- Richard D. Storer, M.P.H., Ph.D., Principal Reviewer
  Department of Genetic and Cellular Toxicology
  Merck Research Laboratories
  West Point, PA
- Mary Anna Thrall, D.V.M.
  Department of Pathology
  College of Veterinary Medicine and Biomedical Sciences
  Colorado State University
  Fort Collins, CO
- Mary Vore, Ph.D.
  Graduate Center for Toxicology
  University of Kentucky
  Lexington, KY
- Cheryl Lyn Walker, Ph.D.
  M.D. Anderson Cancer Center
  The University of Texas
  Smithville, TX