# DISCUSSION AND CONCLUSIONS

Trimethylolpropane triacrylate and pentaerythritol triacrylate are representative multifunctional acrylates. Chemically, multifunctional acrylates are esters of acrylic acid esterified to a polyhydroxy backbone molecule. Trimethylolpropane triacrylate is a triester of acrylic acid with trimethylol propane, and pentaerythritol triacrylate is a triester of acrylic acid with pentaerythritol.

Monofunctional acrylates, such as ethyl acrylate, and multifunctional acrylates, such as trimethylolpropane triacrylate and pentaerythritol triacrylate, readily undergo free radical polymerization initiated by a peroxy compound or by ultraviolet light. They are therefore used in photocurable inks and in other applications requiring the use of photocurable resins. Multifunctional acrylates are also used in glues and adhesives and in the manufacture of acrylic-based paints. The NTP studied trimethylol propane triacrylate and pentaerythritol triacrylate for toxicity and carcinogenicity. Results of the pentaerythritol triacrylate studies are reported separately (NTP, 2005).

Human exposure to multifunctional acrylates has been documented only in occupational settings and has involved primarily dermal exposure (NIOSH, 1990). Workers involved in the manufacture, processing, product handling, and application of trimethylolpropane triacrylate are at risk of exposure (AIHA, 1981). However, the widespread use of these compounds in the manufacture of consumer products such as certain glues, adhesives, and paints suggests a potential for significant nonoccupational exposure (Dearfield et al., 1989).

From the available data in the literature, the critical effects of multifunctional acrylates are skin and eye irritation. Also, some members of the multifunctional acrylate class are moderate to strong sensitizers in humans, but findings in animals are conflicting. Trimethylolpropane triacrylate was not detected as a sensitizer in repeated-insult patch testing or in guinea pigs using the Buehler method. However, trimethylol propane triacrylate was positive in a guinea pig maximization test (Andrews and Clary, 1986). The NTP has tested trimethylolpropane triacrylate for its ability to induce hypersensitivity and irritancy in a rodent model (Appendix K). Trimethylolpropane triacrylate was found to be an irritant in BALB/c mice at concentrations greater than 0.25%. There was no significant difference compared to the vehicle controls at any single dose in the local lymph node assay. Results of the mouse ear-swelling test were negative at both 24 and 48 hours after dosing for the trimethylolpropane triacrylate concentrations studied. Overall, the studies in BALB/c mice suggest that trimethylolpropane triacrylate is an irritant but not a contact sensitizer.

Repeated dermal exposure to acrylates including trimethylolpropane triacrylate led to contact dermatitis in laboratory animals and humans (Andrews and Clary, 1986); the current 2-week and 3-month studies confirmed these findings. Skin was the major target organ of trimethylolpropane triacrylate toxicity in the current studies. The chemical caused dose-related hyperplastic, vacuolar degenerative, and ultimately necrotizing lesions of the epidermis, accompanied by hyperplasia of sebaceous glands and a chronic dermal inflammation in both sexes of rats and mice. Rats had slightly more severe skin lesions than mice in the 2-week and 3-month studies. Although trimethylolpropane triacrylate is absorbed through skin as shown by additional NTP studies (Appendix L), systemic toxicity was minimal, based on clinical pathology, histopathology, and organ weight findings. In rats, a no-observed-adverse-effect level (NOAEL) was not attained; the NOAEL was determined to be 0.75 mg/kg in mice.

The dose-related skin effects such as inflammation and sustained hyperplasia at the site of application in rats and mice in the 3-month studies suggested trimethylol propane triacrylate may be a dermal carcinogen. Several studies have established that the induction of sustained cellular hyperplasia correlates well with the skin tumor formation ability of various tumor-promoting agents such as phorbol esters, several peroxides, and chrysarobin (Argyris, 1981; Hennings et al., 1993; Slaga et al., 1995). NTP typically performs carcinogenicity studies in two species, rats and mice. Because skin was the only major target organ of toxicity in the 2-week and 3-month studies, dermal carcinogenicity studies were conducted in mice only. For more than 60 years, studies have established the mouse as a sensitive animal model for epidermal carcinogenesis induced by chemical carcinogens (DiGiovanni, 1991). In addition, the mouse is also thought to be an appropriate model for skin squamous cell cancer development in humans because of evidence that known genetic aberrations in tumor cells are similar in human and mouse skin, especially mutational activation of the H-ras oncogene (Nagase et al., 1996).

Leder et al. (1990) developed a transgenic mouse model with an inducible zeta-globin promoter driving the expression of a mutated v-H-ras oncogene (the Tg.AC mouse). With the exception of the bone marrow, constitutive expression of the transgene cannot be detected in adult tissues. The transgene is transcriptionally silent until activated by full-thickness wounding, ultraviolet light, or specific chemical exposure (Cannon et al., 1997; Trempus et al., 1998). Topical application of carcinogens to the shaved dorsal surface of Tg.AC mice induces epidermal squamous cell papillomas or carcinomas, a reporter phenotype that defines the activity of the chemical. The oral route of administration can also generate tumorigenic responses in Tg.AC mice and result in squamous cell papillomas or carcinomas of the forestomach. To date, the induction of either spontaneous or induced tumors has been shown to require activation of transgene expression. Thus, the Tg.AC model could be viewed as genetically initiated due to the presence of the transgene. The model responds to both genotoxic and nongenotoxic carcinogens (Spalding et al., 1999, 2000; Tennant et al., 2001).

When the current 3-month studies in rats and mice were completed, the NTP was evaluating several transgenic mouse models to supplement or replace the traditional 2-year bioassay studies in mice. The major route of human exposure to trimethylolpropane triacrylate is via the skin, and at the time of study design, the Tg.AC mouse model was showing promise for carcinogenicity testing (hazard identification) via dermal exposure. Efforts were under way to more fully assess the model’s potential. Therefore, the NTP decided to conduct initial studies in the Tg.AC model, and upon completion of these studies, assess their findings in light of updated information about the Tg.AC model. Even if testing in additional species or strains were necessary, the Tg.AC studies would add to the body of knowledge concerning the Tg.AC model’s potential. This allowed assessment of the Tg.AC model in a completely prospective manner. The Tg.AC mouse model’s usefulness and limitations in detecting chemical carcinogens have since been evaluated (Spalding et al., 2000; Eastin et al., 2001; Tennant et al., 2001; Pritchard et al., 2003; Sistare et al., 2002).

For the current 6-month dermal study in Tg.AC mice, the selected doses were based on the results of the 2-week and 3-month studies in F344/N rats and B6C3F_1_ mice. Others have used 2- to 4-week studies in the Tg.AC mouse or FVB/N wildtype parent strain for dose range-finding studies (Tennant et al., 1999; Eastin et al., 2001). However, the dermal response to compounds was not expected to differ markedly between the mouse strains. While some information may have been lost by use of a different mouse strain, in this case, additional information concerning the effects of trimethylolpropane triacrylate on the skin was also gained by the use of two species and the conduct of a 3-month study rather than the typically shorter Tg.AC range-finding study.

When selecting doses for a 2-year dermal study based on 3-month study findings, dose concentrations that cause ulceration, necrosis, or marked inflammation or hyperplasia at the site of application are generally avoided. Therefore, because of the presence of mild necrosis and minimal to mild degeneration and suppurative inflammation, 12 mg/kg would not have been selected for use in a 2-year study. These pathologic alterations are consistent with the irritation identified grossly in the 12 mg/kg group in the 3-month study. Necrosis and degeneration occurred in fewer animals and/or with lesser severity in the 6 mg/kg group and hardly at all in lower dose groups. However, because doses were being selected for a different strain and for a 6-month rather than a 2-year study, five dose groups were used, and 12 mg/kg was the highest dose used.

In mouse dermal carcinogenicity studies, squamous cell papillomas are used as an endpoint of the assay. Some of these papillomas have the potential to progress to squamous cell carcinomas, so they may be regarded as precursor neoplasms and may be used as a quantitative indicator of a carcinogenic process (Enzmann et al., 1998). The results of the current 6-month study clearly show the carcinogenic activity of trimethylolpropane triacrylate at the site of application in Tg.AC mice. The increased incidences of squamous cell papilloma were doserelated in males and females; and the incidences were significantly increased in 6 and 12 mg/kg males and females. Squamous cell carcinomas occurred in a few female mice and their presence at the base of a papilloma in some mice suggested the carcinoma arose from the papilloma.

In the 6-month study, most animals in the 6 and 12 mg/kg groups had epidermal hyperplasia, hyperkeratosis, and chronic active inflammation at the site of application. The incidences of these nonneoplastic lesions were much lower in groups administered 3 mg/kg or less. Histologic evaluation of the skin for nonneoplastic lesions in the presence of multiple papillomas can be problematic, and there was often a significant amount of inflammation associated with the neoplasms. However, minimal to mild nonneoplastic lesions were also observed in the standard sections of skin at the site of application in which neoplasms were generally not present. Also, similar lesions as well as more severe lesions such as necrosis and degeneration were observed in B6C3F_1_ mice at 3 months. Therefore the nonneoplastic lesions were likely primary and not secondary to the papillomas. In the 3-month study in B6C3F_1_ mice, the more severe lesions (necrosis, degeneration, and suppurative inflammation) at the site of application occurred primarily at the same doses, 6 and 12 mg/kg, at which neoplasms occurred in Tg.AC mice. However, epidermal hyperplasia and chronic active inflammation, although more severe in the 6 and 12 mg/kg groups, also occurred in 3 mg/kg mice in the 3-month study.

An increase in cell replication enhances all steps of neoplastic transformation and tumor development (Enzmann et al., 1998). In a study of resorcinol, increased incidences of neoplasms occurred in males and females concurrently with epidermal hyperplasia and in males concurrently with inflammation and sebaceous gland hyperplasia (NTP, 1992; Eastin et al., 1998). However, in an NTP dermal carcinogenicity study on rotenone in Tg.AC mice, no skin papillomas were observed, despite extensive hyperplasia and inflammation in the skin at the site of application (Plate 10; Eastin et al., 1998). This result suggests that the relationship between nonneoplastic lesions of the skin and papilloma induction is complex.

In some instances, such as with diethylstilbestrol, chemically induced skin neoplasms occurred in the absence of nonneoplastic effects (Eastin et al., 1998). Dinitrofluorobenzene caused an increase in skin neoplasms in the Tg.AC mouse that was concluded to be associated with the cytotoxic action of the chemical to the skin (Albert et al., 1996). The authors proposed that the response to dinitrofluorobenzene may be analogous to physical wounding, which promotes neoplasms in normal animals (Argyris, 1980), as well as in the Tg.AC mouse (Spalding et al., 1993). Why chemical or physical wounding causes neoplasm promotion is not known, but may involve both cell damage and inflammation.

Insertion of the zeta-globin promoted v-Ha-ras trans-gene into the FVB mouse genome (Tg.AC) introduces a defined genetic lesion that is critical but insufficient by itself to induce benign or malignant tumors in skin unless activated. Activation and expression of the transgenic ras oncoprotein in this mouse line induces dose-related increases in papilloma (skin reporter phenotype) within weeks. In the current 6-month study, trimethylol propane triacrylate induced dose-related increases in the incidence of squamous cell papilloma at the site of application, with neoplasms appearing as early as 9 weeks into the study. Some papillomas in female mice appeared to progress to carcinoma. Two other multi functional acrylates, tripropylene glycol diacrylate (Nylander-French and French, 1998) and pentaerythritol triacrylate (NTP, 2005) also induced skin papillomas in this model, suggesting the model is responsive to multi functional acrylates. The Tg.AC model appears to respond to both genotoxic and nongenotoxic carcinogens. Chemically induced sustained cell proliferation may be an important component of the multistage process of mouse skin carcinogenesis, particularly for nongenotoxic carcinogens.

In one previous study, no carcinogenic activity was noted in mice exposed to trimethylolpropane triacrylate. Dermal carcinogenicity studies on eight multifunctional acrylates including trimethylolpropane triacrylate were conducted by the Celanese Corporation in C3H/HeJ mice (Andrews and Clary, 1986). Trimethylolpropane triacrylate was administered to the intrascapular region of the skin at a dose level of 100 mg/kg in mineral oil twice weekly for 80 weeks. No skin tumors or systemic lesions were observed. The absence of carcinogenic activity in that study may be due to differences in study design and strain of mouse used. The dose level, 100 mg/kg, was more than eight times the current study’s highest dose. No major effects on the skin were noted, most likely due to the use of mineral oil as a vehicle. Mineral oil is known to ameliorate the irritating properties of chemicals (Nessel et al., 1999).

The only systemic neoplastic effect seen in the current 6-month trimethylolpropane triacrylate study was an increased incidence of squamous cell papilloma of the forestomach in 12 mg/kg female mice that exceeded the historical control values in Tg.AC mice (Mahler et al., 1998). The incidence of forestomach squamous cell papilloma in 12 mg/kg females was significantly higher than that in the controls (60% and 27%, respectively) and well above reported historical control rates of 10% (Mahler et al., 1998) and 25% (Eastin et al., 2001). The background rate of forestomach neoplasms appears highly variable; rates of 40% to 75% have been reported in some dietary studies performed in homozygous Tg.AC mice (Sistare et al., 2002). Because of the limited historical control data available and the lack of a dose-related response in the current study, the relationship between forestomach papillomas and trimethylol propane triacrylate administration is uncertain.

Another systemic change diagnosed in several dosed male and female TG.AC mice involved one to several organs and had characteristics that variably resembled hematopoietic, inflammatory, and neoplastic processes. The most consistent presentation was an aberrant infiltration and/or proliferation of granulocyte-rich inflammatory cells. The major granulocyte component was the eosinophil, an inflammatory cell type usually associated with immune reactions or parasitic infections. The liver was the organ most frequently affected, although other tissues (lymph nodes, spleen, lung, kidney and epididymis) were also affected. The bone marrow, a site that would be expected to be affected, was not microscopically examined in these studies. Because of the variable morphology and uncertain biological behavior, assigning an appropriate diagnostic term was problematic. In its more severe form, the lesion may have resulted from infiltration and/or proliferation, and was diagnosed as myelodysplasia (Mahler et al., 1998). In milder cases, component cells appeared more infiltrative and the change was diagnosed as cellular infiltration. Separating the milder lesions from inflammation and extramedullary hematopoiesis was difficult.

This lesion complex, even in the severe state, appears to be nonneoplastic. This determination is based primarily on morphologic criteria used to distinguish granulocytic hyperplasia and granulocytic leukemia (Long et al., 1986), including the presence of granulocytes in multiple stages of maturation, as well as cells from other lineages such as megakaryocytes. In addition, recent studies suggest that myelodysplasia is a reversible lesion when the inciting chemical stimulus is withdrawn (C. Trempus, personal communication), further suggesting that it is a nonneoplastic process. Myelodysplasia has been previously reported in only one other Tg.AC mouse study of rotenone (Mahler et al., 1998). It has not been observed in untreated Tg.AC mice, and was not present in the vehicle controls in the current study. It has not been reported in other strains of mice; however, in subsequent studies of rotenone involving the Tg.AC and the parent FVB/N strain, it was identified in both (R. Maronpot, personal communication). In the rotenone study, epidermal hyperplasia and dermal inflammation were found at the site of application, but squamous papillomas were not induced, indicating that epidermal tumors are not required for the induction of myelodysplasia (Eastin et al., 1998). Since ras mutations are associated with myeloproliferative disorders (Liu, 1990), the activated v-Ha-ras oncogene in the genome of Tg.AC mice may predispose this strain to exuberant hematopoietic proliferation and infiltration, and myelodysplasia may be one manifestation of this genomic defect, triggered by an inflammatory stimulus (e.g., the skin). It is also possible that myelodysplasia represents an atypical hypersensitivity reaction in this strain. Clearly additional studies are needed to further clarify the biology of this lesion.

Hematopoietic cell proliferation occurred in the liver, spleen, and lymph nodes of animals in the 6 and 12 mg/kg groups. This reaction may have been at least partially due to the inflammatory stimulus at the skin site of application. Enhanced expression of hematopoietic cytokines by mouse epidermal tumor cells has also been demonstrated (Bauluz et al., 1994), suggesting that some of this response may have been due to treatment-induced squamous papillomas at the site of application.

The NTP has studied two monofunctional acrylates, ethyl acrylate (NTP, 1986a) and methyl methacrylate (NTP, 1986b) for carcinogenicity. Ethyl acrylate administered by gavage produced squamous cell papillomas in the forestomach of rats and mice at doses that also induced considerable nonneoplastic pathology. Interestingly, ethyl acrylate was negative when dermally administered in the Tg.AC model (Nylander-French and French, 1998) and positive when administered by gavage to a short-term ras model, the ras H2 mouse (Yamamoto et al., 1998). Methyl methacrylate was not carcinogenic in rats or conventional mice when administered via inhalation for 2 years (NTP, 1986b). Of the eight multifunctional acrylates studied by the Celanese Corporation, two induced skin tumors at the site of application (Andrews and Clary, 1986). All these studies suggest that carcinogenic activity of acrylates is expressed at the site of application only.

Repeated dermal administration of trimethylolpropane triacrylate in the current study caused sustained epidermal cell proliferation and led to formation of papillomas, a major characteristic of the known neoplasm promoters. The evidence of a limited and weak mutagenic response with trimethylolpropane triacrylate in the Salmonella assay (Cameron et al., 1991) might support a nongenotoxic mode of action for this chemical. However, the positive results from other in vitro genotoxicity assays employing endpoints that are associated with chromosomal breakage events (Dearfield et al., 1989; Moore et al., 1989; Cameron et al., 1991) also indicate a potential for a genotoxic mode of action. Based on the current evidence, it is difficult to classify trimethylolpropane triacrylate as either a genotoxic or nongenotoxic carcinogen. Additional studies are needed to understand the mechanism of skin neoplasm formation by trimethylolpropane triacrylate.

## Conclusions

Male and female Tg.AC hemizygous mice dosed with trimethylolpropane triacrylate for 6 months had significantly increased incidences and multiplicity of papillomas of the skin at the site of dermal application. Treatment-related squamous cell carcinomas occurred at the site of application in dosed female mice. Increased incidences of forestomach squamous cell papilloma in female mice may have been related to chemical administration.

Increased incidences of minimal to moderate (mostly mild) hyperplasia of the epidermis, hyperkeratosis, and chronic active inflammation also occurred at the site of application. A hematopoietic disorder (myelodysplasia) also occurred in dosed male and female mice.