# RESULTS

## Rats 2-Week Study

All rats survived to the end of the study (Table 2). Final mean body weights and body weight gains of all dosed groups were similar to those of the vehicle control groups. Dosed rats had irritation at the site of application; this clinical finding was most commonly seen in rats administered 50 mg/kg or greater.

TABLE 2 Survival and Body Weights of Rats in the 2-Week Dermal Study of Trimethylolpropane Triacrylate

Dose (mg/kg) | Survival^a^ | Mean Body Weight^b^ (g) | | | Final Weight Relative to Controls (%)
Dose (mg/kg) | Survival^a^ | Initial | Final | Change | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 97 ± 2 | 170 ± 6 | 73 ± 4
12.5 | 5/5 | 97 ± 3 | 162 ± 6 | 66 ± 5 | 96
25 | 5/5 | 97 ± 2 | 167 ± 4 | 70 ± 4 | 98
50 | 5/5 | 96 ± 3 | 163 ± 8 | 67 ± 5 | 96
100 | 5/5 | 96 ± 2 | 163 ± 3 | 67 ± 3 | 96
200 | 5/5 | 96 ± 2 | 155 ± 4 | 59 ± 4 | 91
Female
0 | 5/5 | 86 ± 2 | 124 ± 3 | 38 ± 1
12.5 | 5/5 | 85 ± 1 | 124 ± 3 | 39 ± 1 | 100
25 | 5/5 | 86 ± 1 | 122 ± 1 | 35 ± 2 | 98
50 | 5/5 | 86 ± 2 | 122 ± 2 | 36 ± 2 | 98
100 | 5/5 | 87 ± 1 | 128 ± 5 | 41 ± 4 | 104
200 | 5/5 | 86 ± 1 | 118 ± 2 | 32 ± 2 | 95

a Number of animals surviving at 2 weeks/number initially in group

b Weights and weight changes are given as mean ± standard error.

There were no biologically significant organ weight changes (Table F1). At necropsy, all dosed groups except 12.5 mg/kg females had crusts at the site of application (data not shown), and the incidence generally increased with increasing dose. Microscopically, lesions occurred at the site of application in all dosed groups (Table 3). Epidermal hyperplasia, hyperkeratosis, and sebaceous gland hyperplasia were found in most treated rats, and were characterized by increased layers of epidermal cells, thickened keratin layer, and prominence of sebaceous glands. Chronic active inflammation (mixed inflammatory cell infiltration) of the dermis also occurred in most rats. More severe lesions occurring generally at doses of 25 mg/kg or greater were ulcer (focal full-thickness necrosis of the epidermis), degeneration (vacuolar change of epidermal cells), parakeratosis (retention of nuclei in keratin layer), and accumulation of neutrophils (suppurative inflammation) in the degenerative and parakeratotic areas of the superficial epidermis. These lesions were not seen in the vehicle controls, and their severity generally increased with increasing dose.

Dose Selection Rationale: Lesions at the site of application occurred in all dose groups. Their severity generally increased with increasing dose and was moderate to marked in the higher dose groups. The incidences and severities of some of the changes (ulcers and suppurative inflammation) precluded use of 25 mg/kg or greater in a 3-month study; therefore, 0.75, 1.5, 3, 6, and 12 mg/kg were selected for use in the 3-month study in rats.

TABLE 3 Incidences of Nonneoplastic Lesions of the Skin (Site of Application) in Rats in the 2-Week Dermal Study of Trimethylolpropane Triacrylate

| Vehicle Control | 12.5 mg/kg | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
Male
Number Examined
Microscopically | 5 | 5 | 5 | 5 | 5 | 5
Epidermis, Hyperplasia^a^ | 0 | 5^**^ (1.4)^b^ | 5^**^ (1.8) | 5^**^ (2.6) | 5^**^ (3.2) | 5^**^ (3.4)
Hyperkeratosis | 0 | 5^**^ (1.6) | 5^**^ (1.2) | 5^**^ (2.4) | 5^**^ (2.0) | 5^**^ (2.0)
Sebaceous Glands, Hyperplasia | 0 | 5^**^ (2.0) | 5^**^ (1.8) | 5^**^ (2.8) | 5^**^ (2.2) | 5^**^ (2.0)
Dermis, Inflammation, Chronic Active | 0 | 5^**^ (1.6) | 5^**^ (2.0) | 5^**^ (2.8) | 5^**^ (2.8) | 5^**^ (3.4)
Ulcer | 0 | 1 (2.0) | 1 (1.0) | 5^**^ (2.2) | 5^**^ (2.6) | 5^**^ (2.8)
Epidermis, Degeneration | 0 | 4^*^ (1.3) | 4^*^ (1.0) | 5^**^ (2.4) | 5^**^ (2.6) | 5^**^ (3.2)
Parakeratosis | 0 | 1 (1.0) | 4^*^ (1.8) | 5^**^ (2.6) | 5^**^ (3.2) | 5^**^ (3.8)
Epidermis, Inflammation, Suppurative | 0 | 2 (1.5) | 5^**^ (1.8) | 5^**^ (3.0) | 5^**^ (3.0) | 5^**^ (3.8)
Female
Number Examined
Microscopically | 5 | 5 | 5 | 5 | 5 | 5
Epidermis, Hyperplasia | 0 | 5^**^ (1.2) | 5^**^ (2.0) | 5^**^ (2.6) | 5^**^ (3.2) | 5^**^ (3.6)
Hyperkeratosis | 0 | 5^**^ (1.0) | 5^**^ (1.4) | 5^**^ (1.2) | 5^**^ (2.0) | 3^*^ (2.0)
Sebaceous Glands, Hyperplasia | 0 | 5^**^ (1.4) | 5^**^ (2.0) | 5^**^ (2.2) | 5^**^ (2.2) | 5^**^ (1.8)
Dermis, Inflammation, Chronic Active | 0 | 3^*^ (1.0) | 5^**^ (2.0) | 5^**^ (2.8) | 5^**^ (3.0) | 5^**^ (3.4)
Ulcer | 0 | 0 | 4^*^ (1.5) | 5^**^ (3.2) | 5^**^ (2.6) | 5^**^ (3.0)
Epidermis, Degeneration | 0 | 1 (1.0) | 5^**^ (2.2) | 5^**^ (3.0) | 5^**^ (3.0) | 5^**^ (3.0)
Parakeratosis | 0 | 3^*^ (1.7) | 5^**^ (2.2) | 5^**^ (3.0) | 5^**^ (3.0) | 5^**^ (3.2)
Epidermis, Inflammation, Suppurative | 0 | 1 (1.0) | 4^*^ (2.0) | 5^**^ (3.0) | 5^**^ (3.4) | 5^**^ (3.2)

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

** P≤0.01

a Number of animals with lesion

b Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## 3-Month Study

All rats survived to the end of the study. Final mean body weights and body weight gains in dosed groups were similar to those of the vehicle controls (Table 4 and Figure 1). Irritation at the site of application was noted in five males and all females administered 12 mg/kg.

Hematology and clinical chemistry data for rats in the 3-month dermal study of trimethylolpropane triacrylate are listed in Table E1. Segmented neutrophil counts were increased in 12 mg/kg males and females at week 14; the increase in males was significant. These increases would be consistent with the suppurative dermatitis observed microscopically. Decreased lymphocyte counts in males at week 14 would be consistent with a stress-related response.

Absolute and relative thymus weights of 12 mg/kg males, absolute thymus weights of 0.75, 6, and 12 mg/kg females, and relative thymus weights of 0.75 and 12 mg/kg females were significantly less than those of the vehicle controls (Table F2). Other organ weight changes were not considered biologically significant. Left testis weights were significantly decreased in 12 mg/kg male rats (Table G1). There were no significant differences in vaginal cytology parameters between dosed and vehicle control females (Table G2).

TABLE 4 Survival and Body Weights of Rats in the 3-Month Dermal Study of Trimethylolpropane Triacrylate

Dose (mg/kg) | Survival^a^ | Mean Body Weight^b^ (g) | | | Final Weight Relative to Controls (%)
Dose (mg/kg) | Survival^a^ | Initial | Final | Change | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 88 ± 3 | 272 ± 6 | 183 ± 7
0.75 | 10/10 | 89 ± 3 | 288 ± 6 | 199 ± 5 | 106
1.5 | 10/10 | 87 ± 3 | 270 ± 8 | 183 ± 9 | 99
3 | 10/10 | 88 ± 3 | 263 ± 5 | 174 ± 4 | 97
6 | 10/10 | 87 ± 3 | 267 ± 6 | 180 ± 6 | 98
12 | 10/10 | 89 ± 4 | 259 ± 7 | 170 ± 7 | 95
Female
0 | 10/10 | 82 ± 2 | 171 ± 3 | 89 ± 3
0.75 | 10/10 | 81 ± 2 | 164 ± 2 | 83 ± 3 | 96
1.5 | 10/10 | 83 ± 2 | 170 ± 2 | 87 ± 2 | 99
3 | 10/10 | 82 ± 2 | 173 ± 3 | 91 ± 3 | 101
6 | 10/10 | 82 ± 2 | 164 ± 2 | 81 ± 2 | 96
12 | 10/10 | 83 ± 2 | 169 ± 3 | 86 ± 4 | 99

a Number of animals surviving at 3 months/number initially in group

b Weights and weight changes are given as mean ± standard error.

FIGURE 1 Growth Curves for Male and Female F344/N Rats Administered Trimethylolpropane Triacrylate Dermally for 3 Months

ERRATUM: An error was identified in the NTP Genetically Modified Model Report on the Toxicology Studies of Trimethylolpropane Triacrylate (GMM 03). The second graph originally showed the growth curve for female mice and has been replaced with a graph showing the growth curve for female rats. [January 21, 2022]

Microscopically, the primary changes at the site of application were epidermal hyperplasia, degeneration, and necrosis, and chronic active inflammation of the dermis (Tables 5, D1, and D2). Epidermal hyperplasia occurred in all dosed groups of males and in 3 mg/kg or greater females. The severity of epidermal hyperplasia was minimal to mild and characterized by focally extensive to diffuse increased thickness of the epidermis, from the normal of one to three cell layers thick to four to six layers. Hyperplasia was accompanied by minimal to mild increased thickness of the superficial keratin layer (hyperkeratosis). Degeneration was seen in 1.5 mg/kg or greater males and 3 mg/kg or greater females. This lesion was a minimal to mild focal change consisting of intraepidermal vacuolization, presumably due to intra- or intercellular fluid accumulation. Epidermal necrosis was present in some 12 mg/kg females, although a dose response was not clear. Necrosis consisted of partial to full thickness coagulative change of the epidermis and was likely a sequela of degeneration. Intraepidermal infiltration of neutrophils (suppurative inflammation) often accompanied degeneration or necrosis of the epidermis. A mixed inflammatory cell infiltrate (chronic active inflammation) was present in the dermis of all dosed groups; the incidence increased with dose and the severity was increased in 12 mg/kg rats. Sebaceous glands at the site of application were slightly enlarged and prominent (hyperplasia) in animals administered 1.5 mg/kg or greater.

TABLE 5 Incidences of Selected Nonneoplastic Lesions of the Skin (Site of Application) in Rats in the 3-Month Dermal Study of Trimethylolpropane Triacrylate

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Male
Numbered Examined
Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Epidermis, Hyperplasia^a^ | 0 | 4^*^ (1.0)^b^ | 7^**^ (1.0) | 10^**^ (1.2) | 10^**^ (1.1) | 10^**^ (1.6)
Epidermis, Degeneration | 0 | 0 | 4^*^ (1.0) | 7^**^ (1.0) | 9^**^ (1.0) | 8^**^ (1.9)
Dermis, Inflammation, Chronic Active | 0 | 1 (1.0) | 3 (1.0) | 6^**^ (1.0) | 10^**^ (1.0) | 10^**^ (2.1)
Hyperkeratosis | 0 | 0 | 5^*^ (1.0) | 10^**^ (1.2) | 10^**^ (1.3) | 10^**^ (1.6)
Epidermis, Inflammation, Suppurative | 0 | 0 | 0 | 0 | 0 | 4^*^ (1.5)
Sebaceous Gland, Hyperplasia | 0 | 0 | 5^*^ (1.0) | 10^**^ (1.2) | 10^**^ (1.5) | 10^**^ (2.6)
Female
Numbered Examined
Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Epidermis, Hyperplasia | 0 | 0 | 0 | 7^**^ (1.0) | 10^**^ (1.1) | 10^**^ (1.4)
Epidermis, Degeneration | 0 | 0 | 0 | 4^*^ (1.0) | 7^**^ (1.0) | 10^**^ (2.0)
Epidermis, Necrosis | 0 | 0 | 0 | 0 | 0 | 5^*^ (2.0)
Dermis, Inflammation, Chronic Active | 1 (1.0) | 2 (1.0) | 1 (1.0) | 9^**^ (1.0) | 8^**^ (1.0) | 10^**^ (1.8)
Hyperkeratosis | 0 | 0 | 3 (1.0) | 9^**^ (1.0) | 10^**^ (1.1) | 10^**^ (2.0)
Epidermis, Inflammation, Suppurative | 0 | 0 | 0 | 0 | 0 | 6^**^ (1.3)
Sebaceous Gland, Hyperplasia | 0 | 1 (1.0) | 6^**^ (1.0) | 9^**^ (1.1) | 10^**^ (1.3) | 10^**^ (2.1)

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

** P≤0.01

a Number of animals with lesion

b Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## Mice 2-Week Study in B6C3F_1_ Mice

All mice survived to the end of the study (Table 6). The final mean body weight gain of 200 mg/kg males was significantly less than that of the vehicle controls; final mean body weights of 100 and 200 mg/kg females were significantly increased. Irritation at the site of application occurred in all dosed males, all 100 and 200 mg/kg males, and one 50 mg/kg female.

TABLE 6 Survival and Body Weights of B6C3F_1_ Mice in the 2-Week Dermal Study of Trimethylolpropane Triacrylate

Dose (mg/kg) | Survival^a^ | Mean Body Weight^b^ (g) | | | Final Weight Relative to Controls (%)
Dose (mg/kg) | Survival^a^ | Initial | Final | Change | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 21.8 ± 0.3 | 25.2 ± 0.5 | 3.4 ± 0.3
12.5 | 5/5 | 21.9 ± 0.4 | 25.6 ± 0.3 | 3.7 ± 0.6 | 101
25 | 5/5 | 21.4 ± 0.3 | 25.0 ± 0.4 | 3.6 ± 0.2 | 99
50 | 5/5 | 22.5 ± 0.6 | 25.5 ± 0.6 | 3.1 ± 0.2 | 101
100 | 5/5 | 22.3 ± 0.6 | 23.7 ± 1.5 | 1.4 ± 1.4 | 94
200 | 5/5 | 22.4 ± 0.5 | 23.1 ± 1.3 | 0.6 ± 1.5^*^ | 91
Female
0 | 5/5 | 18.7 ± 0.4 | 21.0 ± 0.5 | 2.3 ± 0.4
12.5 | 5/5 | 18.4 ± 0.5 | 21.3 ± 0.5 | 2.9 ± 0.3 | 101
25 | 5/5 | 18.3 ± 0.3 | 22.0 ± 0.3 | 3.7 ± 0.6 | 105
50 | 5/5 | 18.1 ± 0.2 | 21.5 ± 0.2 | 3.4 ± 0.3 | 102
100 | 5/5 | 19.5 ± 0.4 | 22.5 ± 0.3^*^ | 2.9 ± 0.5 | 107
200 | 5/5 | 19.3 ± 0.3 | 22.4 ± 0.4^*^ | 3.1 ± 0.2 | 107

* Significantly different (P≤0.05) from the vehicle control group by Williams’ test

a Number of animals surviving at 2 weeks/number initially in group

b Weights and weight changes are given as mean ± standard error.

Thymus weights of male mice administered 50 mg/kg or greater were significantly decreased (Table F3). At necropsy, crusts were observed grossly at the site of application in 50 mg/kg and greater males and in 100 and 200 mg/kg females (data not shown). Microscopically, lesions occurred at the site of application in all dosed groups (Table 7). Hyperplasia of the epidermis, hyperkeratosis, dermal chronic active inflammation, and sebaceous gland hyperplasia occurred in most dosed mice; these lesions were characterized by increased layers of epidermal cells, a thickened keratin layer, dermal infiltration of mixed inflammatory cells, and prominence of sebaceous glands. More severe lesions occurring generally at higher doses were ulcer (focal full-thickness necrosis of the epidermis), degeneration (vacuolar change of epidermal cells), parakeratosis (retention of nuclei in keratin layer), and accumulation of neutrophils (suppurative inflammation) in the degenerative and parakeratotic areas of the superficial epidermis. These lesions were not seen in the vehicle controls, and their severity generally increased with increasing dose. Male mice administered 100 or 200 mg/kg had increased incidences of thymic atrophy, characterized by depletion of cortical lymphocytes.

Dose Selection Rationale: Lesions at the site of application occurred in all dose groups. Their severity generally increased with increasing dose and was moderate to marked in the higher dose groups. The presence of ulceration and suppurative inflammation precluded use of 50 mg/kg or greater for males and 100 mg/kg or greater for females. Lesions were not markedly different between 12.5 and 25 mg/kg males and 12.5, 25, and 50 mg/kg females. However, the combined incidences and severity of the lesions in each of these dose groups represented the upper end of a dose acceptable for use in a 3-month study. Therefore, 12 mg/kg was selected as the highest dose for the 3-month study.

TABLE 7 Incidences of Selected Nonneoplastic Lesions in B6C3F_1_ Mice in the 2-Week Dermal Study of Trimethylolpropane Triacrylate

| Vehicle Control | 12.5 mg/kg | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
Male
Skin, Site of Application^a^ | 5 | 5 | 5 | 5 | 5 | 5
Epidermis, Hyperplasia^b^ | 0 | 5^**^ (1.6)^c^ | 5^**^ (2.2) | 5^**^ (2.2) | 5^**^ (2.8) | 5^**^ (3.6)
Hyperkeratosis | 0 | 5^**^ (1.4) | 4^*^ (1.3) | 5^**^ (1.8) | 3^*^ (1.7) | 3^*^ (1.7)
Dermis, Inflammation, Chronic Active | 0 | 5^**^ (1.8) | 5^**^ (1.8) | 5^**^ (2.6) | 5^**^ (3.0) | 5^**^ (2.8)
Sebaceous Gland, Hyperplasia | 0 | 5^**^ (2.2) | 5^**^ (1.6) | 2 (2.5) | 5^**^ (1.6) | 1 (1.0)
Ulcer | 0 | 0 | 0 | 2 (1.0) | 2 (1.0) | 5^**^ (2.8)
Epidermis, Degeneration | 0 | 3^*^ (1.0) | 4^*^ (1.0) | 1 (1.0) | 1 (1.0) | 1 (1.0)
Parakeratosis | 0 | 0 | 0 | 2 (2.0) | 4^*^ (2.3) | 5^**^ (2.4)
Epidermis, Inflammation, Suppurative | 0 | 5^**^ (1.4) | 2 (1.0) | 4^*^ (1.8) | 4^*^ (1.8) | 5^**^ (3.0)
Thymus | 5 | 5 | 5 | 5 | 5 | 5
Atrophy | 0 | 0 | 0 | 0 | 3^*^ (2.0) | 3^*^ (2.0)
Female
Skin, Site of Application | 5 | 5 | 5 | 5 | 5 | 5
Epidermis, Hyperplasia | 0 | 5^**^ (1.6) | 5^**^ (1.8) | 5^**^ (2.2) | 5^**^ (2.8) | 5^**^ (3.0)
Hyperkeratosis | 0 | 3^*^ (1.0) | 4^*^ (1.5) | 5^**^ (1.8) | 4^**^ (1.8) | 4^*^ (1.8)
Dermis, Inflammation, Chronic Active | 0 | 5^**^ (2.2) | 5^**^ (2.2) | 5^**^ (2.0) | 5^**^ (2.4) | 5^**^ (2.8)
Sebaceous Gland, Hyperplasia | 0 | 5^**^ (2.8) | 5^**^ (2.4) | 5^**^ (2.2) | 5^**^ (2.2) | 5^**^ (2.2)
Ulcer | 0 | 0 | 1 (1.0) | 0 | 3^*^ (2.3) | 3^*^ (1.3)
Epidermis, Degeneration | 0 | 2 (1.0) | 3^*^ (1.3) | 1 (1.0) | 3^*^ (1.3) | 4^*^ (1.5)
Parakeratosis | 0 | 1 (2.0) | 2 (1.0) | 1 (2.0) | 3^*^ (1.7) | 5^**^ (2.0)
Epidermis, Inflammation, Suppurative | 0 | 1 (1.0) | 4^*^ (1.5) | 2 (1.0) | 5^**^ (2.0) | 5^**^ (2.0)

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

** P≤0.01

a Number of animals with tissue examined microscopically

b Number of animals with lesion

c Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## 3-Month Study in B6C3F_1_ Mice

All animals survived to the end of the study. Final mean body weights and body weight gains of dosed groups were similar to those of the vehicle controls (Table 8 and Figure 2). Irritation at the site of application occurred in male and female mice administered 12 mg/kg.

Hematology data for mice in the 3-month study of trimethylolpropane triacrylate are listed in Table E2. Increased segmented neutrophil counts in the 12 mg/kg males and females at study termination were consistent with the suppurative dermatitis observed microscopically.

Organ weights of dosed groups of mice were generally similar to those of the vehicle controls (Table F4). Trimethylolpropane triacrylate administration did not affect reproductive endpoints in males (Table G3). Although the relative length of time spent in the estrous stages differed significantly from the vehicle controls in the 6 and 12 mg/kg groups, the differences were not considered biologically significant (Table G4).

TABLE 8 Survival and Body Weights of B6C3F_1_ Mice in the 3-Month Dermal Study of Trimethylolpropane Triacrylate

Dose (mg/kg) | Survival^a^ | Mean Body Weight^b^ (g) | | | Final Weight Relative to Controls (%)
Dose (mg/kg) | Survival^a^ | Initial | Final | Change | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 22.6 ± 0.4 | 36.5 ± 0.7 | 13.9 ± 0.6
0.75 | 10/10 | 22.5 ± 0.4 | 34.5 ± 0.7 | 12.0 ± 0.5 | 95
1.5 | 10/10 | 22.2 ± 0.4 | 35.6 ± 1.1 | 13.4 ± 0.8 | 98
3 | 10/10 | 22.4 ± 0.5 | 35.8 ± 0.8 | 13.4 ± 0.9 | 98
6 | 10/10 | 22.3 ± 0.4 | 34.2 ± 0.7 | 11.9 ± 0.4 | 94
12 | 10/10 | 22.6 ± 0.5 | 34.6 ± 0.7 | 12.0 ± 0.9 | 95
Female
0 | 10/10 | 19.4 ± 0.4 | 31.0 ± 1.2 | 11.6 ± 0.9
0.75 | 10/10 | 19.6 ± 0.4 | 32.6 ± 0.7 | 13.0 ± 0.6 | 105
1.5 | 10/10 | 19.3 ± 0.4 | 31.9 ± 1.3 | 12.6 ± 1.2 | 103
3 | 10/10 | 19.1 ± 0.4 | 32.4 ± 1.2 | 13.3 ± 0.9 | 105
6 | 10/10 | 19.0 ± 0.4 | 30.1 ± 0.7 | 11.1 ± 0.6 | 97
12 | 10/10 | 19.3 ± 0.2 | 31.4 ± 1.1 | 12.2 ± 1.0 | 101

a Number of animals surviving at 3 months/number initially in group

b Weights and weight changes are given as mean ± standard error.

FIGURE 2 Growth Curves for Male and Female B6C3F_1_ Mice Administered Trimethylolpropane Triacrylate Dermally for 3 Months

Similar to the changes in rats, the primary microscopic changes at the site of application in mice were epidermal hyperplasia, degeneration, and necrosis, and chronic active inflammation of the dermis (Tables 9, D3, and D4). The incidences and severities of epidermal hyperplasia generally increased with increasing dose in the 1.5 mg/kg or greater groups (Plates 1 to 7). Severity was minimal to mild and was characterized by focally extensive to diffuse increased thickness of the epidermis from the normal one to three cell layers to four to six cell layers (Plates 3 to 7). Hyperplasia was accompanied by minimal to mild increases in the thickness of the superficial keratin layer (hyperkeratosis). Minimal to mild epidermal degeneration was diagnosed in several mice administered 3 mg/kg (males) or 6 mg/kg (females) or greater (Plates 5 to 7). This degeneration was a focal change consisting of intraepidermal vacuolization, presumably due to intra- or intercellular fluid accumulation. Minimal to mild epidermal necrosis was diagnosed with increasing incidence and severity in 1.5 mg/kg or greater male mice (Plates 6 and 7); in females, a similar trend occurred in the 3 mg/kg or greater groups. Necrosis consisted of partial to full thickness coagulative change of the epidermis and was likely a pathogenic sequela of degeneration. A mixed inflammatory cell infiltrate (chronic active inflammation) was present in most animals in the 1.5 mg/kg or greater groups, with dose-dependent increases in incidences and severities (Plates 3 to 6). Neutrophils were more prominent in areas of degeneration or necrosis (suppurative inflammation), and slight superficial dermal fibrosis was seen in some 12 mg/kg males and females and one 6 mg/kg female. Sebaceous glands at the site of application were slightly enlarged and prominent (hyperplasia; Plates 5 to 7) in 3 mg/kg or greater males and females.

Dose Selection Rationale: There were no effects on survival or body weights of B6C3F_1_ mice treated with trimethylolpropane triacrylate in the 3-month study. In selecting doses for a 2-year dermal bioassay based on findings in 3-month studies, dose levels containing any severity of ulceration and necrosis or other changes (e.g. inflammation or hyperplasia) in the skin (site of application) that are moderate to marked are generally avoided. Therefore, because of the presence of mild necrosis and minimal to mild degeneration and suppurative inflammation, 12 mg/kg would not have been selected for use in a 2-year bioassay. These pathological alterations are consistent with the irritation identified grossly in the 12 mg/kg group. The necrosis and degeneration occurred in fewer animals and/or at lesser severity in the 6 mg/kg groups and were rare in the lower dose groups. Because doses were being selected for Tg.AC mice and for a 6-month study, five dose levels were used to allow for a margin of error, ranging from doses that produced no lesions to 12 mg/kg.

TABLE 9 Incidences of Selected Nonneoplastic Lesions of the Skin (Site of Application) in B6C3F_1_ Mice in the 3-Month Dermal Study of Trimethylolpropane Triacrylate

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Male
Number Examined
Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Epidermis, Hyperplasia^a^ | 0 | 0 | 3 (1.0)^b^ | 10^**^ (1.0) | 10^**^ (1.4) | 10^**^ (2.2)
Epidermis, Degeneration | 0 | 0 | 0 | 4^*^ (1.0) | 8^**^ (1.0) | 9^**^ (1.8)
Epidermis, Necrosis | 0 | 0 | 1 (1.0) | 1 (1.0) | 2 (1.5) | 7^**^ (2.1)
Dermis, Inflammation, Chronic Active | 1 (1.0) | 0 | 2 (1.0) | 10^**^ (1.1) | 9^**^ (1.4) | 10^**^ (1.8)
Hyperkeratosis | 0 | 0 | 3 (1.0) | 8^**^ (1.0) | 8^**^ (1.0) | 10^**^ (1.4)
Epidermis, Inflammation, Suppurative | 0 | 0 | 1 (1.0) | 0 | 1 (1.0) | 8^**^ (1.6)
Dermis, Fibrosis | 0 | 0 | 0 | 0 | 0 | 7^**^ (1.1)
Sebaceous Gland, Hyperplasia | 0 | 0 | 0 | 9^**^ (1.0) | 10^**^ (1.7) | 10^**^ (2.3)
Female
Number Examined
Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Epidermis, Hyperplasia | 0 | 0 | 3 (1.0) | 10^**^ (1.0) | 9^**^ (1.1) | 10^**^ (1.3)
Epidermis, Degeneration | 0 | 0 | 0 | 0 | 5^*^ (1.0) | 9^**^ (1.6)
Epidermis, Necrosis | 0 | 0 | 0 | 1 (1.0) | 2 (2.0) | 8^**^ (2.0)
Dermis, Inflammation, Chronic Active | 0 | 0 | 7^**^ (1.0) | 10^**^ (1.1) | 10^**^ (2.0) | 10^**^ (1.8)
Hyperkeratosis | 0 | 0 | 3 (1.0) | 10^**^ (1.0) | 9^**^ (1.0) | 8^**^ (1.1)
Epidermis, Inflammation, Suppurative | 0 | 0 | 1 (1.0) | 1 (1.0) | 2 (1.5) | 5^*^ (1.4)
Dermis, Fibrosis | 0 | 0 | 0 | 0 | 1 (1.0) | 7^**^ (1.6)
Sebaceous Gland, Hyperplasia | 0 | 0 | 1 (1.0) | 10^**^ (1.0) | 10^**^ (2.0) | 10^**^ (2.3)

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

** P≤0.01

a Number of animals with lesion

b Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## 6-Month Study in Tg.AC Hemizygous Mice

### Survival

Estimates of 6-month survival probabilities for male and female mice are shown in Table 10 and in the Kaplan-Meier survival curves (Figure 3). Survival of all dosed groups of mice was similar to that of the vehicle controls.

TABLE 10 Survival of Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Male
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Natural deaths | 1 | 0 | 3 | 1 | 2 | 4
Animals surviving to study termination | 14 | 15 | 12 | 14 | 13 | 11
Percent probability of survival at end of study^a^ | 93 | 100 | 80 | 93 | 87 | 73
Mean survival (days)^b^ | 186 | 192 | 175 | 188 | 185 | 187
Survival analysis^c^ | P=0.111 | P=1.000N | P=0.567 | P=1.000N | P=0.984 | P=0.357
Female
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Moribund | 0 | 0 | 1 | 0 | 0 | 0
Natural deaths | 0 | 1 | 2 | 1 | 1 | 3
Animals surviving to study termination | 15 | 14 | 12 | 14 | 14 | 12
Percent probability of survival at end of study | 100 | 93 | 80 | 93 | 93 | 80
Mean survival (days) | 193 | 192 | 171 | 188 | 191 | 187
Survival analysis^c^ | P=0.305 | P=1.000 | P=0.226 | P=1.000 | P=1.000 | P=0.224

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice)

c The result of the life table trend test (Tarone, 1975) is in the vehicle control column, and the results of the life table pairwise comparisons (Cox, 1972) with the vehicle controls are in the dosed group columns. A lower mortality in a dosed group is indicated by N.

FIGURE 3 Kaplan-Meier Survival Curves for Male and Female Tg.AC Hemizgyous Mice Administered Trimethylolpropane Triacrylate Dermally for 6 Months

### Body Weights and Clinical Findings

Mean body weights of dosed groups of mice were 95% to 105% those of the vehicle controls for most of the study (Tables 11 and 12; Figure 4). Treatment-related clinical findings included papillomas at the site of application in 3 mg/kg and greater males and 6 and 12 mg/kg females; one female administered 1.5 mg/kg also had a papilloma. In-life observations of papillomas at the site of application are summarized in Table 13. The number of mice with papillomas, the total number of papillomas, and the mean number of papillomas per mouse increased with increasing dose. Papillomas were observed earlier in the 6 and 12 mg/kg groups than in the other dose groups.

### Organ Weights and Organ-Weight-to-Body-Weight Ratios

Liver weights were increased in 12 mg/kg male and female mice (Table F5). Absolute and relative lung weights of 6 and 12 mg/kg males and 12 mg/kg females were significantly less than those of the vehicle controls; absolute lung weights were also decreased in 6 mg/kg females. Heart weights of 12 mg/kg males and females (absolute only) were significantly increased. Females administered 12 mg/kg also had significantly increased kidney weights.

TABLE 11 Mean Body Weights and Survival of Male Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate

Weeks on Study | Vehicle Control | | 0.75 mg/kg | | | 1.5 mg/kg | | | 3 mg/kg | | | 6 mg/kg | | | 12 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 22.1 | 15 | 21.9 | 99 | 15 | 21.3 | 96 | 15 | 21.9 | 99 | 15 | 21.7 | 98 | 15 | 21.0 | 95 | 15
2 | 22.7 | 15 | 22.5 | 99 | 15 | 22.5 | 99 | 15 | 22.9 | 101 | 15 | 21.2 | 93 | 15 | 22.7 | 100 | 15
3 | 24.3 | 15 | 23.3 | 96 | 15 | 24.0 | 99 | 15 | 23.9 | 98 | 15 | 23.0 | 95 | 15 | 23.9 | 98 | 15
4 | 25.3 | 15 | 24.5 | 97 | 15 | 24.8 | 98 | 15 | 25.1 | 99 | 15 | 24.9 | 98 | 15 | 24.8 | 98 | 15
5 | 25.9 | 15 | 25.2 | 97 | 15 | 26.2 | 101 | 15 | 26.4 | 102 | 15 | 25.9 | 100 | 15 | 26.2 | 101 | 15
6 | 27.2 | 15 | 26.3 | 97 | 15 | 27.5 | 101 | 15 | 26.6 | 98 | 15 | 27.3 | 100 | 15 | 26.7 | 98 | 15
7 | 27.3 | 15 | 26.8 | 98 | 15 | 27.9 | 102 | 15 | 27.4 | 100 | 15 | 27.6 | 101 | 15 | 27.2 | 100 | 15
8 | 28.2 | 15 | 27.5 | 98 | 15 | 28.5 | 101 | 15 | 28.1 | 100 | 15 | 27.9 | 99 | 15 | 28.1 | 100 | 15
9 | 28.0 | 15 | 26.7 | 95 | 15 | 28.7 | 103 | 15 | 28.5 | 102 | 15 | 27.9 | 100 | 15 | 28.0 | 100 | 15
10 | 28.6 | 15 | 27.1 | 95 | 15 | 29.1 | 102 | 15 | 28.6 | 100 | 15 | 28.3 | 99 | 15 | 28.2 | 99 | 15
11 | 29.2 | 15 | 27.9 | 96 | 15 | 29.5 | 101 | 15 | 29.0 | 99 | 15 | 28.8 | 99 | 15 | 28.5 | 98 | 15
12 | 29.7 | 15 | 28.3 | 95 | 15 | 30.6 | 103 | 14 | 29.2 | 98 | 15 | 28.8 | 97 | 15 | 28.9 | 97 | 15
13 | 29.3 | 15 | 28.7 | 98 | 15 | 30.3 | 103 | 14 | 29.7 | 101 | 15 | 28.7 | 98 | 15 | 29.1 | 99 | 15
14 | 30.0 | 15 | 29.2 | 97 | 15 | 29.9 | 100 | 14 | 30.3 | 101 | 15 | 29.3 | 98 | 14 | 29.6 | 99 | 15
15 | 30.4 | 15 | 28.6 | 94 | 15 | 31.7 | 104 | 13 | 31.1 | 102 | 15 | 30.2 | 99 | 14 | 30.0 | 99 | 15
16 | 30.3 | 14 | 29.3 | 97 | 15 | 31.4 | 104 | 13 | 31.0 | 102 | 15 | 29.8 | 98 | 14 | 30.1 | 99 | 15
17 | 30.1 | 14 | 29.9 | 99 | 15 | 31.7 | 105 | 13 | 31.7 | 105 | 15 | 30.3 | 101 | 14 | 30.5 | 101 | 15
18 | 31.3 | 14 | 30.4 | 97 | 15 | 31.8 | 102 | 13 | 32.0 | 102 | 15 | 31.3 | 100 | 14 | 30.7 | 98 | 15
19 | 31.4 | 14 | 30.1 | 96 | 15 | 32.3 | 103 | 13 | 32.2 | 103 | 15 | 30.5 | 97 | 14 | 31.3 | 100 | 15
20 | 31.3 | 14 | 30.9 | 99 | 15 | 31.2 | 100 | 13 | 32.7 | 105 | 14 | 30.6 | 98 | 14 | 31.9 | 102 | 15
21 | 31.2 | 14 | 30.2 | 97 | 15 | 32.6 | 105 | 13 | 32.5 | 104 | 14 | 30.8 | 99 | 14 | 31.7 | 102 | 15
22 | 31.9 | 14 | 31.2 | 98 | 15 | 33.2 | 104 | 13 | 33.4 | 105 | 14 | 31.2 | 98 | 14 | 32.0 | 100 | 15
23 | 32.1 | 14 | 31.1 | 97 | 15 | 32.6 | 102 | 13 | 32.9 | 103 | 14 | 31.0 | 97 | 14 | 32.2 | 100 | 15
24 | 31.7 | 14 | 31.9 | 101 | 15 | 33.9 | 107 | 12 | 33.8 | 107 | 14 | 31.9 | 101 | 14 | 32.9 | 104 | 13
25 | 33.1 | 14 | 32.0 | 97 | 15 | 35.3 | 107 | 12 | 34.3 | 104 | 14 | 30.8 | 93 | 14 | 32.9 | 99 | 13
26 | 32.5 | 14 | 32.1 | 99 | 15 | 33.8 | 104 | 12 | 34.3 | 106 | 14 | 31.6 | 97 | 14 | 33.1 | 102 | 13
27 | 33.1 | 14 | 32.2 | 97 | 15 | 35.2 | 106 | 12 | 34.5 | 104 | 14 | 32.4 | 98 | 13 | 33.5 | 101 | 12
28 | 32.6 | 14 | 32.5 | 100 | 15 | 36.3 | 111 | 12 | 33.8 | 104 | 14 | 32.8 | 101 | 13 | 33.0 | 101 | 12
Mean for weeks
1-13 | 26.8 | | 25.9 | 97 | | 27.0 | 101 | | 26.7 | 100 | | 26.3 | 98 | | 26.4 | 99
14-28 | 31.5 | | 30.8 | 98 | | 32.9 | 104 | | 32.7 | 104 | | 31.0 | 98 | | 31.7 | 100

TABLE 12 Mean Body Weights and Survival of Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate

Weeks on Study | Vehicle Control | | 0.75 mg/kg | | | 1.5 mg/kg | | | 3 mg/kg | | | 6 mg/kg | | | 12 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 18.6 | 15 | 18.4 | 99 | 15 | 18.5 | 100 | 15 | 18.6 | 100 | 15 | 18.7 | 101 | 15 | 18.5 | 100 | 15
2 | 19.3 | 15 | 19.0 | 98 | 15 | 19.4 | 101 | 15 | 18.6 | 96 | 15 | 18.7 | 97 | 15 | 19.4 | 101 | 15
3 | 20.4 | 15 | 20.9 | 103 | 15 | 20.9 | 103 | 15 | 20.7 | 102 | 15 | 20.1 | 99 | 15 | 20.2 | 99 | 15
4 | 21.7 | 15 | 21.6 | 100 | 15 | 21.8 | 101 | 15 | 21.2 | 98 | 15 | 21.5 | 99 | 15 | 21.7 | 100 | 15
5 | 22.8 | 15 | 22.7 | 100 | 15 | 22.8 | 100 | 15 | 22.8 | 100 | 15 | 22.3 | 98 | 15 | 22.3 | 98 | 15
6 | 23.3 | 15 | 23.1 | 99 | 15 | 23.6 | 101 | 15 | 23.6 | 101 | 15 | 23.4 | 100 | 15 | 22.5 | 97 | 15
7 | 23.8 | 15 | 23.7 | 100 | 15 | 23.3 | 98 | 15 | 23.6 | 99 | 15 | 23.0 | 97 | 15 | 23.2 | 98 | 15
8 | 22.8 | 15 | 23.6 | 104 | 15 | 23.6 | 104 | 15 | 24.5 | 108 | 15 | 24.0 | 105 | 15 | 23.3 | 102 | 15
9 | 24.1 | 15 | 23.4 | 97 | 15 | 23.5 | 98 | 15 | 23.0 | 95 | 15 | 23.7 | 98 | 15 | 23.8 | 99 | 15
10 | 24.3 | 15 | 24.6 | 101 | 15 | 25.0 | 103 | 13 | 24.3 | 100 | 15 | 24.5 | 101 | 15 | 23.2 | 96 | 15
11 | 24.4 | 15 | 25.2 | 103 | 15 | 25.3 | 104 | 13 | 25.0 | 103 | 15 | 24.9 | 102 | 15 | 24.5 | 100 | 15
12 | 24.6 | 15 | 25.2 | 102 | 15 | 25.6 | 104 | 13 | 24.8 | 101 | 15 | 25.0 | 102 | 15 | 24.8 | 101 | 15
13 | 25.1 | 15 | 25.5 | 102 | 15 | 25.6 | 102 | 13 | 25.6 | 102 | 15 | 24.8 | 99 | 15 | 25.2 | 100 | 15
14 | 24.7 | 15 | 25.8 | 105 | 15 | 25.7 | 104 | 13 | 25.3 | 102 | 15 | 25.4 | 103 | 15 | 25.3 | 102 | 15
15 | 26.2 | 15 | 25.8 | 99 | 15 | 26.9 | 103 | 13 | 26.0 | 99 | 15 | 26.0 | 99 | 15 | 25.5 | 97 | 15
16 | 25.7 | 15 | 25.8 | 100 | 15 | 26.0 | 101 | 13 | 26.0 | 101 | 15 | 25.7 | 100 | 15 | 24.6 | 96 | 15
17 | 26.1 | 15 | 26.4 | 101 | 15 | 26.9 | 103 | 13 | 26.3 | 101 | 15 | 26.6 | 102 | 15 | 26.2 | 100 | 15
18 | 26.1 | 15 | 26.6 | 102 | 15 | 26.7 | 102 | 13 | 26.1 | 100 | 15 | 26.2 | 100 | 15 | 25.8 | 99 | 14
19 | 25.5 | 15 | 26.2 | 103 | 15 | 26.5 | 104 | 12 | 26.3 | 103 | 14 | 26.3 | 103 | 15 | 26.8 | 105 | 14
20 | 26.0 | 15 | 26.6 | 102 | 15 | 27.3 | 105 | 12 | 27.3 | 105 | 14 | 27.2 | 105 | 15 | 27.4 | 105 | 14
21 | 26.3 | 15 | 26.8 | 102 | 15 | 27.6 | 105 | 12 | 27.0 | 103 | 14 | 27.1 | 103 | 15 | 27.2 | 103 | 14
22 | 27.0 | 15 | 26.7 | 99 | 15 | 27.4 | 102 | 12 | 26.9 | 100 | 14 | 26.3 | 97 | 15 | 27.5 | 102 | 14
23 | 27.2 | 15 | 26.7 | 98 | 15 | 26.9 | 99 | 12 | 27.5 | 101 | 14 | 26.4 | 97 | 15 | 27.4 | 101 | 14
24 | 27.5 | 15 | 26.9 | 98 | 15 | 28.4 | 103 | 12 | 27.6 | 100 | 14 | 27.8 | 101 | 14 | 28.2 | 103 | 14
25 | 27.5 | 15 | 26.9 | 98 | 15 | 28.4 | 103 | 12 | 27.6 | 100 | 14 | 27.6 | 100 | 14 | 27.6 | 100 | 14
26 | 27.1 | 15 | 27.3 | 101 | 15 | 28.1 | 104 | 12 | 26.6 | 98 | 14 | 27.3 | 101 | 14 | 28.4 | 105 | 13
27 | 27.9 | 15 | 27.5 | 99 | 14 | 27.4 | 98 | 12 | 27.9 | 100 | 14 | 26.4 | 95 | 14 | 28.7 | 103 | 13
28 | 28.2 | 15 | 27.6 | 98 | 14 | 28.9 | 103 | 12 | 28.5 | 101 | 14 | 27.9 | 99 | 14 | 28.7 | 102 | 12
Mean for weeks
1-13 | 22.7 | | 22.8 | 101 | | 23.0 | 101 | | 22.8 | 100 | | 22.7 | 100 | | 22.5 | 99
14-28 | 26.6 | | 26.6 | 100 | | 27.3 | 103 | | 26.9 | 101 | | 26.7 | 100 | | 27.0 | 102

FIGURE 4 Growth Curves for Male and Female Tg.AC Hemizygous Mice Administered Trimethylolpropane Triacrylate Dermally for 6 Months

TABLE 13 Skin Papilloma Formation at the Site of Application in Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate^a^

Dose (mg/kg) | Number (Percent) with Papilloma^b^ | Time to Initial Papilloma Occurrence for All Animals in Group^c^ (Week) | | Distribution of Number of Papillomas per Animal^d^ Quantiles | | | Test of Dunson et al. Model^e^
Dose (mg/kg) | Number (Percent) with Papilloma^b^ | First | Median | 20th | 50th | 80th | ϒ_1_ | ϒ_2_
Male
0 | 0 (0.0%) | NA | >28 | 0 | 0 | 0
0.75 | 0 (0.0%) | NA | >28 | 0 | 0 | 0 | | NT
1.5 | 0 (0.0%) | NA | >28 | 0 | 0 | 0 | | NT
3 | 3 (20.9%) | 23 | >28 | 0 | 0 | 0 | | NT
6 | 13 (91.9%) | 14 | 20 | 1 | 6 | 15.5 | ** | NT
12 | 13 (86.7%) | 9 | 13 | 20+ | 20+ | 20+ | ** | NT
Trend | | | | | | | ** | **
Positive Control^f^ | 15 (100.0%) | 9 | 10 | 9 | 20+ | 20+ | ** | NT
Female
0 | 0 (0.0%) | NA | >28 | 0 | 0 | 0
0.75 | 0 (0.0%) | NA | >28 | 0 | 0 | 0 | | NT
1.5 | 1 (8.1%) | 19 | >28 | 0 | 0 | 0 | | NT
3 | 2 (14.0%) | 28 | >28 | 0 | 0 | 0 | | NT
6 | 12 (80.0%) | 9 | 25 | 0 | 1 | 4 | ** | NT
12 | 15 (100.0%) | 10 | 14 | 20+ | 20+ | 20+ | ** | NT
Trend | | | | | | | ** | **
Positive Control | 14 (99.8%) | 9 | 10 | 1 | 16 | 20+ | ** | NT

a 15 males and 15 females initially in each dose group

b Percent is Poly-3 adjusted rate and reflects whether the animal ever had a confirmed papilloma at any point in the study.

c For groups in which fewer than half of the animals had papillomas, the median time to initial occurrence is >28 weeks. NA=not applicable.

d Quantiles are based on all animals in a group, whether removed before the end of study or not. For example, a value of 9 for the 20th quantile implies that 20% of the animals in the study had 9 papillomas or fewer at the end of the study (or at removal from study).

e The Dunson et al. (2000) model accounts for latency (ϒ_1_) and multiplicity (ϒ_2_) in the rate of occurrence, NT (No Test) indicates that a pairwise test could not be meaningfully applied because no papillomas were observed in the control group. ** (P≤0.01) indicates a significant trend or a significant difference from the vehicle control group.

f 100 μL of 1.25 μg 12-O-tetradecanoylphorbol-13-acetate per 100 mL acetone administered three times per week.

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and nonneoplastic lesions of the skin determined by microscopic evaluation; forestomach; liver; spleen; and mandibular, mediastinal, and mesenteric lymph nodes. Summaries of the incidences of neoplasms and nonneoplastic lesions, individual animal tumor diagnoses, and statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group are presented in Appendix A for male mice and Appendix B for female mice.

Skin: Squamous cell neoplasms at the site of application were associated with dermal application of trimethylol propane triacrylate. The incidences of squamous cell papilloma were significantly increased in 6 and 12 mg/kg males and females (Tables 14, A3, and B3). Papillomas were multiple in all 12 mg/kg males and females and 6 mg/kg males. Two males and one female in the 3 mg/kg groups also had squamous cell papillomas at the site of application. Squamous cell papilloma had the typical morphology of an exophytic growth of well-differentiated squamous epithelium covering arborizing fronds of connective tissue. Multiple papillomas were often contiguous. One female in each of the 1.5, 6, and 12 mg/kg groups also had a squamous cell carcinoma at the site of application (Plate 8). These carcinomas appeared to arise within papillomas (Plate 9), with extensions of atypical squamous cells into the underlying dermis and subcutis. Squamous cell carcinomas at the site of application were considered to be treatment-related and possibly the result of malignant conversion of papillomas.

Nonneoplastic effects at the site of application were squamous cell hyperplasia, hyperkeratosis, and chronic active inflammation. Hyperplasia was present in the 3 mg/kg and greater groups and was characterized by increased thickness of the epidermis, from the normal one to three cell layers to four to six cell layers thick (minimal to mild severity). The hyperplasia was generally diffuse in areas between papillomas. Occasionally a focal nodular type of hyperplasia was observed that was considered a precursor lesion to squamous papilloma. Hyperplasia was accompanied by minimal to mild increased thickness of the keratin layer (hyperkeratosis). A minimal to mild infiltrate of mixed inflammatory cells (chronic active inflammation) was present in the dermis, generally in the 6 and 12 mg/kg groups. Some inflammation was invariably associated with neoplasms, but the diagnosis was made when infiltrates were observed in nonneoplastic areas. Sebaceous glands at the site of application were enlarged (hyperplasia) in several males and females administered 3 mg/kg or greater, but this lesion was not diagnosed separately.

TABLE 14 Incidences of Neoplasms and Nonneoplastic Lesions of the Skin (Site of Application) in Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Male
Number Examined
Microscopically | 15 | 15 | 15 | 15 | 15 | 15
Epidermis, Hyperplasia^a^ | 0 | 0 | 0 | 6^**^ (1.0)^b^ | 14^**^ (1.7) | 15^**^ (1.9)
Hyperkeratosis | 0 | 0 | 1 (2.0) | 15^**^ (1.0) | 14^**^ (1.1) | 12^**^ (1.7)
Inflammation, Chronic Active | 0 | 0 | 1 (1.0) | 1 (1.0) | 9^**^ (1.1) | 12^**^ (1.3)
Squamous Cell Papilloma, Multiple | 0 | 0 | 0 | 0 | 12^**^ | 13^**^
Squamous Cell Papilloma (includes multiple)
Overall rate^c^ | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 2/15 (13%) | 12/15 (80%) | 13/15 (87%)
Adjusted rate^d^ | 0.0% | 0.0% | 0.0% | 14.0% | 85.1% | 86.7%
Terminal rate^e^ | 0/14 (0%) | 0/15 (0%) | 0/12 (0%) | 2/14 (14%) | 11/13 (85%) | 9/11 (82%)
First incidefnce (days) | —^g^ | — | — | 192 (T) | 180 | 161
Poly-3 test^f^ | P<0.001 | —^h^ | — | P=0.234 | P<0.001 | P<0.001
Female
Number Examined
Microscopically | 15 | 15 | 15 | 15 | 15 | 15
Epidermis, Hyperplasia | 0 | 0 | 1 (2.0) | 4^*^ (1.0) | 15^**^ (1.2) | 15^**^ (2.0)
Hyperkeratosis | 0 | 0 | 1 (1.0) | 7^**^ (1.0) | 14^**^ (1.1) | 13^**^ (1.6)
Inflammation, Chronic Active | 0 | 0 | 0 | 3 (1.0) | 14^**^ (1.0) | 12^**^ (1.3)
Squamous Cell Papilloma, Multiple | 0 | 0 | 0 | 0 | 5^*^ | 15^**^
Squamous Cell Papilloma (includes multiple)
Overall rate | 0/15 (0%) | 0/15 (0%) | 0/15 (0%) | 1/15 (7%) | 11/15 (73%) | 15/15 (100%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 7.0% | 73.3% | 100%
Terminal rate | 0/15 (0%) | 0/14 (0%) | 0/12 (0%) | 1/14 | 10/14 (71%) | 12/12 (100%)
First incidence (days) | — | — | — | 193 (T) | 162 | 118
Poly-3 test | P<0.001 | — | — | P=0.490 | P<0.001 | P<0.001
Squamous Cell Carcinoma | 0 | 0 | 1 | 0 | 1 | 1

(T)Terminal sacrifice

* Significantly different (P≤0.05) from the vehicle control group by the Poly-3 test

** P≤0.01

a Number of animals with lesion

b Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

c Number of neoplasm-bearing animals/number of animals with skin examined microscopically

d Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortalitye

e Observed incidence at terminal kill

f Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence is the P value corresponding to pairwise comparison between the vehicle controls and that dosed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal sacrifice.

g Not applicable; no neoplasms in animal group

h Value of statistic cannot be computed.

Forestomach: The incidence of squamous cell papilloma in 12 mg/kg females was significantly greater than that in the vehicle control group (Tables 15 and B3). The morphology of these neoplasms was similar to that of skin papillomas. Multiple papillomas occurred in three of the nine affected females in the 12 mg/kg group, in contrast to single incidences in all other groups. No other proliferative squamous lesions (hyperplasia or carcinoma) were observed. Forestomach papilloma is a relatively common spontaneous finding in Tg.AC mice that may occur at a high and variable rate (10%-25% in hemizygous females; higher in homozygous mice; Mahler et al., 1998). The increased incidence of forestomach papilloma in 12 mg/kg females may have been treatment related.

TABLE 15 Incidences of Squamous Cell Papilloma of the Forestomach in Female Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Number Examined
Microscopically | 15 | 15 | 15 | 15 | 15 | 15
Squamous Cell Papilloma, Multiple^a^ | 1 | 1 | 1 | 1 | 1 | 3
Squamous Cell Papilloma (includes multiple)
Overall rate^b^ | 4/15 (27%) | 5/15 (33%) | 4/15 (27%) | 2/15 (13%) | 5/15 (33%) | 9/15 (60%)
Adjusted rate^c^ | 26.7% | 33.7% | 32.5% | 14.0% | 34.3% | 64.6%
Terminal rate^d^ | 4/15 (27%) | 5/14 (36%) | 4/12 (33%) | 2/14 (14%) | 5/14 (36%) | 9/12 (75%)
First incidence (days) | 193 (T) | 193 (T) | 193 (T) | 193 (T) | 193 (T) | 193 (T)
Poly-3 test^e^ | P=0.014 | P=0.493 | P=0.535 | P=0.352N | P=0.481 | P=0.040

(T)Terminal sacrifice

a Number of animals with lesion

b Number of neoplasm-bearing animals/number of animals with forestomach examined microscopically

c Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality

d Observed incidence at terminal kill

e Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence is the P value corresponding to pairwise comparison between the vehicle controls and that dosed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal sacrifice. A lower incidence in a dosed group is indicated by N.

Other Organs: Incidences of hematopoietic cell proliferation in various tissues were increased in dosed mice (Tables 16, A4, and B4). Hematopoietic cell proliferation was significantly increased in the liver of 12 mg/kg males and females and the spleen of 6 and 12 mg/kg males, as well as in the mandibular, mediastinal, and mesenteric lymph node of 12 mg/kg females. Hematopoietic cell proliferation consisted of increased numbers of erythroid and granulocytic precursors in the splenic red pulp, liver sinusoids, or nodal parenchyma. These changes were attributed to the dermal inflammatory stimulus at the application site and/or release of hematopoietic cytokines and growth factors from proliferative epidermal cells.

There was a change that occurred in some animals administered 6 or 12 mg/kg. This change was observed in one or more organs and was characterized by somewhat variable morphology and uncertain biological behavior. Florid lesions, diagnosed as myelodysplasia, were identified in two males and two females exposed to 12 mg/kg, while milder lesions, diagnosed as cell, infiltration, nonspecified site, were identified in several animals (Tables 16, A4, and B4). The change was characterized predominantly by myeloid infiltration/proliferation that tended to be perivascular in the liver and lungs. Infiltrating cells were predominantly mature and immature granulocytes (eosinophils and neutrophils) with lesser numbers of admixed mononuclear cells. In severely affected livers, there was bridging between portal tracts and accumulations of brightly eosinophilic crystalline material in the lumen of bile ductules. The change was commonly observed in the mediastinal, mandibular, axillary, and mesenteric lymph nodes, and often included a pronounced plasma cell population in the medullary sinuses. The epididymis and spleen were also often involved.

TABLE 16 Incidences of Selected Nonneoplastic Lesions in Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Male
Liver^a^ | 15 | 15 | 15 | 15 | 15 | 15
Hematopoietic Cell Proliferation^b^ | 1 (1.0)^c^ | 0 | 1 (1.0) | 0 | 0 | 6^*^ (1.3)
Spleen | 15 | 15 | 15 | 15 | 15 | 15
Hematopoietic Cell Proliferation | 1 (2.0) | 4 (1.5) | 1 (3.0) | 2 (1.5) | 6^*^ (2.0) | 8^**^ (2.6)
All Organs^d^ | 15 | 15 | 15 | 15 | 15 | 15
Myelodysplasia | 0 | 0 | 0 | 0 | 0 | 2
Infiltration Cellular | 0 | 0 | 0 | 0 | 0 | 5^*^
Infiltration Cellular, Plasma Cell | 0 | 0 | 0 | 0 | 0 | 4^*^
Female
Liver | 15 | 15 | 15 | 15 | 15 | 15
Hematopoietic Cell Proliferation | 0 | 0 | 1 (2.0) | 0 | 0 | 6^**^ (1.8)
Lymph Node, Mandibular | 15 | 15 | 15 | 15 | 15 | 15
Hematopoietic Cell Proliferation | 0 | 0 | 1 (3.0) | 0 | 0 | 6^**^ (2.0)
Lymph Node, Mediastinal | 11 | 14 | 13 | 10 | 13 | 12
Hematopoietic Cell Proliferation | 0 | 0 | 0 | 0 | 0 | 5^*^ (2.0)
Lymph Node, Mesenteric | 15 | 14 | 14 | 15 | 15 | 15
Hematopoietic Cell Proliferation | 0 | 0 | 0 | 0 | 0 | 4^*^ (2.0)
All Organs | 15 | 15 | 15 | 15 | 15 | 15
Myelodysplasia | 0 | 0 | 0 | 0 | 0 | 2
Infiltration Cellular | 0 | 0 | 1 | 0 | 0 | 3
Infiltration Cellular, Plasma Cell | 0 | 0 | 1 | 0 | 0 | 2

* Significantly different (P≤0.05) from the vehicle control group by the Poly-3 test

** P≤0.01

a Number of animals with tissue examined microscopically

b Number of animals with lesion

c Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

d Number of animals with any tissue examined microscopically

## Contact Hypersensitivity Studies in BALB/c Mice

These studies are described in Appendix K. There were no deaths, body weight changes, or clinical findings related to trimethylolpropane triacrylate treatment in dosed mice. Results of the irritancy study indicated that the maximal nonirritating and minimal irritating doses were 0.1% and 0.25% trimethylolpropane triacrylate, respectively (Figure K4).

In the mouse ear swelling test, no significant differences in the percentage of ear swelling were observed between the trimethylolpropane triacrylatesensitized and challenged mice and the background controls at 24 or 48 hours after dosing (Figure K5). The local lymph node assay indicated no significant increase in lymph node cell proliferation in mice administered trimethylolpropane triacrylate compared to that in the vehicle controls (Figure K6).

Testing for sensitizing potential using the mouse ear swelling test and local lymph node assay failed to indicate trimethylolpropane triacrylate as a potential contact sensitizer at the concentrations tested.

## Genetic Toxicology

No increase in the frequency of micronucleated normochromatic erythrocytes was observed in peripheral blood samples from male or female mice administered dermal applications of 0.75 to 12 mg trimethylolpropane triacrylate/kg body weight for 3 (Table C1) or 6 months (Table C2). In the 3-month study, ratios of micronucleated polychromatic erythrocytes to NCEs in peripheral blood were unaltered by chemical treatment, indicating an absence of induced bone marrow toxicity. However, in the 6-month study, decreases in the percentages of circulating NCEs among total erythrocytes were noted in 12 mg/kg male and female mice, indicating a stimulation of erythropoiesis and the presence of increased numbers of immature erythrocytes in circulating blood.

PLATE 1 Normal skin (site of application) from a vehicle control B6C3F_1_ mouse in the 3-month dermal study. H&E; 25×

PLATE 2 Skin (site of application) from a male B6C3F_1_ mouse treated with 0.75 mg/kg trimethylolpropane triacrylate in the 3-month dermal study. There is no discernible difference from the vehicle control mouse skin in Plate 1. H&E; 25×

PLATE 3 Skin (site of application) from a male B6C3F_1_ mouse treated with 1.5 mg/kg trimethylolpropane triacrylate in the 3-month dermal study. When compared to the vehicle control mouse skin (Plate 1), there is an increased thickness (hyperplasia) of the epidermis (arrows) and increased cellularity (inflamma tion) of the superficial dermis (arrowheads). H&E; 25×

PLATE 4 Skin (site of application) from a male B6C3F_1_ mouse treated with 3 mg/kg trimethylolpropane triacrylate in the 3-month dermal study. Note the patchy hyperkeratosis and hyperplasia (arrows) of the epidermis and inflammation of the dermis (arrowheads). H&E; 25×

PLATE 5 Skin (site of application) from a male B6C3F_1_ mouse treated with 6 mg/kg trimethylolpropane triacrylate in the 3-month dermal study. The epidermis is hyperplastic and focally disrupted [degeneration (arrow)]. The dermis is inflamed and sebaceous glands are large (hyperplasia) and prominent (arrow heads). H&E; 25×

PLATE 6 Skin (site of application) from a male B6C3F_1_ mouse treated with 12 mg/kg trimethylolpropane triacrylate in the 3-month dermal study. Diffuse hyperker atosis, hyperplasia, and degeneration (arrows) of the epidermis. The hyper plastic sebaceous glands are also very prominent (arrowheads). H&E; 25×

PLATE 7 Skin (site of application) from a male B6C3F_1_ mouse treated with 12 mg/kg trimethylolpropane triacrylate in the 3-month dermal study. Higher magnification of Plate 6 to illustrate the prominent epidermal degeneration, necrosis (arrows), and inflammation. Also note the dermal inflammation and sebaceous gland hyperplasia. H&E; 50×

PLATE 8 Skin from a female Tg.AC mouse treated with 12 mg/kg trimethylopropane triacrylate in the 6-month dermal study. This is an early squamous cell carci noma that appears to be arising within a squamous cell papilloma. H&E; 2×

PLATE 9 Higher magnification of Plate 8. Note the islands of squamous epithelium within the base of the papillomatous mass. H&E; 20×

PLATE 10 Skin (site of application) in a Tg.AC mouse treated with 166 mg/kg rotenone in the 24-week skin application study. The magnification is the same as in Plate 7. Note the intense inflammatory infiltrate (arrowheads) in the dermis and epidermal hyperplasia. H&E; 50×