# INTRODUCTION

TRIMETHYLOLPROPANE TRIACRYLATE

CAS No. 15625-89-5

Chemical Formula: C_15_H_20_O_6_ Molecular Weight: 296.3

Synonyms: Acrylic acid, 2-ethyl-2-(((1-oxo-2-propenyl)oxy)methyl)-1,3-propanediol triester; A-TMPT; 2-ethyl-2-(hydroxymethyl)-1,3 propanediol triacrylate; 2-ethyl-2-(((2-oxo-2-propenyl)oxy)methyl)-1,3-propanediyl ester; 2-propenoic acid, 2-ethyl-2-(((1-oxo 2-propenyl)oxy)methyl)-1,3-propanediol ester; TMPTA; 1,1,1-trimethylolpropane triacrylate

Trade names: Aronix M 3090, Monosizer TD 1500A, NK Ester A-TMPT, SARTOMER SR 351, Setalux UV 2241, SR 351, Viscoat

## Chemical and Physical Properties

Trimethylolpropane triacrylate is a viscous, colorless liquid with an acrylic or pungent odor and a boiling point greater than 200° C at 1 mm Hg (Lenga, 1988; Alfa, 1990). At 25° C, it has a specific gravity of 1.1084 and a vapor pressure of less than 1.0 mm Hg (AIHA, 1981; ARCO, 1989); the refractive index is 1.4736 at 20° C (Lenga, 1988). It is insoluble in water and is hygroscopic, light sensitive, and incompatible with strong oxidizing agents, acids, and bases. Trimethylolpropane triacrylate may undergo spontaneous polymerization when exposed to direct sunlight and heat but may be stabilized with the monomethyl ester of hydroquinone (AIHA, 1981; Lenga, 1988). Trimethylolpropane triacrylate is combustible, with a flashpoint of greater than 110° C (Lenga, 1988). The chemical is reactive and is therefore not available as pure trimethylolpropane triacrylate.

## Production, Use, and Human Exposure

Trimethylolpropane triacrylate is manufactured from trimethylolpropane (Kirk-Othmer, 1978); acrylic acid is a known impurity in the technical-grade compound (Celanese, 1982). The U.S. Environmental Protection Agency’s Toxic Substances Control Act Inventory for 1983 indicated that 120,000 to 1.2 million pounds of trimethylolpropane triacrylate were produced in the United States by companies providing annual production volumes; no information on imported amounts was available (USEPA, 1990).

Trimethylolpropane triacrylate is a multifunctional monomer with a wide range of industrial applications as a cross-linking agent, reactive diluent, and chemical intermediate. It is used in the production of ultraviolet-curable inks, electron beam irradiation-curable coatings, and polymers and resins; as a component of photopolymer and flexographic printing plates and photoresists; and as an ingredient in acrylic glues, adhesives, and anaerobic sealants. It is used in colloidal dispersions for industrial baked coatings, waterborne and solvent-based alkyds, and vinyl/acrylic nonwoven binders. Additionally, trimethylolpropane triacrylate is used in paper and wood impregnates, wire and cable extrusion, polymer-impregnated concrete, and polymer concrete structural composites (Celanese, 1982; Björkner, 1984; Dearfield et al., 1989; Radak, 1990).

Workers involved in the manufacturing, processing, product handling, and application of trimethylolpropane triacrylate are at risk of exposure (AIHA, 1981). Surveys by the National Institute for Occupational Safety and Health (1990) indicated that approximately 4,180 workers were exposed to trimethylolpropane triacrylate between 1981 and 1983. The American Industrial Hygiene Association (1981) established a workplace environmental exposure level (8-hour time-weighted average) of 1 mg/m^3^ trimethylolpropane triacrylate; no other exposure regulations or recommendations have been established. A potential exists for widespread exposure of consumers through the use of trimethylolpropane triacrylate in products such as latex paints and floor polishes (Dearfield et al., 1989).

## Absorption, Distribution, and Excretion

In male F344/N rats, 18.7% of a single dermal dose of 130 mg/kg [^14^C]-trimethylolpropane triacrylate was absorbed and an average of 76% of the administered radiolabel was recovered unabsorbed 72 hours after dosing (Appendix L). In rats administered a 24-hour preexposure dose of nonradiolabeled trimethylolpropane triacrylate, 25% of a subsequent 151 mg/kg radiolabeled dose was absorbed and 65% was recovered unabsorbed from the dose site 72 hours after dosing. The absorption of dermally administered trimethylolpropane triacrylate was inversely related to dose; a total of 18.7% of the 130 mg/kg dose was absorbed, while 32.7% of the 15.2 mg/kg and 55.1% of the 1.7 mg/kg dose were absorbed. In mass terms, approximately five times more trimethylolpropane triacrylate was absorbed as the dose concentration increased by one order of magnitude.

An average of less than 5% of the dose was recovered in the excreta of rats 72 hours after dermal application of 130 mg/kg, compared to an average of approximately 19% of the 15.2 mg/kg dose and 45% of the 1.7 mg/kg dose (Appendix L). Very little radioactivity was associated with most of the tissues 72 hours after exposure; however, the kidney had elevated tissue:blood ratios at each dose concentration.

In male B6C3F_1_ mice, a total of 75% of dermally applied [^14^C]-trimethylolpropane triacrylate was absorbed 72 hours after a single 1.2 mg/kg dose (Appendix L). A much larger percentage of the applied radioactivity remained at the site of application in mice than in rats (31% in mice, 9% in rats). The collected tissues and residual carcass contained less than 2% of the administered dose. Approximately 21% of the dose remained unabsorbed, and approximately 42% was excreted in the urine, feces, and exhaled carbon dioxide after 72 hours. Very little radiolabel was associated with most of the tissues 72 hours after dosing; the non-application site skin, however, had an elevated tissue:blood ratio.

During the 72 hours following an intravenous bolus dose of 9.4 mg/kg [^14^C]-trimethylolpropane triacrylate to rats, a total of 77.4% of the radiolabel was excreted in the urine, feces, and exhaled carbon dioxide, with urine and exhaled carbon dioxide accounting for the largest percentages (Appendix L). Total radiolabel (but not parent trimethylolpropane triacrylate) was measured in the blood, and only slight changes in radiolabel concentrations were observed in blood after 1 hour. Among the tissues collected 72 hours after dosing, the highest radiolabel concentration was in the blood, and the average total recovery of radiolabel was 90% during the 72 hours after the intravenous dose.

To determine if the elevated kidney:blood ratios following dermal dosing were due to covalent binding of radio labeled compounds to tissue macromolecules, the binding of ^14^C to kidney samples from dermal and intravenous studies in rats was determined (Appendix L). The high kidney:blood ratios in dermally treated rats were not due to covalent binding of the radiolabeled compounds to kidney protein, but were probably associated with urine. In contrast, in the intravenous bolus study, the systemically available trimethylol propane triacrylate resulted in covalent binding to macromolecules associated with the kidney.

## Toxicity

### Experimental Animals

Acute oral LD_50_ values reported for trimethylolpropane triacrylate in rats were 3.84 to 7.01 mL trimethylol propane triacrylate/kg body weight (Carpenter et al., 1974) or 5,000 mg/kg (Andrews and Clary, 1986). Dermal LD_50_ values for rabbits were 200 to 2,000 mg/kg (Andrews and Clary, 1986), 3.89 to 10.04 mL/kg (Carpenter et al., 1974), or 5,170 mg/kg for a 24-hour exposure period (AIHA, 1981).

In a series of studies conducted by Celanese Corporation, Inc. (Andrews and Clary, 1986), trimethylolpropane triacrylate was administered undiluted or in acetone or mineral oil to the interscapular region of male C3H/HeJ mice. All five mice administered 50 mg undiluted trimethylolpropane triacrylate died 1 day after treatment; clinical findings included lethargy, inactivity, and salivation shortly after application. A group of three mice administered 50 mg of a 10% solution in acetone twice per week for 2 weeks developed epilated, crusty, severely burned skin. Very slight crusting of the skin was observed in mice treated with 50 mg of a 5% solution in mineral oil twice per week for 5 weeks.

Immunized, outbred, male and female Hartley guinea pigs (number per group not reported) received daily applications of 0.2 mL of a solution of 0.1%, 0.25%, or 0.5% trimethylolpropane triacrylate in acetone:olive oil (4:1) for 7 days (Parker and Turk, 1983). Skin reactions were graded on a scale of 0 (no reaction) to 3 (severe reaction). The guinea pigs developed mild to moderate skin sensitization.

In a sensitization study by Nethercott et al. (1983), groups of 10 female albino Hartley/Dalkin guinea pigs were induced and then challenged with trimethylol propane triacrylate. Three intradermal injections were administered to each shoulder: 0.1 mL of a 0.5% or 10% solution of trimethylolpropane triacrylate in propylene glycol; 0.05 mL Freund’s Complete Adjuvant (FCA) and 0.05 mL of a 0.5% or 10% solution of trimethylol propane triacrylate in propylene glycol; and 0.1 mL FCA. After 1 week, 0.5% or 10% trimethylolpropane triacrylate in petrolatum was applied to the animals’ shaved shoulders, which were then wrapped for 48 hours. The animals were challenged 2 weeks after the topical exposure with skin patches of nonirritant concentrations of trimethylolpropane triacrylate for 24 hours. Four guinea pigs that were administered 0.5% trimethylolpropane triacrylate and 10 of 20 administered the 10% solution became sensitized; the intradermal sensitivity concentration for 50% of the animals was determined to be 5.4%.

In a maximization test to determine skin sensitivity and cross-sensitivity reactions, groups of 15 female albino Dunkin/Hartley guinea pigs were sensitized topically with 25% solutions of commercial-grade pentaerythritol tri- or tetraacrylate in petrolatum and then challenged with two applications on the flank, 1 week apart, of 0.015 g pentaerythritol tri- or tetraacrylate (commercial grade and purified) or trimethylolpropane triacrylate in petrolatum (Björkner, 1984). A booster of the sensitizing chemical was administered intradermally on the neck 48 hours after the first challenge. Of the 10 animals that became sensitized to commercial-grade pentaerythritol triacrylate, seven also reacted to trimethylolpropane triacrylate. Only one guinea pig became sensitized to commercial-grade pentaerythritol tetraacrylate; this animal also reacted to trimethylolpropane triacrylate. These results indicated that pentaerythritol triacrylate was the more potent sensitizer and that guinea pigs sensitized to pentaerythritol triacrylate may cross-react to trimethylol propane triacrylate.

In a maximization test of acrylates and methacrylate esters, outbred female SSc:AL guinea pigs were induced with three 2 × 50 µL intradermal injections, including one of FCA in sterile water and one each of a test compound (methyl methacrylate, ethyleneglycol dimethacrylate, triethyleneglycol dimethacrylate, or trimethylolpropane trimethylacrylate) in soybean oil and in a mixture of emulsified FCA and water (Clemmensen, 1984). On day 7, approximately 250 mg of 10% sodium lauryl sulfate in petrolatum was applied to the neck and left uncovered for 24 hours. On day 8, the test compound or petrolatum (400 µL) was applied to a filter paper patch which was applied to the flank and left in place for 48 hours. On day 21, the guinea pigs were challenged with up to six patches containing 25 µL of the sensitizing compound; 2-hydroxy-methacrylate; 1,6-hexane diolodiacrylate; pentaerythritol triacrylate; or trimethylolpropane triacrylate. Sensitization determinations were made at 48 and 72 hours. The treatment was repeated on the opposite flank of each animal after 35 days. Positive skin sensitization reactions occurred in 14 of 19 guinea pigs induced with trimethylolpropane trimethylacrylate and challenged with 2% trimethylol propane triacrylate; animals induced with the other test chemicals did not have cross reactions with trimethylol propane triacrylate.

Parker et al. (1985) immunized outbred male and female Hartley guinea pigs (number not specified) with subcutaneous injection into the footpad and the nape of the neck with 0.1 mL of an emulsion containing trimethylol propane triacrylate in ethanol:saline (1:4) in FCA. The total trimethylolpropane triacrylate dose was 11.5 µmol. Skin tests of 0.02 mL of 0.25% or 0.5% trimethylol propane triacrylate in acetone:olive oil (4:1) were then applied to the shaved flank of the guinea pig, and reactions were recorded at 24, 48, 72, and 96 hours. Skin reactions were graded on a scale of 0 (no reaction) to 3 (severe reaction). On day 7, the reactions for both concentrations were mild at 24 hours and moderate at 48 hours; the 24- and 48-hour reactions on day 14 were moderate. Parker et al. (1985) also conducted cross sensitivity tests with trimethylolpropane triacrylate on groups of five guinea pigs immunized with methyl acrylate, methyl vinyl ketone, 4-vinyl pyridine, pentaerythritol triacrylate, and trimethylolpropane triacrylate in FCA. Cross sensitivity to trimethylolpropane triacrylate occurred in guinea pigs immunized with methyl acrylate, methyl vinyl ketone, and pentaerythritol triacrylate; the reactions were 20% to 60%, 60% to 80%, and greater than 80%, respectively, relative to the sensitizer response.

A radioimmunoassay detected no anti-trimethylol propane acrylate antibodies in the serum of outbred female Hartley guinea pigs immunized with trimethylol propane triacrylate (Bull et al., 1987). However, high concentrations of these antibodies were observed in the serum of guinea pigs immunized with bovine ϒ-globulin. Prior to analysis, the immunized serum dilutions were incubated with egg albumin and 0.5 µg/mL to 5 mg/mL trimethylolpropane triacrylate, methyl acrylate, or 4-vinyl pyridine for 2 hours. The amount of bound radiolabel decreased with increasing dose, indicating that the anti-trimethylolpropane triacrylate/bovine ϒ-globulin antibodies specifically reacted with trimethylolpropane triacrylate and cross-reacted with methyl acrylate.

In studies conducted by Bull et al. (1985), lymph nodes of trimethylolpropane triacrylate-immunized guinea pigs were examined for T-lymphocyte proliferation 4 to 6 days after application of 50 µmol trimethylolpropane triacrylate to the ear. The numbers of large pyroninophilic cells in the lymph nodes were significantly increased 4 to 6 days after epicutaneous dosing. A positive correlation was noted between skin contact reactions and increases in lymph node weight and T-lymphocyte proliferation.

### Humans

A number of studies have reported the development of dermatitis, characterized by itching of the exposed skin followed by erythema and scaling upon prolonged exposure, after workplace exposure to compounds containing trimethylolpropane triacrylate. In many cases of exposure to industrial mixtures of acrylates, individuals displayed positive reactions to two or more acrylates, making it difficult to establish the potency of trimethylolpropane triacrylate alone (Anonymous, 1985). Irritant or allergic contact dermatitis and irritant contact conjunctivitis occurred in 15 of 19 workers who cured multifunctional acrylic monomers in ultraviolet-curable inks (Nethercott, 1978). Three workers did not have direct contact with the acrylic monomers and were apparently exposed to airborne vapors. Two workers with allergic contact dermatitis had positive vesicular skin reactions to a 48-hour skin patch test with 0.1% trimethylol propane triacrylate.

After trimethylolpropane triacrylate and pentaerythritol triacrylate were introduced as components of radiation drying ink in an ink formulating facility, five of 26 workers developed eczematous dermatitis (Emmett, 1977). Four of the five affected workers had positive reactions to patch tests using 0.2% trimethylolpropane triacrylate in a varnish formulation or in solution in petrolatum; the fifth worker developed irritant dermatitis to undiluted polyfunctional acrylates. Björkner et al. (1980) reported the development of allergic dermatitis in six people who worked with ultraviolet-curable inks containing trimethylolpropane triacrylate for 3 to 32 weeks. All six had positive reactions to skin patch tests with 0.1% or 0.5% trimethylolpropane triacrylate in acetone. Seven of 10 workers exposed to ultraviolet-curable printing inks at a plastic food container manufacturing plant developed contact dermatitis; one person had a positive reaction for sensitization to 0.1% trimethylolpropane triacrylate in petrolatum (Nethercott et al., 1983).

Four workers in a plastic floor manufacturing facility developed hand and face dermatitis a year after the introduction of a varnish with an aziridine-based hardener containing 3% to 5% trimethylolpropane triacrylate (Dahlquist et al., 1983). The workers had positive reactions to skin patch tests with trimethylolpropane triacry late in acetone at 0.0001% (1/4), 0.03% (3/4), and 0.1% (4/4), with the most severe reactions occurring in the worker who reacted to the 0.0001% formulation. Contact dermatitis occurred in 13 of 51 workers at a wallpaper printing company following the introduction of a water-based ink containing a polyfunctional aziri dine hardening agent, of which trimethylolpropane triacrylate was a component (Garabrant, 1985). A worker in optical fiber manufacturing developed dermatitis of the hands, face, and eyelids after 2 years of exposure to ultraviolet-curing acrylate resin coatings containing trimethylolpropane triacrylate and urethane acrylate; the dermatitis cleared within a week after the exposure ended (Maurice and Rycroft, 1986). This worker had positive reactions to 2- and 4-day skin patch tests with 0.01% (2-day test only) and 0.1% trimethylolpropane triacrylate in petrolatum.

Cofield et al. (1985) reported that five of 44 patients administered a skin patch test with 0.5% trimethylol propane triacrylate in petrolatum demonstrated irritant reactions which diminished after 1 week; concentrations of 0.001% to 0.19% induced no reactions. A group of 50 patients had no reaction to a skin patch test of a cross-linking agent (containing trimethylolpropane triacrylate and aziridine) at a concentration of 0.1% in petrolatum.

Skin sensitivity and photo patch testing of 0.2% trimethylolpropane triacrylate in petrolatum was performed on 47 employees of a citrus juice bottling plant who were exposed to ultraviolet-cured printing inks (NIOSH, 1987). All 47 workers had positive reactions to one or both tests. Because few workers showed skin sensitization to trimethylolpropane triacrylate, the past skin reactions were considered to be irritant, not allergic, reactions to the inks and their components.

## Reproductive and Developmental Toxicity

No data on the reproductive or teratogenic effects of trimethylolpropane triacrylate in animals or humans were found in the literature.

## Carcinogenicity

### Experimental Animals

No neoplasms occurred in 50 male C3H/HeJ mice administered 100 mg/kg dermal applications of a solution of 5% trimethylolpropane triacrylate in mineral oil to the interscapular region twice per week for up to 80 weeks (Andrews and Clary, 1986). Ten percent of the group was examined histologically. Slight epilation of the skin was noted at the site of application; in addition, acanthosis of the epidermis occurred in 46 mice and fibrosis of the dermis in 38 mice. No lesions were noted in control mice.

### Humans

No epidemiology studies or case reports associating trimethylolpropane triacrylate exposure with cancer risk in humans were found in the literature.

## Related Compounds

In a series of studies of eight multifunctional alkyl acrylates performed by Celanese Corporation, Inc., groups of 50 male C3H/HeJ mice were given dermal applications twice weekly for up to 80 weeks (Andrews and Clary, 1986). No increases in the incidences of skin or visceral tumors were induced by trimethylolpropane triacrylate; trimethylolpropane trimethacrylate; 1,6-hexanediol diacrylate; tripropyleneglycol diacrylate; or triethyleneglycol dimethacrylate. However, pentaerythritol triacrylate, triethyleneglycol diacrylate, and tetraethyleneglycol diacrylate showed some potential for carcinogenicity when administered at doses of 100 mg/kg in mineral oil. Pentaerythritol triacrylate induced lymphoma with spleen or lymph node involvement in six mice. However, these lesions were not verified in subsequent examinations. Triethyleneglycol diacrylate induced skin tumors in six mice and lymphomas in four mice; tetraethyleneglycol diacrylate induced skin tumors in six mice. However, in 78-week dermal carcinogenicity studies, neither triethyleneglycol diacrylate (0.05%, 0.1%, or 0.5% in acetone) nor triethyleneglycol dimethacrylate (5%, 25%, or 50% in acetone) were carcinogenic in male C3H/HeNHsd mice (Van Miller et al., 2003).

In another study, groups of 40 male C3H/HeJ mice were given dermal applications of 5 mg (approximately 200 mg/kg) neopentylglycol diacrylate or 3 mg (approximately 120 mg/kg) pentaerythritol triacrylate in acetone three times weekly for the lifetime of the animals (DePass et al., 1995). Among mice administered neopentylglycol diacrylate, five had sking papilloma and three had skin carcinoma. No skin neoplasms were observed in pentaerythritol triacrylate-treated mice.

## Genetic Toxicity

Trimethylolpropane triacrylate monomer (79% pure) demonstrated weak mutagenic activity in Salmonella typhimurium strain TA1535 in the presence of hamster liver S9 activation enzymes (Cameron et al., 1991); negative results were obtained with other strains, with and without induced rat or hamster liver S9 enzymes. Tests of the cross-linked polymer (with molecular weights ranging up to 1,000,000) at concentrations up to 6,666 µg/plate showed no mutagenic activity in any of several strains of S. typhimurium, with or without exogenous metabolic activation derived from induced rat liver (Thompson et al., 1991).

Trimethylolpropane triacrylate monomer (0.6, 0.65, and 0.7 µg/mL) was tested in L5178Y mouse lymphoma cells without exogenous metabolic activation for induction of forward mutations at the tk locus, chromosomal aberrations, and micronuclei (Dearfield et al., 1989). Significant dose-related increases in frequencies were observed for all three endpoints; mutant tk colonies were almost exclusively small in size, indicative of the induction of large deletions or other chromosomal alterations rather than point mutations. Further supporting a clastogenic mechanism for the mutagenicity of trimethylol propane triacrylate are the results of comparative studies reported by Moore et al. (1989) which were conducted with the tk locus in L5178Y cells and the hemizygous hgprt locus in Chinese hamster ovary cells as targets. Although significant increases in mutant tk small colonies were observed in the L5178Y cells, no increase in the frequency of hgprt mutant Chinese hamster ovary cells was observed. The authors suggested that the hemizygous nature of the hgprt locus renders it insensitive to the action of clastogens. Results reported by Cameron et al. (1991) confirmed the positive results with the trimethylolpropane triacrylate monomer in mutagenicity tests using L5178Y mouse lymphoma cells without S9 activation. The trimethylolpropane triacrylate cross-linked polymer was also tested in L5178Y mouse lymphoma cells for induction of mutations in the presence and absence of exogenous metabolic activation; the results were negative over a range of concentrations up to 1,392 µg/mL (Thompson et al., 1991). Results of additional tests with the trimethylol propane triacrylate cross-linked polymer that were part of the comprehensive investigation by Thompson et al. (1991) showed no induction of unscheduled DNA synthesis in rat primary hepatocyte cultures and no increase in the incidence of chromosomal aberrations in the bone marrow of male or female rats administered the polymer as a slurry by oral gavage in amounts up to 16 mL/kg. The trimethylolpropane triacrylate monomer was positive in tests for induction of chromosomal aberrations in Chinese hamster ovary cells and L5178Y mouse lymphoma cells, producing dose-related increases in the frequency of aberrations in both systems at doses up to 0.7 µg/mL (Moore et al., 1989).

## Study Rationale

Trimethylolpropane triacrylate was nominated by the National Cancer Institute for study due to its high production volume and use, the potential for human exposure, and the lack of adequate chronic toxicity and carcinogenicity data. It was also chosen as a representative of the multifunctional acrylate class. Trimethylolpropane triacrylate is a suspected carcinogen as a member of this class of compounds; some members of this class have been shown to be carcinogenic to mice in dermal studies.

The major route of human exposure to trimethylol propane triacrylate is via the skin. At the time of study design, the Tg.AC mouse model was showing promise relative to carcinogenicity testing (hazard identification) via dermal exposure. Efforts were under way to to assess more fully the potential of the model. Therefore, it was decided to conduct initial studies in the Tg.AC mouse model and, upon completion of the studies, assess the findings in light of updated information about the model. Importantly, this process allowed assessment of studies in the Tg.AC mouse model in a completely prospective manner.