# APPENDIX L ABSORPTION, DISTRIBUTION, AND EXCRETION STUDIES

## Introduction

Studies were conducted in adult male F344/N rats and B6C3F_1_ mice to determine the absorption, distribution, and excretion of trimethylolpropane triacrylate following intravenous bolus injection or dermal application. These studies were conducted by Research Triangle Institute (Research Triangle Park, NC).

## Materials and Methods

Technical-grade unlabeled trimethylolpropane triacrylate was obtained from Aldrich Chemical Company (Milwaukee, WI) in two lots (03115TV and 03914PV). Identity and purity analyses were conducted by the study laboratory. Proton- and ^13^C-nuclear magnetic resonance and mass spectra were consistent with the structure. Reverse phase high-performance liquid chromatography (HPLC) indicated the presence of several ultraviolet-absorbing impurities that were not identified.

[^14^C]-Trimethylolpropane triacrylate (7.5 mCi, lot 91-350-35-02 and 5 mCi, lot R90-306-69-34) was obtained from Chemsyn Science Laboratories (Lenexa, KS). The chemical’s identity was confirmed by coelution of [^14^C]-trimethylolpropane triacrylate with unlabeled trimethylolpropane triacrylate by reverse phase HPLC. The radiochemical purity of [^14^C]-trimethylolpropane triacrylate was determined to be less than 70%. After development and application of a purification method, the average radiochemical purity of [^14^C]-trimethylolpropane triacrylate was determined to be 98.8%.

Young adult male F344/N rats (240-306 g) and adult B6C3F_1_ mice (25-35 g) were obtained from Charles River Laboratories (Raleigh, NC, and Kingston, NY). Animals were coded by ear tags and quarantined for approximately 1 week. Purina Rodent Chow No. 5002 and tap water were available ad libitum. Prior to the experiments, rats and mice were housed up to a maximum of four animals per cage in polycarbonate cages. During the excretion studies, animals were housed individually in glass metabolism chambers that allowed for separate collection of urine, feces, and exhaled CO_2_ beginning at least 1 day before the studies.

Rats received a single intravenous injection of 9.4 mg [^14^C]-trimethylolpropane triacrylate/kg body weight or a single dermal dose of 1.7, 15.2, or 130 mg/kg (13.3, 7.2, 10.5, and 10.5 µCi, respectively). In a dermal-tape stripping experiment in rats, successive strips of the washed application site skin were analyzed following a single 124 mg/kg dose of [^14^C]-trimethylolpropane triacrylate (3.8 µCi). In a preexposure study, rats were given a dermal dose of 151 mg/kg unlabeled trimethylolpropane triacrylate followed 24 hours later by a single dermal dose of 151 mg/kg [^14^C]-trimethylolpropane triacrylate (8.9 µCi). Mice received a single dermal dose of 1.2 mg/kg [^14^C]-trimethylolpropane triacrylate (2.1 µCi). In ancillary tolerance studies, rats were administered single intravenous doses of 0.1, 1, or 10 mg/kg or single dermal doses of 16.2, 34.5, 63.4, 91, or 124 mg/kg unlabeled trimethylolpropane triacrylate.

Rats in the intravenous bolus study were anesthetized with an intramuscular or intraperitoneal dose of 60 mg/kg ketamine:xylazine (7:1) or an intraperitoneal dose of 80 to 100 mg/kg ketamine:xylazine:acepromazine (10:1:1) and then implanted with indwelling jugular cannulae to facilitate the collection of blood samples. The design of the cannula was similar to that of Harms and Ojeda (1974) as modified by McKenna and Bieri (1984). The rats were allowed to recover for at least 1 day before dosing. At the time of dosing, the rats were restrained and the intravenous dose was administered as a bolus injection into a lateral tail vein.

Animals in dermal dosing experiments were sedated with an intramuscular dose of 60 mg/kg ketamine:xylazine (7:1) approximately 24 hours before dermal doses were applied, and the fur on the back of each animal was clipped. The clipped area was wiped with acetone, dried, and examined; animals with broken skin in the clipped area were excluded from the study. The doses were applied to 1 square inch (rats) or 0.5 square inch (mice) previously outlined with a permanent, felt-tip marker. Before dosing, a self-adhering protective foam appliance with a center-cut window was glued onto the back of each rat with Hollister^®^ medical adhesive (Hollister, Inc., Libertyville, IL). Doses were administered with either a ball-tipped gavage needle and glass syringe equipped with a Teflon^®^-tipped plunger or a silylated glass wiretrol (Drummond Scientific Co., Broomall, PA) to the square inch of skin exposed through the window in the foam appliance. After dosing was complete, a cloth cover was attached to the foam appliance, and a protective metal cover was secured over the appliance with either Elastoplast^®^ or Coban^®^ adhesive bandage (3M Medical-Surgical Division, St. Paul, MN).

After dosing the mice, a halved tissue capsule (Fisher HistoPrep; Fisher Scientific Company, Pittsburgh, PA), the latticed top of which was covered with 50/50 polyester/cotton sheeting, was glued over the dosing site with Dura Quick Gel super glue (Loctite Corp., Rocky Hill, CT). Doses were administered to the shaved skin of mice with a 50 µL wiretrol.

Radiolabeled dose formulations were prepared with purified [^14^C]-trimethylolpropane triacrylate, which had been concentrated from HPLC fractions. Individual doses of [^14^C]-trimethylolpropane triacrylate reconstituted in the appropriate solvent were prepared the day before dosing. The intravenous injection dose was formulated in a mixture of absolute ethanol, Emulphor^®^, and phosphate-buffered saline by adding appropriate quantities of labeled and nonlabeled trimethylolpropane triacrylate to yield a final specific activity of 5.73 µCi/mg trimethylolpropane triacrylate. All dermal doses were prepared by dissolving appropriate quantities of labeled and/or nonlabeled trimethylolpropane triacrylate in acetone. (Final specific activities of the radiolabeled doses for the 1.2 mg/kg mouse and 1.7, 15.2, 124 (tape stripping), 130, and 151 (preexposure) rat studies were 54, 7.2, 2.6, 0.275, and 0.229 µCi trimethylolpropane triacrylate, respectively.)

For the definitive dermal studies in male rats, groups of four or five animals were administered single dermal applications of 1.7, 15.2, 130, or 151 mg [^14^C]-trimethylolpropane triacrylate/kg body weight. Animals in the 151 mg/kg group had been preexposed to a single dermal dose of unlabeled trimethylolpropane triacrylate at the same concentration approximately 24 hours before the radiolabeled dose. Urine and feces were collected separately into round-bottom flasks cooled with dry ice. Exhaled ^14^CO_2_ was collected by passing air from the metabolism cages through two traps containing room temperature 1 N sodium hydroxide. To measure cumulative excretion of radiolabel, collection flasks and traps were changed at 8, 24, 48, and 72 hours postdosing. At 72 hours postdosing, the cages were rinsed, and the dosing appliances were removed from the anesthetized animals. The dosing site skin was washed and collected for analysis of acetone-extractable and nonextractable radiolabel. Skin samples from the 1.7 mg/kg group were not extracted. Blood was withdrawn from the animals into a heparinized syringe by cardiac puncture. The animals were sacrificed by intracardiac injection of Euthanasia-6^®^ (Sparhawk Veterinary Laboratories, Inc., Lenexa, KS) or by carbon dioxide asphyxiation. Bladder urine was removed from each animal and added to the final urine collection. Selected tissues were removed from the carcasses and the blood, urine, and tissues were stored at −20° C for subsequent analysis of total radiolabel.

Aliquots of urine, cage rinse, skin wash, and breath trap contents were mixed with scintillation cocktail and directly assayed for ^14^C content by liquid scintillation spectrometry (LSS); aliquots of blood, feces, and tissues were digested in Soluene 350^®^ (Packard Instrument Company, Meriden, CT), neutralized, decolorized with perchloric acid and hydrogen peroxide, and assayed for total radiolabel. Skin samples and the residual carcass were digested in 2 N ethanolic sodium hydroxide prior to analysis for radiolabel. The dosing appliances were cut into eight pieces, added to scintillation vials containing 2 mL methanol, and analyzed by LSS. Appropriate background samples containing the same combination of reagents as the corresponding biological samples were prepared for all sample types.

A group of five male mice was administered a single dermal dose of 1.2 mg [^14^C]-trimethylolpropane triacrylate/kg. Urine, feces, breath, cage rinse, skin wash, appliance, and tissue samples were collected, digested, and analyzed as in the definitive dermal studies in rats, except the skin samples were not extracted with acetone prior to digestion.

In the dermal tape stripping experiment, groups of four male rats were given either 0.5 or 72 hours exposure to a single dermal application of 124 mg [^14^C]-trimethylolpropane triacrylate/kg followed by 15 strippings of residual radiolabel from the washed dosing site using 2.5 inch × 2.5 inch pieces of Scotch tape (3M^®^, St. Paul, MN). The tape strips and an acetone extract of the dosing site skin were analyzed for radiolabel by LSS and the presence of trimethylolpropane triacrylate by HPLC, respectively.

In the intravenous injection study, a group of five male rats was given a single bolus dose of 9.4 mg [^14^C]-trimethylolpropane triacrylate/kg. Serial blood collections were taken at 0.08, 0.5, 1, 3, 6, 24, and 48 hours from the indwelling cannula and at 72 hours by cardiac puncture to analyze for blood concentrations of radiolabel. Urine, feces, cage rinse, and exhaled ^14^CO_2_ were collected and analyzed for cumulative excretion of radiolabel as in the definitive dermal rat studies except that collections were made at 3, 6, 24, 48, and 72 hours postdosing. Tissue samples were collected at 72 hours postdosing and digested and analyzed for radiolabel as described for the definitive dermal studies in rats.

Kidney samples from the 15.2 mg/kg (dermal) and 9.4 mg/kg (intravenous injection) groups were analyzed to determine the extent of covalent binding of radiolabeled trimethylolpropane triacrylate to kidney protein using the methods of Jollow et al. (1973). Homogenized samples were precipitated four times with 0.6 M trichloroacetic acid, and each supernatant was assayed for radiolabel by LSS. The final pellet was extracted four times with methanol:water (80:20), and each extract was assayed for radiolabel by LSS. The final extracted pellet was assayed for protein concentration and radiolabel.

## Results and Discussion

Combined results of the definitive and ancillary dermal tolerance studies (data not shown) revealed irritation of the skin (erythema and edema) at all dermal dose levels with the lowest doses (1.5 mg/kg in rats and 1.2 mg/kg in mice) exhibiting only slight irritation.

In rats, 18.7% of a single dermal dose of 130 mg [^14^C]-trimethylolpropane triacrylate/kg was absorbed and an average of 76% of the administered radiolabel was recovered unabsorbed from the appliance and dose site skin 72 hours after dosing (Table L1). In animals administered a 24-hour preexposure dose of nonradiolabeled trimethylolpropane triacrylate, 25% of the subsequent 151 mg/kg radiolabeled dose was absorbed and 65% was recovered unabsorbed from the dose site 72 hours after dosing. These results indicate that preexposed rats absorbed 1.33 times as much [^14^C]-trimethylolpropane triacrylate as animals that were not preexposed. Because the site of application appeared irritated after a single application of trimethylolpropane triacrylate, chronic exposure may make the skin more permeable to subsequent trimethylolpropane triacrylate exposures. Absorption of dermally administered trimethylolpropane triacrylate was inversely related to dose; a total of 18.7% of the 130 mg/kg dose was absorbed, while 32.7% of the 15.2 mg/kg and 55.1% of the 1.7 mg/kg dose were absorbed. In terms of mass, approximately five times more was trimethylolpropane triacrylate was absorbed as the dose level increased by one order of magnitude. Most of the radiolabel remaining in the animals 72 hours after dermal application was associated with the skin at the dose site. Nonabsorbed test chemical was removed from this skin by thorough washing with soapy water at the end of the dermal study. Acetone extracted 8%, 10%, and 9%, respectively, of the dose from the site of application of rats administered single doses of 15.2, 130 or 151 mg/kg (preexposed). HPLC analysis of the acetone extracts showed that trimethylolpropane triacrylate was the major constituent removed from the skin by acetone 72 hours after exposure (Figure L1).

An average of less than 5% of the dose was recovered in the excreta of rats 72 hours after dermal application of 130 mg/kg, compared to an average of approximately 19% of the 15.2 g/kg dose and 45% of the 1.7 mg/kg dose (Table L2). Very little radioactivity was associated with most of the tissues 72 hours after exposure (Table L3); however, for each of the studies, the kidney had elevated tissue:blood ratios.

In mice, a total of 75% of the dermally applied [^14^C]-trimethylolpropane triacrylate was absorbed 72 hours after a single dose of 1.2 mg/kg, approximately 1.4 times as much as was absorbed by rats administered a similar dose (Table L4). This result was not surprising because mouse skin is generally considered to be more permeable than rat skin. A much larger percentage of the applied radioactivity remained at the site of application in mice than in rats (31% in mice, 9% in rats). The collected tissues and residual carcass contained less than 2% of the administered dose. Approximately 21% of the dose remained unabsorbed after 72 hours, yet the dose site showed very little skin irritation. Approximately 42% of the dose was excreted by mice in the urine, feces, and exhaled CO_2_ by 72 hours after dosing (Table L5), an amount similar to that excreted by rats treated with 1.7 mg/kg. Similar to the studies in rats, very little radiolabel was associated with most of the tissues 72 hours after dosing; the skin, however, did have an elevated tissue:blood ratio (Table L6).

The tape stripping experiment was conducted in rats to further determine whether trimethylolpropane triacrylate is stable on the skin and absorbed as the parent compound. After a single 124 mg/kg dermal application of [^14^C]-trimethylolpropane triacrylate and wash of the site of application either 30 minutes or 72 hours postdosing, the site was repeatedly stripped with Scotch^®^ tape. The quantity of radiolabel removed by the tape decreased as the tape strip number increased (Figure L2). On average, 1.3% of the radiolabeled dose was removed by tape stripping after a 30-minute exposure and 1.6% of the dose was removed after a 72-hour exposure.

Following 72 hours of exposure, acetone extracts of the stripped, sliced skin were prepared and analyzed by HPLC; the major peak, accounting for approximately 73% of the radiolabel, was associated with trimethylolpropane triacrylate (Figure L3). Two more peaks accounted for 14% and 10% of the radiolabel. Parent trimethylolpropane triacrylate was therefore the major xenobiotic in the skin at the dosing site and most likely the major xenobiotic available to the systemic circulation throughout the studies.

Ancillary tolerance studies indicated that single intravenous injections of 0.1, 1, and 10 mg trimethylolpropane triacrylate/kg into the lateral tail vein of rats were all adequately tolerated (data not shown). During the 72 hours following a bolus dose of 9.4 mg/kg [^14^C]-trimethylolpropane triacrylate/kg to rats in the definitive intravenous study, a total of 77.4% of the radiolabel was excreted in the urine, feces, and exhaled CO_2_ (Table L7). Urine and exhaled CO_2_ accounted for the largest percentages (approximately 48% and 20%, respectively). Preliminary stability studies indicated that [^14^C]-trimethylolpropane triacrylate was chemically unstable in whole blood (data not shown). Accordingly, total radiolabel (but not parent trimethylolpropane triacrylate) was reliably measured in blood, and only slight changes in radiolabel concentrations were observed in blood after 1 hour (Table L8). Among the tissues collected 72 hours after dosing, the highest radiolabel concentration was in the blood (Table L9). The average total recovery of radiolabel was 90% during the 72 hours after the intravenous dose (Table L10).

Elevated kidney:blood ratios of radiolabel (approximately 3.3-11.1) were noted in rats after dermal exposures to [^14^C]-trimethylolpropane triacrylate (Table L3). However, urinary excretion of radiolabel during the interval from 48 to 72 hours after dosing was minimal (approximately 1%-7%; Table L2). The kidney:blood ratio of radiolabel after intravenous bolus administration was not elevated (0.19; Table L9).

To determine whether the elevated kidney:blood ratios following dermal doses were due to covalent binding of radiolabeled compounds to tissue macromolecules, the binding of ^14^C to kidney samples from dermal and intravenous studies in rats was analyzed. As shown in Table L11, the nature of binding varied with the route of administration. Approximately 94% of the radiolabel was recovered in the trichloroacetic acid supernatants and approximately 1% in the methanol:water extracts of the kidney homogenates prepared from animals that had been exposed dermally. This result indicates that the high kidney:blood ratios in dermally dosed rats were not due to covalent binding of radiolabeled compounds to kidney proteins. In contrast, the fact that 60% of the radiolabel remained in the trichloroacetic acid-precipitated pellets prepared from the intravenous bolus study indicates that systemically available trimethylolpropane triacrylate results in covalent binding to macromolecules associated with the kidney. Because trimethylolpropane triacrylate is reactive in blood and remains in circulation at substantial levels (approximately 14 µg-Eq/g blood 72 hours after a 9.4 mg/kg intravenous bolus dose; Table L8), the elevated kidney:blood ratio seen after dermal exposure may be due to urine in the making at the time of necropsy.

## References

Harms, P.G. and Ojeda, S.R. (1974). A rapid and simple procedure for chronic cannulation of the rat jugular vein. J. Appl. Physiol. 36, 319–392.
Jollow, D.J., Mitchell, J.R., Potter, W.Z., Davis, D.C., Gillette, J.R., and Brodie, B.B. (1973). Acetaminophen-induced hepatic necrosis. II. Role of covalent binding in vivo. J. Pharmacol. Exp. Ther. 187, 195–202.4746327
McKenna, M.C., and Bieri, J.G. (1984). Multilayer cannula for long-term infusion of unrestrained rats. Lab. Anim. Sci. 34, 308–310.6748611

TABLE L1 Distribution of Radiolabel in Male F344/N Rats 72 Hours after a Single Dermal Application of [^14^C]-Trimethylolpropane Triacrylate^a^

| 1.7 mg/kg^b^ | 15.2 mg/kg | 130 mg/kg | 151 mg/kg^c^
Absorbed Dose
Urine | 28.0 ± 1.2 | 12.1 ± 1.4 | 3.0 ± 0.4 | 5.8 ± 1.5
Cage wash | 0.9 ± 0.4 | 0.9 ± 0.4 | 0.1 ± 0.0 | 0.4 ± 0.2
Feces | 2.51 ± 0.5 | 1.2 ± 0.2 | 0.2 ± 0.1 | 0.4 ± 0.2
Exhaled CO_2_ | 13.1 ± 1.4 | 4.9 ± 0.8 | 1.4 ± 0.2 | 3.4 ± 1.1
Dose site skin
Acetone extractable | —^d^ | 8.0 ± 2.3 | 10.4 ± 5.1 | 8.5 ± 1.0
Nonextractable | 8.5 ± 1.4 | 3.3 ± 0.6 | 3.2 ± 1.3 | 2.6 ± 0.6
Selected tissues | 0.4 ± 0.1 | 1.0 ± 0.1 | 0.2 ± 0.0 | 0.7 ± 0.3
Residual carcass | 1.7 ± 0.3 | 1.2 ± 0.2 | 0.3 ± 0.0 | 3.6 ± 2.3
Total Absorbed Dose | 55.1 ± 3.0 | 32.7 ± 4.6 | 18.7 ± 6.7 | 25.4 ± 4.4
Total Unabsorbed Dose^e^ | 34.8 ± 4.8 | 57.0 ± 5.2 | 76.1 ± 6.3 | 65.3 ± 6.4
Total Dose Recovery | 90.0 ± 2.9 | 89.7 ± 1.3 | 94.8 ± 2.3 | 90.7 ± 2.2

a Data are presented as percentage of dose (mean ± standard deviation) for five animals.

b n=4

c Animals were preexposed to a single dermal dose of 151 mg/kg unlabeled trimethylolpropane triacrylate 24 hours before administration of the radiolabeled dose.

d Skin samples not extracted

e Total radioactivity in appliance and skin wash

FIGURE L1 High-Performance Liquid Chromatographic Analysis of [^14^C]-Trimethylolpropane Triacrylate and Acetone Extracts of Dose Site Skin 72 Hours after a Single Dermal Application of 130 or 151 mg/kg [^14^C]-Trimethylolpropane Triacrylate to Male F344/N Rats

Animals dosed with 151 mg/kg were preexposed to a single dermal application of 151 mg/kg unlabeled trimethylolpropane triacrylate.

TABLE L2 Cumulative Excretion of Radiolabel by Male F344/N Rats after a Single Dermal Application of [^14^C]-Trimethylolpropane Triacrylate^a^

Time (hours after dosing) | Urine | Feces | Exhaled CO_2_ | Cage Rinse
1.7 mg/kg^b^
8 | 2.3 ± 0.8 | 0.0 ± 0.0 | 2.1 ± 0.4 | —^c^
24 | 10.6 ± 0.9 | 0.9 ± 0.2 | 6.6 ± 0.8 | —
48 | 21.1 ± 0.8 | 1.9 ± 0.4 | 10.6 ± 1.1 | —
72 | 28.0 ± 1.2 | 2.5 ± 0.5 | 13.1 ± 1.4 | 0.9 ± 0.4
Total^d^ | 44.6 ± 2.7
15.2 mg/kg
8 | 0.5 ± 0.1 | 0.0 ± 0.0 | 0.4 ± 0.6 | —
24 | 3.1 ± 0.3 | 0.3 ± 0.1 | 1.5 ± 0.2 | —
48 | 7.2 ± 1.1 | 0.8 ± 0.1 | 3.1 ± 0.5 | —
72 | 12.1 ± 1.4 | 1.2 ± 0.2 | 4.9 ± 0.8 | 0.9 ± 0.4
Total | 19.2 ± 2.5
130 mg/kg
8 | 0.1 ± 0.1 | 0.0 ± 0.0 | 0.1 ± 0.0 | —
24 | 0.6 ± 0.2 | 0.0 ± 0.0 | 0.5 ± 0.0 | —
48 | 1.7 ± 0.2 | 0.1 ± 0.0 | 0.9 ± 0.2 | —
72 | 3.0 ± 0.4 | 0.2 ± 0.1 | 1.4 ± 0.2 | 0.1 ± 0.0
Total | 4.7 ± 0.6
151 mg/kg^e^
8 | 0.1 ± 0.0 | 0.0 ± 0.0 | 0.1 ± 0.0 | —
24 | 1.0 ± 0.2 | 0.1 ± 0.0 | 0.5 ± 0.1 | —
48 | 3.0 ± 0.8 | 0.2 ± 0.1 | 1.7 ± 0.4 | —
72 | 5.8 ± 1.5 | 0.4 ± 0.2 | 3.5 ± 1.1 | 0.4 ± 0.2
Total | 10.1 ± 2.8

a Data are presented as cumulative percentage of dose (mean ± standard deviation) for five animals.

b n=4

c Samples not collected at this time point

d 72-Hour cumulative total of excreted radiolabel

e Animals were preexposed to a single dermal dose of 151 mg/kg unlabeled trimethylolpropane triacrylate 24 hours before administration of the radiolabeled dose.

TABLE L3 Tissue Distribution of Radiolabel in Male F344/N Rats 72 Hours after a Single Dermal Application of [^14^C]-Trimethylolpropane Triacrylate^a^

Tissue | Trimethylolpropane Triacrylate Equivalents in Tissue (ng/g) | Tissue-to-Blood Ratio | Dose in Total Tissue^b^ (%)
1.7 mg/kg^c^
Adipose | 11 ± 3 | 0.11 ± 0.05 | 0.04 ± 0.01
Bladder | 89 ± 52 | 0.92 ± 0.64 | 0.00 ± 0.00
Blood | 104 ± 29 | —^d^ | 0.30 ± 0.09
Brain | 7 ± 1 | 0.07 ± 0.02 | 0.00 ± 0.00
Heart | 43 ± 21 | 0.40 ± 0.08 | 0.01 ± 0.01
Kidney | 500 ± 86 | 4.98 ± 1.02 | 0.20 ± 0.04
Liver | 66 ± 8 | 0.66 ± 0.14 | 0.12 ± 0.02
Lung | 67 ± 31 | 0.63 ± 0.12 | 0.02 ± 0.01
Muscle | 8 ± 1 | 0.08 ± 0.03 | 0.20 ± 0.03
Skin | 22 ± 3 | 0.22 ± 0.03 | 0.20 ± 0.03
Spleen | 69 ± 20 | 0.67 ± 0.13 | 0.01 ± 0.00
Testis | 10 ± 2 | 0.11 ± 0.03 | 0.01 ± 0.00
15.2 mg/kg
Adipose | 75 ± 45 | 0.14 ± 0.10 | 0.03 ± 0.02
Bladder | 406 ± 194 | 0.75 ± 0.31 | 0.00 ± 0.00
Blood | 533 ± 6 | — | 0.18 ± 0.02
Brain | 62 ± 47 | 0.11 ± 0.07 | 0.00 ± 0.00
Heart | 255 ± 14 | 0.48 ± 0.03 | 0.01 ± 0.00
Kidney | 5,910 ± 715 | 11.1 ± 0.9 | 0.28 ± 0.03
Liver | 480 ± 47 | 0.90 ± 0.06 | 0.12 ± 0.01
Lung | 321 ± 40 | 0.60 ± 0.03 | 0.01 ± 0.00
Muscle | 53 ± 10 | 0.10 ± 0.02 | 0.17 ± 0.03
Skin | 326 ± 40 | 0.61 ± 0.02 | 0.00 ± 0.00
Spleen | 166 ± 8 | 0.31 ± 0.03 | 0.19 ± 0.01
Testis | 114 ± 46 | 0.21 ± 0.08 | 0.01 ± 0.00
130 mg/kg
Adipose | 94 ± 35 | 0.08 ± 0.04 | 0.01 ± 0.00
Bladder | 1,705 ± 810 | 1.49 ± 0.76 | 0.00 ± 0.00
Blood | 1,163 ± 116 | — | 0.01 ± 0.01
Brain | 78 ± 11 | 0.07 ± 0.01 | 0.00 ± 0.00
Heart | 468 ± 46 | 0.40 ± 0.03 | 0.00 ± 0.00
Kidney | 9,636 ± 2,334 | 8.34 ± 2.16 | 0.05 ± 0.01
Liver | 1,201 ± 225 | 1.04 ± 0.24 | 0.03 ± 0.01
Lung | 668 ± 104 | 0.58 ± 0.09 | 0.00 ± 0.00
Muscle | 125 ± 37 | 0.11 ± 0.04 | 0.05 ± 0.01
Skin | 324 ± 101 | 0.29 ± 0.12 | 0.04 ± 0.01
Spleen | 698 ± 164 | 0.60 ± 0.12 | 0.00 ± 0.00
Testis | 196 ± 127 | 0.18 ± 0.13 | 0.00 ± 0.00
151 mg/kg^e^
Adipose | 863 ± 614 | 0.12 ± 0.05 | 0.04 ± 0.03
Bladder | 6,441 ± 2,780 | 1.24 ± 1.11 | 0.00 ± 0.00
Blood | 6,802 ± 2,776 | — | 0.09 ± 0.06
Brain | 434 ± 154 | 0.07 ± 0.01 | 0.00 ± 0.00
Heart | 2,655 ± 1,560 | 0.38 ± 0.13 | 0.01 ± 0.00
Kidney | 20,098 ± 3,447 | 3.29 ± 1.08 | 0.09 ± 0.02
Liver | 3,849 ± 1,384 | 0.59 ± 0.08 | 0.08 ± 0.03
Lung | 3,807 ± 1,332 | 0.58 ± 0.06 | 0.02 ± 0.01
Muscle | 500 ± 228 | 0.08 ± 0.04 | 0.16 ± 0.07
Skin | 1,630 ± 1,282 | 0.23 ± 0.11 | 0.18 ± 0.14
Spleen | 3,877 ± 1,477 | 0.58 ± 0.06 | 0.01 ± 0.00
Testis | 674 ± 393 | 0.10 ± 0.03 | 0.00 ± 0.00

a Data are presented as mean ± standard deviation for five animals.

b Percent dose was calculated using the following values for the mass of total tissue, expressed as a percent of body weight: adipose, 7.0%; blood, 5.2%; muscle, 48%; and skin, 17%.

c n=4

d Unity

e Animals were preexposed to a single dermal dose of 151 mg/kg unlabeled trimethylolpropane triacrylate 24 hours before administration of the radiolabeled dose.

TABLE L4 Distribution of Radiolabel in Male B6C3F_1_ Mice 72 Hours after a Single Dermal Application of 1.2 mg/kg [^14^C]-Trimethylolpropane Triacrylate^a^

| Percentage of Dose
Absorbed Dose
Urine | 16.5 ± 2.8
Cage wash | 2.0 ± 0.9
Feces | 5.6 ± 4.2
Exhaled CO_2_ | 18.2 ± 5.4
Dose site skin^b^ | 30.8 ± 4.9
Selected tissues | 0.2 ± 0.1
Residual carcass | 1.7 ± 0.2
Total Absorbed Dose | 75.0 ± 2.4
Total Unabsorbed Dose^c^ | 20.9 ± 0.8
Total Dose Recovery | 95.9 ± 1.8

a Data are presented as mean ± standard deviation for five animals.

b Skin samples were not extracted with acetone.

c Total radioactivity in appliance and skin wash

TABLE L5 Cumulative Excretion of Radiolabel by Male B6C3F_1_ Mice after a Single Dermal Application of 1.2 mg/kg [^14^C]-Trimethylolpropane Triacrylate^a^

Time (hours after dosing) | Urine | Feces | Exhaled CO_2_ | Cage Rinse
8 | 0.8 ± 1.6 | —^b^ | 8.3 ± 2.3 | —
24 | 10.0 ± 2.5 | 2.9 ± 2.6 | 13.7 ± 4.0 | —
48 | 14.3 ± 2.9 | 4.3 ± 3.7 | 16.7 ± 4.9 | —
72 | 16.5 ± 2.8 | 5.6 ± 4.2 | 18.2 ± 5.4 | 2.0 ± 0.9
Total^c^ | 42.4 ± 7.3

a Data are presented as cumulative percentage of dose (mean ± standard deviation) for five animals.

b Samples not collected at this time point

c 72-Hour cumulative total of excreted radiolabel

TABLE L6 Tissue Distribution of Radiolabel in Male B6C3F_1_ Mice 72 Hours after a Single Dermal Application of 1.2 mg/kg [^14^C]-Trimethylolpropane Triacrylate^a^

Tissue | Trimethylolpropane Triacrylate Equivalents in Tissue (ng-Eq/g) | Tissue-to-Blood Ratio | Dose in Total Tissue (%)^b^
Adipose | 3 ± 3 | 0.14 ± 0.12 | 0.02 ± 0.02
Bladder | 35 ± 16 | 2.07 ± 1.55 | 0.00 ± 0.00
Blood | 20 ± 6 | —^c^ | 0.12 ± 0.02
Brain | 2 ± 1 | 0.09 ± 0.04 | 0.00 ± 0.00
Heart | 8 ± 1 | 0.44 ± 0.14 | 0.00 ± 0.00
Kidney | 36 ± 3 | 1.93 ± 0.55 | 0.05 ± 0.01
Liver | 20 ± 4 | 1.04 ± 0.27 | 0.07 ± 0.02
Lung | 18 ± 11 | 0.88 ± 0.50 | 0.01 ± 0.00
Muscle | 4 ± 1 | 0.20 ± 0.08 | 0.13 ± 0.04
Skin | 106 ± 23 | 5.52 ± 1.65 | 1.20 ± 0.31
Spleen | 11 ± 2 | 0.56 ± 0.09 | 0.00 ± 0.00
Testis | 4 ± 1 | 0.22 ± 0.04 | 0.00 ± 0.00

a Data are presented as mean ± standard deviation for five animals.

b Percent dose was calculated using the following values for the mass of total tissue, expressed as a percent of body weight: adipose, 9.6%; blood, 7.6%; muscle, 45.2%; and skin, 14.4%.

c Unity

FIGURE L2 Radioactivity Present in Tape Strips of the Dermal Dose Sites 30 Minutes or 72 Hours after a Single Dermal Application of 124 mg/kg [^14^C]-Trimethylolpropane Triacrylate to Male F344/N Rats

Values are mean ± standard deviation for four animals.

FIGURE L3 High-Performance Liquid Chromatographic Analysis of an Acetone Extract of the Stripped Dose Skin 72 Hours after a Single Dermal Application of 124 mg/kg [^14^C]-Trimethylolpropane Triacrylate to Male F344/N Rats

TABLE L7 Cumulative Excretion of Radiolabel by Male F344/N Rats after a Single Intravenous Injection of 9.4 mg/kg [^14^C]-Trimethylolpropane Triacrylate^a^

Time (hours after dosing) | Urine | Feces | Exhaled CO_2_ | Cage Rinse
3 | —^b^ | — | 6.4 ± 0.8 | —
6 | 24.1 ± 2.6 | 6.1 ± 5.5 | 12.9 ± 4.7 | —
24 | 44.6 ± 4.9 | 6.1 ± 5.5 | 18.6 ± 5.9 | —
48 | 47.3 ± 4.5 | 8.1 ± 7.0 | 19.8 ± 5.9 | —
72 | 48.3 ± 4.4 | 8.7 ± 7.1 | 20.1 ± 6.0 | 0.3 ± 0.1
Total^c^ | 77.4 ± 3.5

a Data are presented as cumulative percentage of the dose (mean ± standard deviation) for five animals.

b Samples not collected at this time point

c 72-Hour cumulative total of excreted radiolabel

TABLE L8 Concentration of Trimethylolpropane Triacrylate Equivalents in the Blood of Male F344/N Rats after a Single Intravenous Injection of 9.4 mg/kg [^14^C]-Trimethylolpropane Triacrylate^a^

Time (hours after dosing) | Rat 1 | Rat 2 | Rat 3 | Rat 4 | Rat 5 | Mean ± Standard Deviation
0.08 | 15.2 | 24.3 | 39.7 | 27.0 | 33.5 | 27.9 ± 9.3
0.5 | 20.2 | 21.7 | 25.2 | 18.6 | 21.2 | 21.4 ± 2.4
1 | 12.9 | 22.0 | 16.9 | 10.8 | 19.7 | 16.5 ± 4.6
3 | 23.0 | 21.9 | 16.5 | 15.9 | 17.1 | 18.9 ± 3.3
6 | 22.1 | 20.7 | 20.0 | 14.9 | 16.6 | 18.9 ± 3.0
24 | 20.4 | 18.7 | 19.5 | 14.3 | 16.4 | 17.9 ± 2.5
48 | 17.6 | 17.1 | 17.0 | 12.6 | 15.4 | 15.9 ± 2.0
72 | 14.8 | 15.0 | 14.8 | 11.3 | 13.4 | 13.9 ± 1.6

a Data are presented as μg equivalents per gram of blood.

TABLE L9 Tissue Distribution of Radiolabel in Male F344/N Rats 72 Hours after a Single Intravenous Injection of 9.4 mg/kg [^14^C]-Trimethylolpropane Triacrylate^a^

Tissue | Trimethylolpropane Triacrylate Equivalents in Tissue (ng-Eq/g) | Tissue-to-Blood Ratio | Dose in Total Tissue (%)^b^
Adipose | 156 ± 47 | 0.01 ± 0.00 | 0.12 ± 0.04
Bladder | 436 ± 80 | 0.03 ± 0.01 | 0.00 ± 0.00
Blood | 13,800 ± 1,560 | —^c^ | 5.01 ± 0.70
Brain | 935 ± 370 | 0.07 ± 0.03 | 0.07 ± 0.03
Heart | 3,880 ± 700 | 0.28 ± 0.05 | 0.12 ± 0.03
Kidney | 2,530 ± 368 | 0.19 ± 0.04 | 0.20 ± 0.02
Liver | 2,390 ± 189 | 0.17 ± 0.01 | 0.93 ± 0.17
Lung | 9,570 ± 2,050 | 0.70 ± 0.17 | 0.50 ± 0.18
Muscle | 173 ± 31 | 0.01 ± 0.00 | 0.81 ± 0.26
Skin | 276 ± 31 | 0.02 ± 0.00 | 0.49 ± 0.06
Spleen | 7,620 ± 1,150 | 0.55 ± 0.06 | 0.20 ± 0.04
Testis | 142 ± 26 | 0.01 ± 0.00 | 0.02 ± 0.00

a Data are presented as mean ± standard deviation for five animals.

b Percent dose was calculated using the following values for the mass of total tissue, expressed as a percent of body weight: adipose, 7.0%; blood, 5.2%; muscle, 48%; and skin, 17%.

c Unity

TABLE L10 Distribution of Radiolabel in Male F344/N Rats 72 Hours after a Single Intravenous Injection of 9.4 mg/kg [^14^C]-Trimethylolpropane Triacrylate^a^

Compartment | Cumulative % of Dose
Residual carcass | 3.63 ± 0.2
Tail | 1.07 ± 0.6
Selected tissues | 2.04 ± 0.3
Urine | 48.6 ± 4.5
Feces | 8.7 ± 7.1
Exhaled CO_2_ | 20.1 ± 6.0
72-hour blood | 5.01 ± 0.7
Blood samples for assay | 0.99 ± 0.2
Total | 90.1 ± 2.6

a Data are presented as mean ± standard deviation for five animals.

TABLE L11 Binding of Radiolabel to Kidney Protein 72 Hours after a Single Dermal Application or Intravenous Injection of [^14^C]-Trimethylolpropane Triacrylate in Male F344/N Rats

Route | Dose Level (mg/kg) | Kidney Radiolabel in Repetitive Extracts (%) | | | | | | | | Total Radiolabel in Supernatants (%) | Total Radiolabel Remaining in Pellet (Bound) (%) | Pellet Suspension Protein Concentration (μg/mL)
Route | Dose Level (mg/kg) | Trichloroacetic Acid^a^ | | | | Methanol:Water (80:20) | | | | Total Radiolabel in Supernatants (%) | Total Radiolabel Remaining in Pellet (Bound) (%) | Pellet Suspension Protein Concentration (μg/mL)
Route | Dose Level (mg/kg) | 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | Total Radiolabel in Supernatants (%) | Total Radiolabel Remaining in Pellet (Bound) (%) | Pellet Suspension Protein Concentration (μg/mL)
Dermal | 15.2 | 81.1 | 10.0 | 1.3 | 0.2 | 1.0 | 0.3 | —^b^ | — | 93.9 | 6.1 | 65.3
Dermal | 15.2 | 83.8 | 9.8 | 1.1 | 0.2 | 0.7 | 0.2 | — | — | 95.8 | 4.4 | 108
Intravenous | 9.4 | 26.2 | 3.8 | 1.2 | 0.7 | 4.4 | 1.9 | 1.2 | 0.9 | 40.3 | 59.7 | 78.7

a 0.6 M Trichloroacetic acid final concentration

b Not extracted further