# APPENDIX K CONTACT HYPERSENSITIVITY STUDIES

## Introduction

Studies were conducted with female BALB/c mice to evaluate the potential for trimethylolpropane triacrylate to induce contact hypersensitization. A primary irritancy study of trimethylolpropane triacrylate was performed to screen for toxicity and determine the maximal nonirritating and minimal irritating concentrations for a mouse ear swelling test and a local lymph node assay, two assessments of the dermal sensitizing potential of the compound. The studies were performed by the Medical College of Virginia Immunotoxicology Laboratory (Virginia Commonwealth University, Richmond, VA).

## Materials and Methods

Trimethylolpropane triacrylate (lot 01031AW) was obtained from Aldrich Chemical Company (Milwaukee, WI). Acetone was used as the vehicle. Analyses of the bulk chemicals are described in Appendix H. Dose formulations were prepared daily by mixing trimethylolpropane triacrylate in acetone.

Female BALB/c mice were obtained from the National Cancer Institute (Bethesda, MD). The mice were approximately 6 to 7 weeks of age at receipt and were quarantined for at least 6 days; serology tests indicated that the animals were free of viral (mouse hepatitis and Sendai) and bacterial (Mycoplasma) contamination. Mice received certified NIH-07 rodent feed and tap water in water bottles ad libitum. Mice were housed no more than five per cage in plastic shoe-box type cages with sawdust bedding; the cages were cleaned and sanitized twice per week.

For the irritancy study (Figure K1), groups of four mice received 50 µL dermal applications of 0% (vehicle controls), 0.025%, 0.05%, 0.075%, 0.1%, 0.25%, or 0.5% (w/v) trimethylolpropane triacrylate in acetone; 12.5 µL were applied to each side of each ear. Doses were administered by pipette once per day for 4 consecutive days. An additional group of four animals was maintained as untreated (naive) controls. Prior to application of the first dose and 24 ± 2 hours after the last dose, the thickness of each ear was measured at two sites with a modified micrometer (Mitutoyo America Corp., Aurora, IL). Ear swelling (mean thickness after dosing/mean thickness predosing) was calculated as a percentage for each ear.

For the mouse ear swelling test (Figure K2), groups of eight mice were sensitized with 50 µL dermal applications of 0% (two control groups), 0.01%, 0.05%, or 0.1% (w/v) trimethylolpropane triacrylate in acetone to the shaved dorsal lumbar area. Doses were administered by pipette once per day for 3 consecutive days. The animals were restrained after dosing to allow the vehicle to begin to volatilize. The mice were not dosed on days 4 through 7. On day 8, the thickness of the right ear of each animal was measured prior to dosing as described for the irritancy study. Challenge doses (25.0 µL total volume) were applied to the dorsal and ventral surfaces of the right ear pinna, divided between the two sides. The two control groups sensitized with acetone received challenges of acetone (vehicle controls) or 0.25% trimethylolpropane triacrylate (background controls). The three groups sensitized with trimethylolpropane triacrylate received a 0.25% trimethylolpropane triacrylate challenge dose. The right ears were remeasured 24 and 48 hours after the challenge doses were applied, and ear swelling was calculated as a percentage for each mouse at each time point.

For the local lymph node assay (Figure K3), groups of six mice were sensitized with 50 µL dermal applications of 0% (vehicle controls), 0.05%, 0.1%, or 0.25% (w/v) trimethylolpropane triacrylate in acetone. The doses (12.5 µL applied to each side of each ear) were applied by pipette once per day for 3 consecutive days. The mice were not dosed on day 4. On day 5, 0.2 mL (20 µCi) of [^3^H]-thymidine was intravenously injected (tail vein). The animals were killed 5 hours after the injection, and the left and right draining (superficial cervical) lymph nodes were excised and placed in cold phosphate-buffered saline. All lymph nodes were dissociated by grinding between the frosted ends of two microscope slides. The cells were washed twice in phosphate-buffered saline and then resuspended in 3 mL 5% trichloroacetic acid in distilled water. After 18 to 60 hours at approximately 4° C, the cells were resuspended in trichloroacetic acid, transferred into 5 mL scintillation cocktail, and counted on a beta counter for 5 minutes.

The data were analyzed for homogeneity with Bartlett’s chi-square test (Bartlett, 1937). Homogeneous data were tested for significance with a one-way analysis of variance (Kruskal and Wallis, 1952) followed by Dunnett’s multiple-range t-test (Dunnett, 1955) if the analysis of variance indicated a significant main effect. For nonhomogeneous data, a nonparametric analysis of variance, Wilson’s test (Wilson, 1956), and the Wilcoxon rank sum test (Gross and Clark, 1975) were used to compare treatment groups with the controls.

## Results and Discussion

There were no deaths, body weight changes, or clinical findings related to trimethylolpropane triacrylate treatment in dosed mice. Results of the irritancy study indicated that the maximal nonirritating and minimal irritating doses were 0.1% and 0.25% trimethylolpropane triacrylate, respectively (Figure K4).

In the mouse ear swelling test, no significant differences in the percentage of ear swelling were observed between trimethylolpropane triacrylate-sensitized and -challenged mice and the background controls at 24 or 48 hours after dosing (Figure K5). The local lymph node assay indicated no significant increase in lymph node cell proliferation in mice administered trimethylolpropane triacrylate compared to that in the vehicle controls (Figures K4 to K6).

Testing for sensitizing potential using the mouse ear swelling test and local lymph node assay failed to indicate trimethylolpropane triacrylate as a potential contact sensitizer at the concentrations tested.

## References

Bartlett, M.S. (1937). Sub-sampling for attributes. J. Royal Stat. Soc. (Suppl. 4), 131–135.
Dunnett, C.W. (1955). A multiple comparison procedure for comparing several treatments with a control. J. Am. Stat. Assoc. 50, 1096–1121.
Gross, A.J., and Clark, V.A., Eds. (1975). Gehan-Wilcoxon Test. In Survival Distribution: Reliability Applications in the Biomedical Sciences, pp. 120–123. John Wiley and Sons, New York.
Kruskal, W.H., and Wallis, W.A. (1952). Use of ranks in one-criterion variance analysis. J. Am. Stat. Assoc. 47, 583–621.
Wilson, K.V. (1956). A distribution free test of analysis of variance hypothesis. Psychol. Bull. 53, 96–101.13289969

FIGURE K1 Major Events of the Primary Irritancy Study

FIGURE K2 Major Events of the Mouse Ear Swelling Test

FIGURE K3 Major Events of the Local Lymph Node Assay

FIGURE K4 Primary Irritancy Response to Trimethylopropane Triacrylate Mixture in Female BALB/c Mice

* Statistically significant (P<0.05) compared to vehicle control

** P<0.01

Means for each group are shown, with bars representing the standard error.

VH=vehicle controls, NA=untreated (naive) controls, TMT=trimethylolpropane triacrylate mixture

FIGURE K5 Contact Hypersensitivity Response to Trimethylolpropane Triacrylate Mixture in Female BALB/c Mice (Mouse Ear Swelling Test)

Means for each group are shown, with bars representing the standard error.

VH=vehicle controls, BC=background controls, TMT=trimethylolpropane triacrylate mixture

FIGURE K6 Contact Hypersensitivity Response to Trimethylolpropane Triacrylate Mixture in Female BABL/c Mice (Local Lymph Node Assay)

Means for each group are shown, with bars representing the standard error.

DPM=disintegrations per minute, VH=vehicle controls, TMT=trimethylolpropane triacrylate mixture