# APPENDIX H CHEMICAL CHARACTERIZATION AND DOSE FORMULATION STUDIES

## Procurement and Characterization

### Trimethylolpropane Triacrylate

Trimethylolpropane triacrylate was obtained from Aldrich Chemical Company (Milwaukee, WI) in one lot (01031AW), which was used throughout the studies. Identity, moisture content, purity, and stability analyses were conducted by the analytical chemistry laboratories and the study laboratory (Battelle Columbus Laboratories, Columbus, OH). Reports on analyses performed in support of the trimethylolpropane triacrylate studies are on file at the National Institute of Environmental Health Sciences.

The chemical, a colorless to yellow viscous liquid, was identified as trimethylolpropane triacrylate by the analytical chemistry laboratory using infrared spectrometry and proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy and by the study laboratory using infrared spectrometry. All spectra were consistent with the structure of trimethylolpropane triacrylate; the infrared spectrum was also consistent with a literature spectrum (Aldrich, 1985). The infrared and NMR spectra are presented in Figures H1 through H3.

The analytical chemistry laboratories and the study laboratory determined moisture content using Karl Fischer titration and purity using elemental analyses, gas chromatography (GC), high-performance liquid chromatography (HPLC), and HPLC with mass spectrometry (HPLC/MS). GC was performed using systems A and B (Table H1). HPLC was performed with an Ultracarb 5 ODS (30) column (150 mm × 4.6 mm, 5-µm particle size; Phenomenex, Torrance, CA) and ultraviolet detection at 221 nm. A mobile phase of (A) methanol:Milli-Q water (50:50) and (B) methanol:Milli-Q water (90:10) was used; the solvent program was a linear gradient of 100% A to 100% B over 30 minutes with a 30-minute hold, then 100% B to 100% A in 1 minute with a 10-minute hold. The flow rate was 0.8 mL/minute.

Karl Fischer titration indicated approximately 747 ppm water. Elemental analyses for carbon, hydrogen, and oxygen were in agreement with the theoretical values for trimethylolpropane triacrylate. GC indicated one major peak and two impurities with areas of 6.5% and 3.4% relative to the major peak area. HPLC indicated a major peak and five impurities with a combined area of 22.2%. HPLC/MS indicated 10 impurities contributing or corresponding to the impurity peaks identified by HPLC. These impurities included four structurally related acrylates or adducts: trimethylolpropane diacrylate, trimethylolpropane triacrylate acrylic acid adduct, trimethylolpropane triacrylate-trimethylolpropane monoacrylate adduct, and trimethylolpropane triacrylatetrimethylolpropane diacrylate adduct. No substantial amount of 4-methoxyphenol, a stabilizer added to trimethylolpropane triacrylate, was detected. The overall purity of lot 01031AW was estimated to be approximately 80%.

To ensure stability, the bulk chemical was stored at room temperature, protected from light, in amber glass bottles with Teflon^®^-lined lids. Stability was monitored throughout the studies with GC by systems similar to system A (2-week and 3-month studies) or B (6-month study). No degradation of the bulk chemical was detected.

### 12-O-Tetradecanoylphorbol-13-acetate

12-O-Tetradecanoylphorbol-13-acetate was obtained from Sigma Chemical Company (St. Louis, MO) in one lot (48H1178) for use in the 6-month study. Identity and purity analyses were conducted by the analytical chemistry laboratory, Research Triangle Institute (Research Triangle Park, NC). The bulk chemical was stored in its original containers, protected from light, at −20° C or less.

The chemical was identified as 12-O-tetradecanoylphorbol-13-acetate by infrared and proton NMR spectroscopy. All spectra were consistent with the structure of 12-O-tetradecanoylphorbol-13-acetate.

The purity was determined with HPLC using a Zorbax Rx C_8_ column (250 mm × 4.6 mm, 5-µm particle size; DuPont, Wilmington, DE) and ultraviolet detection at 232 nm. A mobile phase of water:acetonitrile (10:90) (isocratic) was used; the flow rate was 1.0 mL/minute. HPLC indicated a major peak, one impurity peak with an area of approximately 0.11% of the total peak area, and two minor impurities with areas less than 0.1% of the total peak area. The overall purity was determined to be greater than 99%.

### Acetone

Acetone was obtained in two lots from Honeywell Burdick and Jackson (Muskegon, MI) (lots BK792 and BL631) and in five lots from Spectrum Chemical Manufacturing Corporation (Gardena, CA) (lots JE342, KP206, LS0051, MI0172, and NE0173). Lots BK792, BL631, and JE342 were used in the 2-week studies, lots KP206 and LS0051 were used in the 3-month studies, and lots MI0172 and NE0173 were used in the 6-month study. Identity and purity analyses of lots BL631 and JE342 and all lots used in the 3- and 6-month studies were conducted by the analytical chemistry laboratory (Midwest Research Institute, Kansas City, MO) and the study laboratory.

The chemical, a clear liquid, was identified as acetone by the analytical chemistry laboratory (lots BL631, JE342, KP206, and LS0051) or the study laboratory (lots MI0172 and NE0173) using infrared spectroscopy. All spectra were consistent with a literature spectrum (Aldrich, 1985) or with the structure of acetone.

The purity was analyzed by the analytical chemistry laboratory (lots BL631, JE342, KP206, and LS0051) or the study laboratory (lots MI0172 and NE0173) using GC by systems similar to system C (lots JE342, MI0172, and NE0173) and by system D (lots BL631, KP206, and LS0051). No significant impurities were detected in any lot. The overall purity of each lot was determined to be greater than 99%.

To ensure stability, the bulk chemical was stored in amber glass bottles at room temperature. Stability was monitored with GC by system C. No degradation of the acetone was detected.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared twice (2-week studies) or every 4 weeks by mixing trimethylolpropane triacrylate and acetone to give the required concentration (Table H2). The dose formulations were stored for up to 35 days at room temperature in amber glass bottles with Teflon^®^-lined lids except dose formulations prepared on September 3 and 6, 1996 (3-month studies), which were stored in amber (rat) or clear (mouse) glass vials with Teflon^®^ septa at −20° C or less. Positive control formulations for the 6-month study were prepared twice by mixing 12-O-tetradecanoylphorbol-13-acetate with acetone to provide a concentration of 12.5 µg/mL.

Stability studies of the 6.25 and 100 mg/mL dose formulations for the 2-week studies as well as 50 and 400 µg/mL dose formulations were performed by the study laboratory with GC by systems similar to system B. Stability was confirmed for at least 35 days for dose formulations stored in amber glass bottles with Teflon^®^-lined lids or septa, with minimal headspace, at temperatures up to 25° C and for 3 hours under animal room conditions, periodically or continually exposed to air and light.

Periodic analyses of the dose formulations of trimethylolpropane triacrylate were conducted by the study laboratory using GC by systems similar to system B. During the 2-week studies, the dose formulations were analyzed once; all five dose formulations for rats and three of five for mice were within 10% of the target concentrations (Table H3). Animal room samples of these dose formulations were also analyzed; four of five animal room samples for rats and all samples for mice were within 10% of the target concentrations. The dose formulations were analyzed at the beginning, midpoint, and end of the 3-month studies; animal room samples of these dose formulations were also analyzed (Table H4). Of the dose formulations analyzed, 14 of 15 for rats and 15 of 15 for mice were within 10% of the target concentrations, with no value greater than 103% of the target concentration; 12 of 15 of the animal room samples for rats and 14 of 15 for mice were within 10% of the target concentrations. During the 6-month study, the dose formulations were analyzed approximately every 8 or 12 weeks (Table H5). Of the dose formulations analyzed, 14 of 15 were within 10% of the target concentrations; all five animal room samples were within 10% of the target concentrations. In all studies, dose formulations that were not within 10% of the target concentrations were remixed and reanalyzed; all dose formulations analyzed that were administered to rats and mice were within specifications. The positive control formulations were analyzed by the analytical chemistry laboratory using HPLC with a system similar to that described for the positive control purity analysis and were found to be within 10% of the target concentration (data not shown).

FIGURE H1 Infrared Absorption Spectrum of Trimethylolpropane Triacrylate

FIGURE H2 Proton Nuclear Magnetic Resonance Spectrum of Trimethylolpropane Triacrylate

FIGURE H3 ^13^C Nuclear Magnetic Resonance Spectrum of Trimethylolpropane Triacrylate

TABLE H1 Gas Chromatography Systems Used in the Dermal Studies of Trimethylolpropane Triacrylate

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization | DB-5, 30 m × 0.32 mm, 0.25-μm film thickness (J&W Scientific, Folsom, CA) | Helium at 5 mL/minute | 70° C for 2.5 minutes, then 9° C/minute to 210° C, held 10 minutes
System B
Flame ionization | RTX-5, 30 m × 0.25 mm, 0.25-μm film thickness (Restek, Bellefonte, PA) | Helium at approximately 3 mL/minute | 70° C for 2.5 minutes, then 9° C/minute to 210° C, held 10 minutes
System C
Flame ionization | 20% SP-2401/0.1% Carbowax on 100/120 Supelcoport, 2.4 m × 2 mm | Nitrogen or helium at approximately 30 mL/minute | 40° C for 4 minutes, then 10° C/minute to 170° C
System D
Flame ionization | DB-WAX, 30 m × 0.53 mm, 1-μm film thickness (J&W Scientific) | Helium at 10 mL/minute | 80° C for 5 minutes, then 10° C/minute to 220° C, held 4 minutes

TABLE H2 Preparation and Storage of Dose Formulations in the Dermal Studies of Trimethylolpropane Triacrylate

2-Week Studies | 3-Month Studies | 6-Month Study
Preparation
Trimethylolpropane triacrylate was manually shaken or sonicated with acetone. Dose formulations were prepared twice. | Same as 2-week studies. Dose formulations were prepared every 4 weeks. | Same as 3-month studies
Trimethylolpropane Triacrylate Lot Number
01031AW | 01031AW | 01031AW
Maximum Storage Time
35 days | 35 days | 35 days
Storage Conditions
Stored in amber glass bottles with Teflon^®^-lined lids at room temperature | Formulations prepared on September 3 and 6, 1996, were stored in amber or clear glass vials with Teflon^®^ septa at −20° C or less; other formulations were stored same as 2-week studies. | Same as 2-week studies
Study Laboratory
Battelle Columbus Laboratories (Columbus, OH) | Battelle Columbus Laboratories (Columbus, OH) | Battelle Columbus Laboratories (Columbus, OH)

TABLE H3 Results of Analyses of Dose Formulations Administered to Rats and B6C3F_1_ Mice in the 2-Week Dermal Studies of Trimethylolpropane Triacrylate

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
Rats
May 1, 1996 | May 2, 1996 | 25 | 24.28 | −3
May 1, 1996 | May 2, 1996 | 50 | 49.41 | −1
May 1, 1996 | May 2, 1996 | 100 | 97.87 | −2
May 1, 1996 | May 2, 1996 | 200 | 188.7 | −6
May 1, 1996 | May 2, 1996 | 400 | 392.8 | −2
May 1, 1996 | May 22–24, 1996^b^ | 25 | 26.11 | +4
May 1, 1996 | May 22–24, 1996^b^ | 50 | 52.80 | +6
May 1, 1996 | May 22–24, 1996^b^ | 100 | 106.0^c^ | +6
May 1, 1996 | May 22–24, 1996^b^ | 200 | 192.1 | −4
May 1, 1996 | May 22–24, 1996^b^ | 400 | 457.8 | +14
Mice
May 1, 1996 | May 2, 1996 | 6.25 | —^d,e^ | —
May 1, 1996 | May 2, 1996 | 12.5 | 21.72^e^ | +74
May 1, 1996 | May 2, 1996 | 25 | 24.28 | −3
May 1, 1996 | May 2, 1996 | 50 | 49.41 | −1
May 1, 1996 | May 2, 1996 | 100 | 97.87 | −2
May 3, 1996 | May 4, 1996 | 6.25 | 7.198^e,f^ | +15
May 3, 1996 | May 4, 1996 | 12.5 | 7.954^e,f^ | −36
May 6, 1996 | May 7, 1996 | 6.25 | 5.748^f^ | −8
May 6, 1996 | May 7, 1996 | 12.5 | 11.95^f^ | −4
May 6, 1996 | May 22–24, 1996^b^ | 6.25 | 6.225 | 0
May 6, 1996 | May 22–24, 1996^b^ | 12.5 | 12.96 | +4
May 6, 1996 | May 22–24, 1996^b^ | 25 | 25.66 | +3
May 6, 1996 | May 22–24, 1996^b^ | 50 | 52.04 | +4
May 6, 1996 | May 22–24, 1996^b^ | 100 | 104.9 | +5

a Results of duplicate analyses. For rats, dosing volume=0.5 mL/kg; 25 mg/mL=12.5 mg/kg; 50 mg/mL=25 mg/kg; 100 mg/mL=50 mg/kg; 200 mg/mL=100 mg/kg; 400 mg/mL=200 mg/kg. For mice, dosing volume=2.0 mL/kg; 6.25 mg/mL=12.5 mg/kg; 12.5 mg/mL=25 mg/kg; 25 mg/mL=50 mg/kg; 50 mg/mL=100 mg/kg; 100 mg/mL=200 mg/kg

b Animal room samples

c Results of quadruplicate analyses

d Not quantifiable

e Remixed; not used in study

f Results of remix

TABLE H4 Results of Analyses of Dose Formulations Administered to Rats and B6C3F_1_ Mice in the 3-Month Dermal Studies of Trimethylolpropane Triacrylate

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
Rats
September 3, 1996 | September 5, 1996 | 1.5 | 1.514 | +1
September 3, 1996 | September 5, 1996 | 3 | 3.038 | +1
September 3, 1996 | September 5, 1996 | 6 | 6.033 | +1
September 3, 1996 | September 5, 1996 | 12 | 8.653^b^ | −28
September 3, 1996 | September 5, 1996 | 24 | 24.66 | +3
September 6, 1996 | September 6, 1996 | 12 | 11.94^c^ | 0
September 6, 1996 | October 4, 1996^d^ | 1.5 | 1.556 | +4
September 6, 1996 | October 4, 1996^d^ | 3 | 3.076 | +3
September 6, 1996 | October 4, 1996^d^ | 6 | 6.207 | +3
September 6, 1996 | October 4, 1996^d^ | 12 | 12.27 | +2
September 6, 1996 | October 4, 1996^d^ | 24 | 24.72 | +3
October 28, 1996 | October 29, 1996 | 1.5 | 1.503 | 0
October 28, 1996 | October 29, 1996 | 3 | 3.011 | 0
October 28, 1996 | October 29, 1996 | 6 | 5.944 | −1
October 28, 1996 | October 29, 1996 | 12 | 11.84 | −1
October 28, 1996 | October 29, 1996 | 24 | 23.51 | −2
October 28, 1996 | December 2–3, 1996^d^ | 1.5 | 1.529 | +2
October 28, 1996 | December 2–3, 1996^d^ | 3 | 3.205 | +7
October 28, 1996 | December 2–3, 1996^d^ | 6 | 6.854 | +14
October 28, 1996 | December 2–3, 1996^d^ | 12 | 13.65 | +14
October 28, 1996 | December 2–3, 1996^d^ | 24 | 26.59 | +11
November 25, 1996 | November 25, 1996 | 1.5 | 1.514 | +1
November 25, 1996 | November 25, 1996 | 3 | 3.005 | 0
November 25, 1996 | November 25, 1996 | 6 | 6.024 | 0
November 25, 1996 | November 25, 1996 | 12 | 12.00 | 0
November 25, 1996 | November 25, 1996 | 24 | 23.81 | −1
November 25, 1996 | December 31, 1996^d^ | 1.5 | 1.493 | 0
November 25, 1996 | December 31, 1996^d^ | 3 | 3.019 | +1
November 25, 1996 | December 31, 1996^d^ | 6 | 6.283 | +5
November 25, 1996 | December 31, 1996^d^ | 12 | 11.86 | −1
November 25, 1996 | December 31, 1996^d^ | 24 | 23.88 | 0
Mice
September 3, 1996 | September 5, 1996 | 0.375 | 0.3848 | +3
September 3, 1996 | September 5, 1996 | 0.75 | 0.7620 | +2
September 3, 1996 | September 5, 1996 | 1.5 | 1.514 | +1
September 3, 1996 | September 5, 1996 | 3 | 3.038 | +1
September 3, 1996 | September 5, 1996 | 6 | 6.033 | +1
September 3, 1996 | October 4, 1996^d^ | 0.375 | 0.3892 | +4
September 3, 1996 | October 4, 1996^d^ | 0.75 | 0.7772 | +4
September 3, 1996 | October 4, 1996^d^ | 1.5 | 1.567 | +4
September 3, 1996 | October 4, 1996^d^ | 3 | 3.082 | +3
September 3, 1996 | October 4, 1996^d^ | 6 | 6.280 | +5
October 28, 1996 | October 29, 1996 | 0.375 | 0.3629 | −3
October 28, 1996 | October 29, 1996 | 0.75 | 0.7475 | 0
October 28, 1996 | October 29, 1996 | 1.5 | 1.503 | 0
October 28, 1996 | October 29, 1996 | 3 | 3.011 | 0
October 28, 1996 | October 29, 1996 | 6 | 5.944 | −1
October 28, 1996 | December 2–3, 1996^d^ | 0.375 | 0.3880 | +3
October 28, 1996 | December 2–3, 1996^d^ | 0.75 | 0.7769 | +4
October 28, 1996 | December 2–3, 1996^d^ | 1.5 | 1.548 | +3
October 28, 1996 | December 2–3, 1996^d^ | 3 | 3.168 | +6
October 28, 1996 | December 2–3, 1996^d^ | 6 | 6.762 | +13
November 25, 1996 | November 25, 1996 | 0.375 | 0.3780 | +1
November 25, 1996 | November 25, 1996 | 0.75 | 0.7362 | −2
November 25, 1996 | November 25, 1996 | 1.5 | 1.514 | +1
November 25, 1996 | November 25, 1996 | 3 | 3.005 | 0
November 25, 1996 | November 25, 1996 | 6 | 6.024 | 0
November 25, 1996 | December 31, 1996^d^ | 0.375 | 0.3673 | −2
November 25, 1996 | December 31, 1996^d^ | 0.75 | 0.7500 | 0
November 25, 1996 | December 31, 1996^d^ | 1.5 | 1.539 | +3
November 25, 1996 | December 31, 1996^d^ | 3 | 3.051 | +2
November 25, 1996 | December 31, 1996^d^ | 6 | 6.264 | +4

a Results of duplicate analyses. For rats, dosing volume=0.5 mL/kg; 1.5 mg/mL=0.75 mg/kg; 3 mg/mL=1.5 mg/kg; 6 mg/mL=3 mg/kg; 12 mg/mL=6 mg/kg; 24 mg/mL=12 mg/kg. For mice, dosing volume=2.0 mL/kg; 0.375 mg/mL=0.75 mg/kg; 0.75 mg/mL=1.5 mg/kg; 1.5 mg/mL=3 mg/kg; 3 mg/mL=6 mg/kg; 6 mg/mL=12 mg/kg

b Remixed; not used in study

c Results of remix

d Animal room samples

TABLE H5 Results of Analyses of Dose Formulations Administered to Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
July 14, 1998 | July 15, 1998 | 0.227 | 0.2542^b^ | +12
July 14, 1998 | July 15, 1998 | 0.455 | 0.4797 | +5
July 14, 1998 | July 15, 1998 | 0.909 | 0.9867 | +9
July 14, 1998 | July 15, 1998 | 1.82 | 1.930 | +6
July 14, 1998 | July 15, 1998 | 3.64 | 3.676 | +1
July 16, 1998 | July 16, 1998 | 0.227 | 0.2188^c^ | −4
July 16, 1998 | August 20–21, 1998^d^ | 0.227 | 0.2252 | −1
July 16, 1998 | August 20–21, 1998^d^ | 0.455 | 0.4675 | +3
July 16, 1998 | August 20–21, 1998^d^ | 0.909 | 0.9396 | +3
July 16, 1998 | August 20–21, 1998^d^ | 1.82 | 1.881 | +3
July 16, 1998 | August 20–21, 1998^d^ | 3.64 | 3.666 | +1
September 9, 1998 | September 10–11, 1998 | 0.227 | 0.2088 | −8
September 9, 1998 | September 10–11, 1998 | 0.455 | 0.4224 | −7
September 9, 1998 | September 10–11, 1998 | 0.909 | 0.8422 | −7
September 9, 1998 | September 10–11, 1998 | 1.82 | 1.754 | −4
September 9, 1998 | September 10–11, 1998 | 3.64 | 3.589 | −1
December 1, 1998 | December 2–3, 1998 | 0.227 | 0.2304 | +1
December 1, 1998 | December 2–3, 1998 | 0.455 | 0.4603 | +1
December 1, 1998 | December 2–3, 1998 | 0.909 | 0.9200 | +1
December 1, 1998 | December 2–3, 1998 | 1.82 | 1.887 | +4
December 1, 1998 | December 2–3, 1998 | 3.64 | 3.741 | +3

a Results of duplicate analyses. Dosing volume=3.3 mL/kg; 0.227 mg/mL=0.75 mg/kg; 0.455 mg/mL=1.5 mg/kg; 0.909 mg/mL=3 mg/kg; 1.82 mg/mL=6 mg/kg; 3.64 mg/mL=12 mg/kg

b Remixed; not used in study

c Results of remix

d Animal room samples (0.227 mg/mL formulation from July 16, 1998, mix; all others from July 14, 1998, mix).