# APPENDIX G REPRODUCTIVE TISSUE EVALUATIONS AND ESTROUS CYCLE CHARACTERIZATION

TABLE G1 Summary of Reproductive Tissue Evaluations for Male Rats in the 3-Month Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 3 mg/kg | 6 mg/kg | 12 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 280 ± 6 | 279 ± 6 | 272 ± 6 | 259 ± 7
L. Cauda epididymis | 0.151 ± 0.005 | 0.135 ± 0.003 | 0.142 ± 0.005 | 0.150 ± 0.007
L. Epididymis | 0.441 ± 0.010 | 0.429 ± 0.007 | 0.433 ± 0.011 | 0.436 ± 0.013
L. Testis | 1.45 ± 0.02 | 1.46 ± 0.02 | 1.45 ± 0.03 | 1.36 ± 0.03^*^
Spermatid measurements
Spermatid heads (10^7^/g testis) | 153 ± 5 | 147 ± 4 | 144 ± 4 | 161 ± 7
Spermatid heads (10^7^/testis) | 191 ± 7 | 186 ± 6 | 181 ± 7 | 189 ± 7
Spermatid heads (10^7^/g cauda) | 553 ± 25 | 588 ± 39 | 569 ± 31 | 549 ± 30
Spermatid heads (10^7^/cauda) | 83.1 ± 3.0 | 78.9 ± 5.1 | 80.5 ± 5.1 | 81.4 ± 3.7
Epididymal spermatozoal measurements
Motility (%) | 73.8 ± 1.4 | 75.1 ± 0.9 | 75.0 ± 1.2 | 74.7 ± 0.7

* Significantly different (P≤0.05) from the vehicle control group by Dunnett’s test.

a Data are given as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weight) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

TABLE G2 Estrous Cycle Characterization for Female Rats in the 3-Month Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 3 mg/kg | 6 mg/kg | 12 mg/kg
n | 10 | 10 | 10 | 10
Necropsy body wt (g) | 177 ± 3 | 179 ± 4 | 167 ± 2 | 171 ± 3
Estrous cycle length (days) | 4.89 ± 0.07^b^ | 5.06 ± 0.15^c^ | 5.20 ± 0.20 | 5.20 ± 0.20
Estrous stages (% of cycle)
Diestrus | 42.5 | 45.0 | 45.0 | 50.0
Proestrus | 13.3 | 15.8 | 17.5 | 16.7
Estrus | 19.2 | 17.5 | 20.8 | 19.2
Metestrus | 17.5 | 15.0 | 16.7 | 14.2
Uncertain diagnoses | 7.5 | 6.7 | 0.0 | 0.0

a Necropsy body weight and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weight and estrous cycle length). By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages.

b Estrous cycle was longer than 12 days or unclear in 1 of 10 animals.

c Estrous cycle was longer than 12 days or unclear in 2 of 10 animals.

TABLE G3 Summary of Reproductive Tissue Evaluations for Male B6C3F_1_ Mice in the 3-Month Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 3 mg/kg | 6 mg/kg | 12 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 36.7 ± 0.7 | 36.1 ± 0.9 | 34.9 ± 0.7 | 35.0 ± 0.7
L. Cauda epididymis | 0.015 ± 0.001 | 0.014 ± 0.001 | 0.014 ± 0.001 | 0.014 ± 0.001
L. Epididymis | 0.040 ± 0.001 | 0.040 ± 0.001 | 0.040 ± 0.001 | 0.041 ± 0.001
L. Testis | 0.11 ± 0.00 | 0.12 ± 0.00 | 0.11 ± 0.00 | 0.11 ± 0.00
Spermatid measurements
Spermatid heads (10^7^/g testis) | 231 ± 11 | 220 ± 8 | 248 ± 17 | 243 ± 11
Spermatid heads (10^7^/testis) | 21 ± 2 | 21 ± 1 | 23 ± 2 | 24 ± 1
Spermatid heads (10^7^/g cauda) | 986 ± 129 | 1,049 ± 57 | 1,135 ± 116 | 989 ± 53
Spermatid heads (10^7^/cauda) | 14.6 ± 2.1 | 14.1 ± 0.5 | 15.4 ± 1.2 | 14.3 ± 0.9
Epididymal spermatozoal measurements
Motility (%) | 73.7 ± 1.0 | 74.6 ± 1.4 | 75.1 ± 1.5 | 74.4 ± 1.0

a Data are given as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body and tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

TABLE G4 Estrous Cycle Characterization for Female B6C3F_1_ Mice in the 3-Month Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 3 mg/kg | 6 mg/kg | 12 mg/kg
n | 10 | 10 | 10 | 10
Necropsy body wt (g) | 31.1 ± 1.4 | 32.9 ± 1.2 | 30.6 ± 0.5 | 31.1 ± 1.2
Estrous cycle length (days) | 4.11 ± 0.18^b^ | 4.06 ± 0.06^b^ | 3.99 ± 0.15 | 4.47 ± 0.30
Estrous stages (% of cycle)
Diestrus | 36.7 | 32.5 | 48.3 | 40.0
Proestrus | 17.5 | 15.0 | 5.8 | 6.7
Estrus | 23.3 | 30.8 | 26.7 | 32.5
Metestrus | 20.0 | 21.7 | 12.5 | 19.2
Uncertain diagnoses | 2.5 | 0.0 | 6.7 | 1.7

a Necropsy body weight and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weight and estrous cycle length).

b Estrous cycle was longer than 12 days or unclear in 1 of 10 animals.

c Evidence shows that females dosed with 6 or 12 mg/kg differ significantly (Wilk’s Criterion, P≤0.05) from the vehicle control females in the relative length of time spent in the estrous stages.