# APPENDIX F ORGAN WEIGHTS AND ORGAN-WEIGHT-TO-BODY-WEIGHT RATIOS

TABLE F1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the 2-Week Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 12.5 mg/kg | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Necropsy body wt | 170 ± 6 | 162 ± 6 | 167 ± 4 | 163 ± 8 | 163 ± 3 | 155 ± 4
Heart
Absolute | 0.665 ± 0.017 | 0.619 ± 0.023 | 0.651 ± 0.016 | 0.640 ± 0.022 | 0.656 ± 0.023 | 0.707 ± 0.042
Relative | 3.928 ± 0.054 | 3.814 ± 0.063 | 3.902 ± 0.059 | 3.939 ± 0.100 | 4.024 ± 0.101 | 4.548 ± 0.169^**^
R. Kidney
Absolute | 0.688 ± 0.023 | 0.642 ± 0.033 | 0.697 ± 0.027 | 0.692 ± 0.046 | 0.713 ± 0.035 | 0.706 ± 0.021
Relative | 4.055 ± 0.046 | 3.945 ± 0.058 | 4.176 ± 0.078 | 4.235 ± 0.117 | 4.370 ± 0.131^*^ | 4.555 ± 0.047^**^
Liver
Absolute | 8.298 ± 0.442 | 7.700 ± 0.567 | 8.168 ± 0.257 | 8.065 ± 0.498 | 8.256 ± 0.164 | 7.806 ± 0.292
Relative | 48.8 ± 1.1 | 47.2 ± 1.8 | 48.9 ± 0.6 | 49.4 ± 1.1 | 50.7 ± 0.8 | 50.3 ± 0.8
Lung
Absolute | 1.208 ± 0.059 | 1.133 ± 0.063 | 1.163 ± 0.089 | 1.225 ± 0.178 | 1.281 ± 0.105 | 1.163 ± 0.043
Relative | 7.119 ± 0.233 | 6.981 ± 0.327 | 6.964 ± 0.458 | 7.537 ± 1.066 | 7.880 ± 0.685 | 7.501 ± 0.155
R. Testis
Absolute | 1.059 ± 0.026 | 1.062 ± 0.036 | 1.069 ± 0.026 | 1.035 ± 0.039 | 1.068 ± 0.025 | 1.095 ± 0.030
Relative | 6.251 ± 0.059 | 6.551 ± 0.147 | 6.408 ± 0.069 | 6.362 ± 0.071 | 6.559 ± 0.064^*^ | 7.066 ± 0.076^**^
Thymus
Absolute | 0.440 ± 0.014 | 0.373 ± 0.021^*^ | 0.403 ± 0.027 | 0.384 ± 0.005 | 0.404 ± 0.017 | 0.360 ± 0.008^*^
Relative | 2.600 ± 0.088 | 2.302 ± 0.123 | 2.408 ± 0.117 | 2.374 ± 0.104 | 2.482 ± 0.096 | 2.327 ± 0.063
Female
Necropsy body wt | 124 ± 3 | 124 ± 3 | 122 ± 1 | 122 ± 2 | 128 ± 5 | 118 ± 2
Heart
Absolute | 0.548 ± 0.036 | 0.552 ± 0.006 | 0.508 ± 0.006 | 0.526 ± 0.016 | 0.566 ± 0.036 | 0.517 ± 0.012
Relative | 4.451 ± 0.352 | 4.453 ± 0.083 | 4.183 ± 0.036 | 4.321 ± 0.113 | 4.398 ± 0.133 | 4.388 ± 0.125
R. Kidney
Absolute | 0.536 ± 0.013 | 0.552 ± 0.023 | 0.546 ± 0.012 | 0.567 ± 0.022 | 0.609 ± 0.028 | 0.570 ± 0.020
Relative | 4.329 ± 0.039 | 4.437 ± 0.096 | 4.495 ± 0.079 | 4.656 ± 0.126^*^ | 4.738 ± 0.098^**^ | 4.828 ± 0.104^**^
Liver
Absolute | 5.972 ± 0.137 | 5.908 ± 0.153 | 5.907 ± 0.154 | 5.994 ± 0.101 | 6.491 ± 0.532 | 5.802 ± 0.211
Relative | 48.4 ± 1.6 | 47.6 ± 0.6 | 48.6 ± 0.9 | 49.3 ± 0.8 | 50.3 ± 2.3 | 49.2 ± 1.1
Lung
Absolute | 1.005 ± 0.050 | 1.018 ± 0.060 | 0.952 ± 0.055 | 0.973 ± 0.043 | 1.018 ± 0.049 | 0.860 ± 0.026
Relative | 8.105 ± 0.285 | 8.192 ± 0.388 | 7.828 ± 0.426 | 8.010 ± 0.424 | 7.940 ± 0.335 | 7.296 ± 0.202
Thymus
Absolute | 0.337 ± 0.011 | 0.365 ± 0.016 | 0.324 ± 0.024 | 0.342 ± 0.010 | 0.350 ± 0.020 | 0.325 ± 0.013
Relative | 2.729 ± 0.124 | 2.937 ± 0.085 | 2.666 ± 0.198 | 2.812 ± 0.074 | 2.718 ± 0.063 | 2.762 ± 0.127

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

TABLE F2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the 3-Month Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 280 ± 6 | 298 ± 6 | 282 ± 7 | 279 ± 6 | 272 ± 6 | 259 ± 7^*^
Heart
Absolute | 0.895 ± 0.020 | 0.940 ± 0.025 | 0.908 ± 0.026 | 0.904 ± 0.020 | 0.899 ± 0.019 | 0.882 ± 0.034
Relative | 3.194 ± 0.028 | 3.157 ± 0.077 | 3.218 ± 0.053 | 3.244 ± 0.083 | 3.306 ± 0.053 | 3.397 ± 0.064
R. Kidney
Absolute | 1.010 ± 0.028 | 1.039 ± 0.027 | 0.989 ± 0.024 | 1.007 ± 0.019 | 0.995 ± 0.027 | 1.004 ± 0.034
Relative | 3.603 ± 0.055 | 3.484 ± 0.047 | 3.507 ± 0.051 | 3.607 ± 0.043 | 3.653 ± 0.042 | 3.865 ± 0.053^**^
Liver
Absolute | 11.741 ± 0.345 | 12.165 ± 0.425 | 11.265 ± 0.351 | 11.115 ± 0.382 | 10.585 ± 0.436 | 10.607 ± 0.509
Relative | 41.9 ± 0.7 | 40.8 ± 1.1 | 39.9 ± 0.7 | 39.7 ± 0.7 | 38.8 ± 1.0 | 40.7 ± 1.2
Lung
Absolute | 1.801 ± 0.117 | 1.716 ± 0.134 | 1.586 ± 0.071^b^ | 1.536 ± 0.074 | 1.605 ± 0.111 | 1.443 ± 0.049^*^
Relative | 6.396 ± 0.311 | 5.747 ± 0.411 | 5.534 ± 0.206^b^ | 5.513 ± 0.280 | 5.918 ± 0.439 | 5.589 ± 0.212
R. Testis
Absolute | 1.402 ± 0.015 | 1.447 ± 0.023 | 1.382 ± 0.027 | 1.403 ± 0.015 | 1.402 ± 0.022 | 1.335 ± 0.026
Relative | 5.020 ± 0.092 | 4.866 ± 0.091 | 4.905 ± 0.077 | 5.030 ± 0.068 | 5.161 ± 0.067 | 5.162 ± 0.083
Thymus
Absolute | 0.344 ± 0.010 | 0.366 ± 0.011 | 0.334 ± 0.016 | 0.320 ± 0.015 | 0.318 ± 0.014 | 0.273 ± 0.012^**^
Relative | 1.230 ± 0.033 | 1.230 ± 0.036 | 1.177 ± 0.039 | 1.145 ± 0.051 | 1.170 ± 0.049 | 1.055 ± 0.044^**^
Female
Necropsy body wt | 177 ± 3 | 169 ± 2 | 174 ± 2 | 179 ± 4 | 167 ± 2 | 171 ± 4
Heart
Absolute | 0.662 ± 0.015 | 0.613 ± 0.009^*^ | 0.643 ± 0.018 | 0.649 ± 0.010 | 0.610 ± 0.011^*^ | 0.662 ± 0.010
Relative | 3.748 ± 0.047 | 3.636 ± 0.063 | 3.690 ± 0.092 | 3.639 ± 0.053 | 3.652 ± 0.051 | 3.879 ± 0.063
R. Kidney
Absolute | 0.681 ± 0.012 | 0.639 ± 0.013 | 0.690 ± 0.011 | 0.709 ± 0.022 | 0.666 ± 0.016 | 0.716 ± 0.023
Relative | 3.860 ± 0.049 | 3.787 ± 0.058 | 3.964 ± 0.079 | 3.960 ± 0.053 | 3.985 ± 0.065 | 4.197 ± 0.149^**^
Liver
Absolute | 6.560 ± 0.076 | 6.215 ± 0.116 | 6.562 ± 0.225 | 6.793 ± 0.325 | 6.383 ± 0.102 | 6.374 ± 0.223
Relative | 37.2 ± 0.5 | 36.8 ± 0.4 | 37.7 ± 1.3 | 37.8 ± 1.0 | 38.2 ± 0.5 | 37.2 ± 0.8
Lung
Absolute | 1.112 ± 0.038 | 1.100 ± 0.033 | 1.178 ± 0.079 | 1.154 ± 0.054 | 1.196 ± 0.028 | 1.191 ± 0.052
Relative | 6.284 ± 0.127 | 6.528 ± 0.212 | 6.737 ± 0.400 | 6.461 ± 0.290 | 7.163 ± 0.172 | 6.935 ± 0.190
Thymus
Absolute | 0.281 ± 0.009 | 0.227 ± 0.006^*^ | 0.278 ± 0.008 | 0.265 ± 0.009 | 0.241 ± 0.006^**^ | 0.237 ± 0.007^**^
Relative | 1.597 ± 0.065 | 1.343 ± 0.036^**^ | 1.598 ± 0.061 | 1.486 ± 0.056 | 1.442 ± 0.034 | 1.385 ± 0.042^*^

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

b n=9

TABLE F3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for B6C3F_1_ Mice in the 2-Week Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 12.5 mg/kg | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Necropsy body wt | 25.2 ± 0.5 | 25.6 ± 0.3 | 25.0 ± 0.4 | 25.5 ± 0.6 | 23.7 ± 1.5 | 23.1 ± 1.3
Heart
Absolute | 0.129 ± 0.001 | 0.137 ± 0.002 | 0.143 ± 0.009 | 0.144 ± 0.004 | 0.135 ± 0.008 | 0.125 ± 0.007
Relative | 5.113 ± 0.091 | 5.368 ± 0.083 | 5.710 ± 0.286^*^ | 5.621 ± 0.071 | 5.716 ± 0.114^*^ | 5.413 ± 0.073
R. Kidney
Absolute | 0.240 ± 0.008 | 0.248 ± 0.009 | 0.242 ± 0.009 | 0.261 ± 0.010 | 0.229 ± 0.013 | 0.238 ± 0.010
Relative | 9.511 ± 0.283 | 9.691 ± 0.306 | 9.646 ± 0.212 | 10.208 ± 0.284 | 9.712 ± 0.219 | 10.382 ± 0.249
Liver
Absolute | 1.409 ± 0.027 | 1.427 ± 0.059 | 1.392 ± 0.038 | 1.462 ± 0.031 | 1.240 ± 0.133 | 1.250 ± 0.120
Relative | 55.9 ± 0.8 | 55.8 ± 1.8 | 55.6 ± 0.7 | 57.3 ± 1.0 | 51.7 ± 3.0 | 53.7 ± 2.8
Lung
Absolute | 0.202 ± 0.004 | 0.191 ± 0.004 | 0.193 ± 0.014 | 0.211 ± 0.006 | 0.182 ± 0.009 | 0.180 ± 0.008
Relative | 8.009 ± 0.199 | 7.487 ± 0.148 | 7.702 ± 0.461 | 8.266 ± 0.269 | 7.720 ± 0.159 | 7.938 ± 0.652
R. Testis
Absolute | 0.099 ± 0.002 | 0.100 ± 0.004 | 0.104 ± 0.004 | 0.104 ± 0.002 | 0.101 ± 0.002 | 0.100 ± 0.002
Relative | 3.942 ± 0.057 | 3.924 ± 0.179 | 4.146 ± 0.105 | 4.057 ± 0.060 | 4.347 ± 0.270 | 4.436 ± 0.371
Thymus
Absolute | 0.060 ± 0.003 | 0.049 ± 0.004 | 0.054 ± 0.003 | 0.045 ± 0.003^**^ | 0.038 ± 0.003^**^ | 0.036 ± 0.005^**^
Relative | 2.365 ± 0.119 | 1.922 ± 0.143 | 2.148 ± 0.105 | 1.747 ± 0.104^**^ | 1.615 ± 0.090^**^ | 1.532 ± 0.185^**^
Female
Necropsy body wt | 21.0 ± 0.5 | 21.3 ± 0.5 | 22.0 ± 0.3 | 21.5 ± 0.2 | 22.5 ± 0.3^*^ | 22.4 ± 0.4^*^
Heart
Absolute | 0.121 ± 0.004 | 0.124 ± 0.002 | 0.128 ± 0.003 | 0.132 ± 0.003 | 0.126 ± 0.005 | 0.132 ± 0.003
Relative | 5.747 ± 0.133 | 5.842 ± 0.135 | 5.840 ± 0.201 | 6.148 ± 0.149 | 5.590 ± 0.179 | 5.911 ± 0.164
R. Kidney
Absolute | 0.176 ± 0.008 | 0.171 ± 0.004 | 0.181 ± 0.003 | 0.176 ± 0.003 | 0.189 ± 0.007 | 0.191 ± 0.008
Relative | 8.358 ± 0.245 | 8.048 ± 0.124 | 8.239 ± 0.208 | 8.186 ± 0.136 | 8.390 ± 0.237 | 8.511 ± 0.248
Liver
Absolute | 1.282 ± 0.044 | 1.246 ± 0.056 | 1.346 ± 0.047 | 1.297 ± 0.036 | 1.295 ± 0.038 | 1.316 ± 0.034
Relative | 61.0 ± 0.9 | 58.5 ± 1.3 | 61.0 ± 1.2 | 60.4 ± 1.2 | 57.6 ± 1.2 | 58.7 ± 1.0
Lung
Absolute | 0.176 ± 0.014 | 0.194 ± 0.009 | 0.183 ± 0.011 | 0.176 ± 0.002 | 0.197 ± 0.008 | 0.178 ± 0.005
Relative | 8.327 ± 0.511 | 9.119 ± 0.331 | 8.309 ± 0.501 | 8.188 ± 0.133 | 8.777 ± 0.264 | 7.927 ± 0.234
Thymus
Absolute | 0.073 ± 0.007 | 0.073 ± 0.003 | 0.082 ± 0.006 | 0.073 ± 0.002 | 0.076 ± 0.003 | 0.078 ± 0.006
Relative | 3.488 ± 0.300 | 3.420 ± 0.060 | 3.718 ± 0.224 | 3.417 ± 0.074 | 3.369 ± 0.155 | 3.453 ± 0.219

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

TABLE F4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for B6C3F1 Mice in the 3-Month Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 36.70 ± 0.70 | 34.86 ± 0.81 | 36.80 ± 1.13 | 36.10 ± 0.89 | 34.87 ± 0.70 | 34.87 ± 0.70
Heart
Absolute | 0.180 ± 0.004 | 0.167 ± 0.003 | 0.184 ± 0.005 | 0.178 ± 0.007 | 0.186 ± 0.009 | 0.180 ± 0.006
Relative | 4.897 ± 0.087 | 4.818 ± 0.114 | 5.019 ± 0.137 | 4.941 ± 0.180 | 5.323 ± 0.215 | 5.137 ± 0.169
R. Kidney
Absolute | 0.334 ± 0.006 | 0.329 ± 0.008 | 0.329 ± 0.0080.349 | 0.324 ± 0.010 | 0.331 ± 0.007 | 0.329 ± 0.008
Relative | 9.117 ± 0.196 | 9.469 ± 0.267 | 9.518 ± 0.162 | 9.003 ± 0.272 | 9.528 ± 0.240 | 9.426 ± 0.213
Liver
Absolute | 1.744 ± 0.042 | 1.671 ± 0.052 | 1.865 ± 0.050 | 1.741 ± 0.068 | 1.748 ± 0.036 | 1.738 ± 0.039
Relative | 47.6 ± 1.0 | 47.9 ± 1.0 | 50.8 ± 0.9 | 48.2 ± 1.3 | 50.2 ± 0.9 | 49.7 ± 0.7
Lung
Absolute | 0.302 ± 0.019 | 0.280 ± 0.009 | 0.281 ± 0.014 | 0.283 ± 0.018^b^ | 0.266 ± 0.013 | 0.267 ± 0.016
Relative | 8.263 ± 0.538 | 8.044 ± 0.282 | 7.649 ± 0.340 | 7.848 ± 0.482^b^ | 7.656 ± 0.396 | 7.618 ± 0.402
R. Testis
Absolute | 0.112 ± 0.004 | 0.117 ± 0.003 | 0.119 ± 0.003 | 0.118 ± 0.004 | 0.115 ± 0.003 | 0.120 ± 0.003
Relative | 3.058 ± 0.102 | 3.374 ± 0.105 | 3.250 ± 0.068 | 3.271 ± 0.105 | 3.304 ± 0.066 | 3.448 ± 0.104^*^
Thymus
Absolute | 0.043 ± 0.002 | 0.040 ± 0.004 | 0.042 ± 0.003 | 0.042 ± 0.002 | 0.041 ± 0.002 | 0.041 ± 0.002
Relative | 1.168 ± 0.058 | 1.139 ± 0.110 | 1.128 ± 0.065 | 1.173 ± 0.051 | 1.168 ± 0.057 | 1.158 ± 0.037
Female
Necropsy body wt | 31.07 ± 1.36 | 31.88 ± 0.92 | 33.29 ± 1.65 | 32.85 ± 1.25 | 30.55 ± 0.54 | 32.85 ± 1.2530
Heart
Absolute | 0.146 ± 0.004 | 0.161 ± 0.007 | 0.162 ± 0.005 | 0.151 ± 0.003 | 0.154 ± 0.003 | 0.161 ± 0.006
Relative | 4.752 ± 0.157 | 5.083 ± 0.267 | 4.964 ± 0.278 | 4.648 ± 0.185 | 5.058 ± 0.138 | 5.247 ± 0.284
R. Kidney
Absolute | 0.216 ± 0.005 | 0.225 ± 0.004 | 0.226 ± 0.006 | 0.219 ± 0.004 | 0.221 ± 0.006 | 0.231 ± 0.006
Relative | 7.043 ± 0.252 | 7.094 ± 0.173 | 6.880 ± 0.221 | 6.730 ± 0.223 | 7.234 ± 0.178 | 7.234 ± 0.1787.5
Liver
Absolute | 1.521 ± 0.050 | 1.528 ± 0.051 | 1.629 ± 0.066 | 1.559 ± 0.035 | 1.527 ± 0.025 | 1.550 ± 0.046
Relative | 49.4 ± 1.8 | 48.0 ± 1.2 | 49.2 ± 1.5 | 47.8 ± 1.4 | 50.0 ± 0.8 | 50.2 ± 1.4
Lung
Absolute | 0.301 ± 0.019 | 0.317 ± 0.012 | 0.296 ± 0.013 | 0.290 ± 0.013 | 0.311 ± 0.020 | 0.305 ± 0.018
Relative | 9.724 ± 0.583 | 10.013 ± 0.502 | 9.069 ± 0.576 | 8.924 ± 0.474 | 68.924 ± 0.4741 | 9.971 ± 0.712
Thymus
Absolute | 0.060 ± 0.003 | 0.060 ± 0.003 | 0.062 ± 0.005 | 0.058 ± 0.003 | 0.054 ± 0.003 | 0.059 ± 0.003
Relative | 1.949 ± 0.088 | 1.879 ± 0.054 | 1.843 ± 0.101 | 1.769 ± 0.096 | 1.773 ± 0.085 | 1.895 ± 0.067

* Significantly different (P≤0.05) from the vehicle control group by Dunnett’s test

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

b n=9

TABLE F5 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Tg.AC Hemizygous Mice in the 6-Month Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Male
n | 14 | 15 | 12 | 14 | 13 | 11
Necropsy body wt | 33.4 ± 0.8 | 32.5 ± 1.3 | 36.8 ± 1.3 | 34.7 ± 0.9 | 33.1 ± 0.9 | 35.8 ± 1.7
Heart
Absolute | 0.222 ± 0.004 | 0.211 ± 0.006 | 0.233 ± 0.009 | 0.225 ± 0.005 | 0.221 ± 0.006 | 0.289 ± 0.014^**^
Relative | 6.700 ± 0.187 | 6.599 ± 0.260 | 6.389 ± 0.275 | 6.516 ± 0.113 | 6.678 ± 0.166 | 8.189 ± 0.411^**^
R. Kidney
Absolute | 0.299 ± 0.008 | 0.301 ± 0.018 | 0.306 ± 0.005 | 0.294 ± 0.006 | 0.300 ± 0.008 | 0.334 ± 0.010
Relative | 8.977 ± 0.170 | 9.292 ± 0.415 | 8.381 ± 0.187 | 8.509 ± 0.168 | 9.079 ± 0.157 | 9.465 ± 0.321
Liver
Absolute | 1.833 ± 0.049 | 1.778 ± 0.075 | 1.920 ± 0.062 | 1.874 ± 0.055 | 1.800 ± 0.049 | 2.088 ± 0.081^*^
Relative | 54.9 ± 0.9 | 54.8 ± 0.9 | 52.3 ± 1.1 | 54.2 ± 1.2 | 54.4 ± 0.9 | 58.7 ± 1.4
Lung
Absolute | 0.360 ± 0.013 | 0.315 ± 0.019 | 0.346 ± 0.013 | 0.345 ± 0.009 | 0.311 ± 0.013^*^ | 0.272 ± 0.016^**^
Relative | 10.836 ± 0.405 | 9.715 ± 0.451 | 9.567 ± 0.486 | 10.007 ± 0.272 | 9.432 ± 0.411^*^ | 7.780 ± 0.613^**^
R. Testis
Absolute | 0.082 ± 0.005 | 0.089 ± 0.005 | 0.088 ± 0.002 | 0.091 ± 0.003 | 0.088 ± 0.003 | 0.075 ± 0.003
Relative | 2.468 ± 0.148 | 2.702 ± 0.116 | 2.409 ± 0.093 | 2.631 ± 0.097 | 2.678 ± 0.102 | 2.114 ± 0.099
Thymus
Absolute | 0.030 ± 0.002 | 0.025 ± 0.002 | 0.035 ± 0.004 | 0.033 ± 0.002 | 0.032 ± 0.004 | 0.023 ± 0.003
Relative | 0.883 ± 0.071 | 0.765 ± 0.054 | 0.969 ± 0.107 | 0.950 ± 0.060 | 0.953 ± 0.088 | 0.636 ± 0.084
Female
n | 15 | 14 | 12 | 14 | 14 | 12
Necropsy body wt | 28.4 ± 0.9 | 27.4 ± 0.7 | 28.8 ± 0.5 | 27.8 ± 0.4 | 27.0 ± 1.1 | 29.0 ± 0.7
Heart
Absolute | 0.195 ± 0.004 | 0.189 ± 0.003 | 0.187 ± 0.006 | 0.183 ± 0.005 | 0.200 ± 0.006 | 0.226 ± 0.008^**^
Relative | 6.910 ± 0.193 | 6.932 ± 0.158 | 6.499 ± 0.185 | 6.582 ± 0.148 | 7.626 ± 0.561 | 7.808 ± 0.284
R. Kidney
Absolute | 0.215 ± 0.004 | 0.210 ± 0.004 | 0.217 ± 0.005 | 0.209 ± 0.004 | 0.204 ± 0.006 | 0.248 ± 0.007^**^
Relative | 7.610 ± 0.169 | 7.683 ± 0.144 | 7.573 ± 0.245 | 7.521 ± 0.137 | 7.667 ± 0.248 | 8.573 ± 0.252^**^
Liver
Absolute | 1.590 ± 0.042 | 1.550 ± 0.040 | 1.608 ± 0.036 | 1.515 ± 0.026^b^ | 1.482 ± 0.064 | 1.903 ± 0.087^**^
Relative | 56.2 ± 1.1 | 56.6 ± 1.2 | 56.0 ± 1.8 | 54.5 ± 0.6^b^ | 55.1 ± 1.6 | 65.8 ± 2.9^**^
Lung
Absolute | 0.331 ± 0.007 | 0.321 ± 0.008 | 0.320 ± 0.012 | 0.308 ± 0.009^b^ | 0.301 ± 0.011^*^ | 0.246 ± 0.009^**^
Relative | 11.757 ± 0.387 | 11.750 ± 0.329 | 11.109 ± 0.434 | 11.098 ± 0.341^b^ | 11.279 ± 0.389 | 8.548 ± 0.389^**^
Thymus
Absolute | 0.034 ± 0.002 | 0.034 ± 0.003 | 0.036 ± 0.003 | 0.033 ± 0.002 | 0.033 ± 0.002 | 0.025 ± 0.002
Relative | 1.181 ± 0.046 | 1.247 ± 0.083 | 1.247 ± 0.117 | 1.165 ± 0.074 | 1.233 ± 0.080 | 0.881 ± 0.073^*^

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

b n=13