# APPENDIX E CLINICAL PATHOLOGY RESULTS

TABLE E1 Hematology and Clinical Chemistry Data for Rats in the 3-Month Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Male
Hematology
n
Day 4 | 10 | 10 | 10 | 9 | 10 | 10
Day 23 | 9 | 10 | 10 | 9 | 10 | 10
Week 14 | 9 | 10 | 10 | 10 | 10 | 9
Hematocrit (%)
Day 4 | 39.1 ± 0.4 | 38.3 ± 0.5 | 37.1 ± 0.4^*^ | 37.7 ± 0.5 | 38.6 ± 0.41 | 39.3 ± 0.5
Day 23 | 43.5 ± 0.5 | 43.4 ± 0.7 | 42.8 ± 0.5 | 43.2 ± 0.5 | 43.5 ± 0.4 | 43.7 ± 0.3
Week 14 | 46.7 ± 0.3 | 46.2 ± 0.5 | 46.1 ± 0.2 | 47.2 ± 0.4 | 47.5 ± 0.6 | 48.1 ± 0.6
Hemoglobin (g/dL)
Day 4 | 12.8 ± 0.1 | 12.6 ± 0.2 | 12.3 ± 0.1 | 12.5 ± 0.2 | 12.7 ± 0.1 | 12.9 ± 0.2
Day 23 | 14.4 ± 0.2 | 14.3 ± 0.2 | 14.2 ± 0.1 | 14.3 ± 0.1 | 14.4 ± 0.1 | 14.4 ± 0.1
Week 14 | 15.2 ± 0.1 | 15.0 ± 0.1 | 15.1 ± 0.1 | 15.3 ± 0.1 | 15.5 ± 0.1 | 15.8 ± 0.1^*^
Erythrocytes (10^6^/µL)
Day 4 | 6.54 ± 0.08 | 6.50 ± 0.09 | 6.27 ± 0.09 | 6.35 ± 0.09 | 6.52 ± 0.07 | 6.65 ± 0.09
Day 23 | 7.68 ± 0.11 | 7.66 ± 0.12 | 7.51 ± 0.10 | 7.61 ± 0.09 | 7.69 ± 0.09 | 7.75 ± 0.07
Week 14 | 9.09 ± 0.07 | 8.97 ± 0.10 | 9.04 ± 0.04 | 9.14 ± 0.07 | 9.25 ± 0.09 | 9.42 ± 0.09^*^
Reticulocytes (10^6^/µL)
Day 4 | 0.39 ± 0.04 | 0.32 ± 0.04 | 0.30 ± 0.04 | 0.28 ± 0.03 | 0.40 ± 0.03 | 0.31 ± 0.04
Day 23 | 0.17 ± 0.02 | 0.16 ± 0.01 | 0.15 ± 0.01 | 0.14 ± 0.01 | 0.16 ± 0.01 | 0.15 ± 0.01
Week 14 | 0.15 ± 0.01 | 0.14 ± 0.02 | 0.15 ± 0.01 | 0.15 ± 0.01 | 0.13 ± 0.01 | 0.12 ± 0.01
Nucleated erythrocytes (10^3^/µL)
Day 4 | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.02 ± 0.02 | 0.02 ± 0.02 | 0.00 ± 0.00 | 0.01 ± 0.01
Day 23 | 0.01 ± 0.01 | 0.02 ± 0.01 | 0.00 ± 0.00 | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.01 ± 0.01 | 0.01 ± 0.01 | 0.02 ± 0.01 | 0.02 ± 0.01
Mean cell volume (fL)
Day 4 | 59.7 ± 0.2 | 58.9 ± 0.3 | 59.1 ± 0.3 | 59.3 ± 0.3 | 59.2 ± 0.2 | 59.2 ± 0.2
Day 23 | 56.7 ± 0.3 | 56.6 ± 0.2 | 57.0 ± 0.3 | 56.7 ± 0.2 | 56.5 ± 0.3 | 56.4 ± 0.3
Week 14 | 51.4 ± 0.1 | 51.5 ± 0.2 | 51.0 ± 0.2 | 51.6 ± 0.1 | 51.4 ± 0.3 | 51.0 ± 0.3
Mean cell hemoglobin (pg)
Day 4 | 19.5 ± 0.1 | 19.4 ± 0.1 | 19.6 ± 0.1 | 19.6 ± 0.1 | 19.5 ± 0.1 | 19.4 ± 0.1
Day 23 | 18.7 ± 0.1 | 18.7 ± 0.1 | 18.9 ± 0.1 | 18.8 ± 0.1 | 18.7 ± 0.1 | 18.6 ± 0.1
Week 14 | 16.7 ± 0.1 | 16.8 ± 0.1 | 16.7 ± 0.1 | 16.8 ± 0.1 | 16.7 ± 0.1 | 16.8 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 4 | 32.6 ± 0.1 | 32.9 ± 0.2 | 33.1 ± 0.1 | 33.0 ± 0.1 | 32.9 ± 0.1 | 32.8 ± 0.1
Day 23 | 33.1 ± 0.1 | 33.0 ± 0.1 | 33.2 ± 0.2 | 33.1 ± 0.1 | 33.0 ± 0.2 | 33.0 ± 0.1
Week 14 | 32.5 ± 0.1 | 32.5 ± 0.2 | 32.8 ± 0.1 | 32.5 ± 0.1 | 32.6 ± 0.2 | 32.9 ± 0.2
Platelets (10^3^/µL)
Day 4 | 929.4 ± 37.5 | 944.9 ± 24.1 | 963.8 ± 12.9 | 910.1 ± 19.3 | 951.4 ± 16.8 | 900.3 ± 36.4
Day 23 | 790.7 ± 13.6 | 791.8 ± 13.6 | 805.4 ± 6.4 | 781.4 ± 15.8 | 800.6 ± 13.1 | 820.3 ± 13.6
Week 14 | 708.6 ± 15.6 | 719.9 ± 11.7 | 689.5 ± 13.9 | 738.7 ± 17.6 | 706.2 ± 12.4 | 729.3 ± 14.9
Leukocytes (10^3^/µL)
Day 4 | 7.48 ± 0.33 | 7.15 ± 0.29 | 6.96 ± 0.48 | 6.67 ± 0.56 | 6.90 ± 0.25 | 8.12 ± 0.18
Day 23 | 7.37 ± 0.56 | 7.76 ± 0.61 | 7.68 ± 0.36 | 7.22 ± 0.54 | 7.83 ± 0.35 | 7.13 ± 0.51
Week 14 | 9.22 ± 0.28 | 9.64 ± 0.38 | 8.27 ± 0.40 | 8.42 ± 0.30 | 7.82 ± 0.29^**^ | 8.51 ± 0.49
Segmented neutrophils (10^3^/µL)
Day 4 | 1.14 ± 0.13 | 1.19 ± 0.10 | 1.06 ± 0.15 | 0.99 ± 0.12 | 0.87 ± 0.09 | 1.24 ± 0.14
Day 23 | 0.71 ± 0.08 | 0.88 ± 0.13 | 0.75 ± 0.09 | 0.86 ± 0.10 | 0.76 ± 0.07 | 0.91 ± 0.07
Week 14 | 1.16 ± 0.13 | 1.25 ± 0.09 | 1.33 ± 0.11 | 1.13 ± 0.08 | 1.28 ± 0.17 | 2.10 ± 0.19^**^
n
Day 4 | 10 | 10 | 10 | 9 | 10 | 10
Day 23 | 9 | 10 | 10 | 9 | 10 | 10
Week 14 | 9 | 10 | 10 | 10 | 10 | 9
Bands (10^3^/µL)
Day 4 | 0.02 ± 0.02 | 0.04 ± 0.02 | 0.02 ± 0.01 | 0.02 ± 0.01 | 0.04 ± 0.01 | 0.05 ± 0.02
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL)
Day 4 | 6.16 ± 0.32 | 5.70 ± 0.23 | 5.72 ± 0.40 | 5.52 ± 0.46 | 5.87 ± 0.23 | 6.63 ± 0.14
Day 23 | 6.57 ± 0.50 | 6.78 ± 0.54 | 6.84 ± 0.35 | 6.26 ± 0.48 | 6.97 ± 0.32 | 6.12 ± 0.51
Week 14 | 7.86 ± 0.23 | 8.19 ± 0.38 | 6.74 ± 0.34^*^ | 7.11 ± 0.28 | 6.40 ± 0.32^**^ | 6.25 ± 0.49^**^
Monocytes(10^3^/µL)
Day 4 | 0.15 ± 0.03 | 0.19 ± 0.06 | 0.13 ± 0.04 | 0.13 ± 0.04 | 0.12 ± 0.05 | 0.17 ± 0.03
Day 23 | 0.06 ± 0.02 | 0.08 ± 0.02 | 0.06 ± 0.02 | 0.09 ± 0.02 | 0.08 ± 0.02 | 0.08 ± 0.02
Week 14 | 0.16 ± 0.02 | 0.14 ± 0.02 | 0.14 ± 0.020.14 | 0.10 ± 0.03 | 0.09 ± 0.03 | 0.13 ± 0.04
Basophils (10^3^/µL)
Day 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Day 23 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 14 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/µL)
Day 4 | 0.02 ± 0.01 | 0.03 ± 0.02 | 0.03 ± 0.02 | 0.02 0.01 | 0.02 ± 0.01 | 0.03 ± 0.02
Day 23 | 0.03 ± 0.02 | 0.02 ± 0.01 | 0.04 ± 0.01 | 0.02 ± 0.01 | 0.02 ± 0.01 | 0.02 ± 0.01
Week 14 | 0.04 ± 0.02 | 0.06 ± 0.02 | 0.07 ± 0.01 | 0.09 ± 0.03 | 0.07 ± 0.01 | 0.03 ± 0.02
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 9.6 ± 0.2 | 9.6 ± 0.4 | 10.4 ± 0.6 | 9.7 ± 0.4 | 9.7 ± 0.4 | 10.0 ± 0.3
Day 23 | 12.0 ± 0.5 | 11.6 ± 0.5 | 11.5 ± 0.4 | 12.4 ± 0.4 | 11.5 ± 0.4 | 11.3 ± 0.5
Week 14 | 16.5 ± 0.6 | 15.2 ± 0.6 | 16.6 ± 0.3 | 16.8 ± 0.5 | 16.8 ± 0.5 | 15.4 ± 0.3
Creatinine (mg/dL)
Day 4 | 0.43 ± 0.02 | 0.39 ± 0.01 | 0.41 ± 0.01 | 0.42 ± 0.01 | 0.40 ± 0.00 | 0.42 ± 0.01
Day 23 | 0.45 ± 0.02 | 0.43 ± 0.02 | 0.43 ± 0.02 | 0.47 ± 0.02 | 0.48 ± 0.01 | 0.48 ± 0.01
Week 14 | 0.50 ± 0.00 | 0.50 ± 0.00 | 0.50 ± 0.02 | 0.51 ± 0.01 | 0.51 ± 0.01 | 0.51 ± 0.01
Total protein (g/dL)
Day 4 | 5.4 ± 0.1 | 5.3 ± 0.1 | 5.3 ± 0.1 | 5.3 ± 0.1 | 5.3 ± 0.1 | 5.4 ± 0.1
Day 23 | 5.8 ± 0.1 | 5.7 ± 0.1 | 5.7 ± 0.1 | 5.8 ± 0.1 | 5.8 ± 0.1 | 5.8 ± 0.1
Week 14 | 6.5 ± 0.1 | 6.6 ± 0.1 | 6.5 ± 0.16.6 ± 0 | 6.6 ± 0.16.5 ± 0 | 6.6 ± 0.16.5 ± 0 | 6.6 ± 0.16.5 ± 0
Albumin (g/dL)
Day 4 | 4.1 ± 0.0 | 4.0 ± 0.1 | 4.0 ± 0.14.0 | 4.1 ± 0.1 | 4.0 ± 0.0 | 4.1 ± 0.1
Day 23 | 4.3 ± 0.1 | 4.2 ± 0.1 | 4.2 ± 0.1 | 4.3 ± 0.14.2 ± 0 | 4.3 ± 0.14.2 ± 0 | 4.2 ± 0.14.2 ± 0
Week 14 | 4.6 ± 0.0 | 4.6 ± 0.0 | 4.6 ± 0.0 | 4.7 ± 0.0 | 4.6 ± 0.0 | 4.7 ± 0.0
Alanine aminotransferase (IU/L)
Day 4 | 78 ± 2 | 78 ± 3 | 77 ± 2 | 78 ± 2 | 76 ± 4 | 83 ± 3
Day 23 | 66 ± 2 | 66 ± 1 | 62 ± 2 | 65 ± 2 | 61 ± 2 | 64 ± 1
Week 14 | 67 ± 2 | 67 ± 2 | 66 ± 3 | 73 ± 3 | 66 ± 2 | 79 ± 3
n | 10 | 10 | 10 | 10 | 10 | 10
Alkaline phosphatase (IU/L)
Day 4 | 812 ± 21 | 790 ± 23 | 779 ± 17 | 782 ± 10 | 752 ± 12^*^ | 754 ± 9^*^
Day 23 | 502 ± 6 | 497 ± 10 | 480 ± 7 | 489 ± 13 | 489 ± 7 | 498 ± 8
Week 14 | 291 ± 6 | 276 ± 4 | 284 ± 7 | 262 ± 4^**^ | 279 ± 4 | 286 ± 7
Creatine kinase (IU/L)
Day 4 | 266 ± 12 | 313 ± 43 | 283 ± 19 | 406 ± 63 | 359 ± 58 | 354 ± 36
Day 23 | 526 ± 83 | 334 ± 43^b^ | 526 ± 100 | 447 ± 49^b^ | 426 ± 50 | 446 ± 49
Week 14 | 179 ± 22 | 230 ± 41 | 183 ± 28 | 196 ± 25 | 251 ± 28 | 311 ± 73
Sorbitol dehydrogenase (IU/L)
Day 4 | 13 ± 1 | 14 ± 1 | 13 ± 0 | 14 ± 1 | 14 ± 1 | 14 ± 1
Day 23 | 15 ± 1 | 15 ± 1 | 15 ± 1 | 15 ± 1 | 16 ± 1 | 15 ± 1
Week 14 | 18 ± 1 | 19 ± 1 | 18 ± 1 | 17 ± 1 | 18 ± 1 | 17 ± 1
Bile acids (µmol/L)
Day 4 | 26.2 ± 2.6 | 24.8 ± 1.9 | 24.3 ± 1.6 | 24.2 ± 2.3 | 22.9 ± 1.6 | 26.1 ± 1.8
Day 23 | 31.8 ± 3.0 | 25.7 ± 1.8 | 29.3 ± 2.5 | 24.3 ± 2.3 | 25.4 ± 2.5 | 22.3 ± 2.4
Week 14 | 24.4 ± 2.8 | 23.3 ± 2.6 | 27.0 ± 3.5 | 28.1 ± 2.1 | 28.5 ± 2.8 | 24.9 ± 1.9
Female
Hematology
n
Day 4 | 10 | 10 | 10 | 10 | 10 | 10
Day 23 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 10 | 10 | 9 | 10 | 8 | 10
Hematocrit (%)
Day 4 | 40.6 ± 0.6 | 40.9 ± 0.3 | 40.8 ± 0.7 | 39.9 ± 0.4 | 39.8 ± 0.7 | 40.3 ± 0.4
Day 23 | 45.7 ± 0.3 | 45.8 ± 0.4 | 46.8 ± 0.4 | 46.4 ± 0.5 | 46.5 ± 0.6 | 46.3 ± 0.7
Week 14 | 45.0 ± 0.3 | 45.9 ± 0.3 | 45.9 ± 0.34 | 44.6 ± 0.7 | 46.0 ± 0.4 | 46.0 ± 0.445
Hemoglobin (g/dL)
Day 4 | 13.5 ± 0.2 | 13.5 ± 0.21 | 13.6 ± 0.2 | 13.3 ± 0.1 | 13.2 ± 0.2 | 13.4 ± 0.1
Day 23 | 14.9 ± 0.1 | 14.8 ± 0.1 | 15.2 ± 0.1 | 15.2 ± 0.1 | 15.2 ± 0.115.2 | ± 0.1 15.2
Week 14 | 14.8 ± 0.1 | 15.0 ± 0.1 | 15.0 ± 0.1 | 14.7 ± 0.2 | 15.0 ± 0.1 | 15.2 ± 0.1^**^
Erythrocytes (10^6^/µL)
Day 4 | 6.85 ± 0.11 | 6.93 ± 0.06 | 6.90 ± 0.13 | 6.90 ± 0.136.8 | 6.81 ± 0.12 | 6.84 ± 0.08
Day 23 | 7.93 ± 0.06 | 7.91 ± 0.06 | 8.03 ± 0.07 | 8.05 ± 0.08 | 8.06 ± 0.12 | 8.02 ± 0.13
Week 14 | 8.22 ± 0.06 | 8.43 ± 0.06 | 8.34 ± 0.07 | 8.19 ± 0.15 | 8.42 ± 0.07 | 8.34 ± 0.078
Reticulocytes(10^6^/µL)
Day 4 | 0.36 ± 0.03 | 0.38 ± 0.02 | 0.34 ± 0.03 | 0.34 ± 0.03 | 0.34 ± 0.02 | 0.38 ± 0.02
Day 23 | 0.08 ± 0.01 | 0.09 ± 0.01 | 0.09 ± 0.01 | 0.09 ± 0.01 | 0.08 ± 0.01 | 0.09 ± 0.01
Week 14 | 0.10 ± 0.01 | 0.09 ± 0.01 | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.09 ± 0.01
Nucleated erythrocytes (10^3^/µL)
Day 4 | 0.01 ± 0.01 | 0.02 ± 0.01 | 0.01 ± 0.02 | 0.01 ± 0.01 | 0.03 ± 0.01 | 0.01 ± 0.01
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.01 ± 0.01 | 0.00 ± 0.00
Week 14 | 0.02 ± 0.01 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 0.01 | 0.02 ± 0.01 | 0.00 ± 0.01
Mean cell volume (fL)
Day 4 | 59.3 ± 0.2 | 59.1 ± 0.3 | 59.1 ± 0.359.2 | 58.7 ± 0.4 | 58.4 ± 0.5 | 58.9 ± 0.2
Day 23 | 57.7 ± 0.3 | 57.9 ± 0.2 | 58.2 ± 0.2 | 57.6 ± 0.3 | 57.7 ± 0.4 | 57.7 ± 0.3
Week 14 | 54.7 ± 0.2 | 54.4 ± 0.3 | 54.4 ± 0.2 | 54.4 ± 0.3 | 54.6 ± 0.3 | 54.1 ± 0.2
Mean cell hemoglobin (pg)
Day 4 | 19.6 ± 0.1 | 19.5 ± 0.1 | 19.7 ± 0.1 | 19.6 ± 0.1 | 19.5 ± 0.1 | 19.6 ± 0.1
Day 23 | 18.8 ± 0.1 | 18.7 ± 0.1 | 18.9 ± 0.1 | 18.9 ± 0.1 | 18.9 ± 0.1 | 18.8 ± 0.1
Week 14 | 18.0 ± 0.1 | 17.9 ± 0.1 | 17.9 ± 0.1 | 18.0 ± 0.1 | 17.9 ± 0.1 | 17.9 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 4 | 33.2 ± 0.1 | 33.0 ± 0.1 | 33.2 ± 0.1 | 33.3 ± 0.1 | 33.3 ± 0.1 | 33.3 ± 0.1
Day 23 | 32.6 ± 0.1 | 32.4 ± 0.1 | 32.5 ± 0.1 | 32.7 ± 0.1 | 32.7 ± 0.1 | 32.6 ± 0.1
Week 14 | 32.9 ± 0.1 | 32.8 ± 0.1 | 33.0 ± 0.1 | 33.0 ± 0.1 | 33.1 ± 0.132 | 33.1 ± 0.132
Platelets (10^3^/µL)
Day 4 | 958.6 ± 16.1 | 892.6 ± 14.8 | 952.6 ± 21.9 | 990.1 ± 19.9 | 928.9 ± 17.5 | 941.5 ± 36.2
Day 23 | 804.6 ± 17.8 | 784.4 ± 24.2 | 794.9 ± 16.6 | 831.3 ± 16.3 | 796.5 ± 22.0 | 796.5 ± 22.0
Week 14 | 685.4 ± 19.0 | 667.8 ± 15.2 | 689.4 ± 11.8 | 677.9 ± 14.7 | 705.6 ± 12.2 | 711.2 ± 17.4
Leukocytes (10^3^/µL)
Day 4 | 7.39 ± 0.32 | 8.05 ± 0.28 | 8.04 ± 0.31 | 7.47 ± 0.41 | 7.78 ± 0.38 | 8.04 ± 0.317
Day 23 | 8.96 ± 0.60 | 9.39 ± 0.71 | 10.00 ± 0.84 | 9.52 ± 0.96 | 9.66 ± 0.76 | 10.26 ± 0.57
Week 14 | 8.89 ± 0.19 | 8.85 ± 0.62 | 8.80 ± 0.38 | 8.65 ± 0.37 | 9.58 ± 0.42 | 8.49 ± 0.52
Segmented neutrophils (10^3^/µL)
Day 4 | 1.07 ± 0.11 | 1.02 ± 0.12 | 0.99 ± 0.11 | 0.90 ± 0.07 | 1.02 ± 0.120.9 | 1.08 ± 0.08
Day 23 | 0.95 ± 0.09 | 0.85 ± 0.08^b^ | 0.90 ± 0.09 | 1.00 ± 0.17 | 1.00 ± 0.170 | 0.94 ± 0.10
Week 14 | 1.29 ± 0.08 | 1.38 ± 0.12 | 1.07 ± 0.05 | 1.26 ± 0.13 | 1.34 ± 0.11 | 1.71 ± 0.22
n
Day 4 | 10 | 10 | 10 | 10 | 10 | 10
Day 23 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 10 | 10 | 9 | 10 | 8 | 10
Bands (10^3^/µL)
Day 4 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00^b^ | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL)
Day 4 | 6.19 ± 0.29 | 6.87 ± 0.31 | 6.86 ± 0.26 | 6.46 ± 0.38 | 6.65 ± 0.37 | 6.71 ± 0.25
Day 23 | 7.84 ± 0.56 | 8.38 ± 0.62 | 8.84 ± 0.78 | 8.37 ± 0.81 | 8.58 ± 0.65 | 9.15 ± 0.54
Week 14 | 7.35 ± 0.23 | 7.21 ± 0.52 | 7.59 ± 0.35 | 7.15 ± 0.35 | 7.97 ± 0.36 | 6.66 ± 0.33
Monocytes(10^3^/µL)
Day 4 | 0.11 ± 0.03 | 0.14 ± 0.02 | 0.15 ± 0.03 | 0.09 ± 0.03 | 0.06 ± 0.02 | 0.12 ± 0.02
Day 23 | 0.12 ± 0.03 | 0.13 ± 0.04 | 0.14 ± 0.02 | 0.11 ± 0.03 | 0.11 ± 0.02 | 0.13 ± 0.04
Week 14 | 0.15 ± 0.04 | 0.18 ± 0.03 | 0.09 ± 0.01 | 0.15 ± 0.05 | 0.18 ± 0.05 | 0.09 ± 0.03
Basophils(10^3^/µL)
Day 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Day 23 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 14 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/µL)
Day 4 | 0.03 ± 0.01 | 0.03 ± 0.02 | 0.05 ± 0.02 | 0.02 ± 0.01 | 0.07 ± 0.02 | 0.04 ± 0.02
Day 23 | 0.05 ± 0.02 | 0.07 ± 0.02 | 0.11 ± 0.04 | 0.04 ± 0.02 | 0.07 ± 0.03 | 0.04 ± 0.02
Week 14 | 0.11 ± 0.02 | 0.08 ± 0.02 | 0.05 ± 0.02 | 0.09 ± 0.03 | 0.10 ± 0.04 | 0.03 ± 0.02
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 11.4 ± 0.5 | 11.6 ± 0.4 | 12.1 ± 0.6 | 11.5 ± 0.4 | 11.7 ± 0.5 | 11.3 ± 0.4
Day 23 | 15.3 ± 0.3 | 14.0 ± 0.3 | 14.9 ± 0.4 | 15.0 ± 0.4 | 14.7 ± 0.4 | 13.8 ± 0.6
Week 14 | 17.5 ± 0.3 | 18.6 ± 0.5 | 18.8 ± 0.6 | 17.6 ± 0.9 | 19.1 ± 0.5 | 16.7 ± 0.4
Creatinine (mg/dL)
Day 4 | 0.42 ± 0.01 | 0.41 ± 0.01 | 0.41 ± 0.01 | 0.41 ± 0.01 | 0.41 ± 0.01 | 0.43 ± 0.02
Day 23 | 0.39 ± 0.01 | 0.40 ± 0.00 | 0.40 ± 0.00 | 0.42 ± 0.01 | 0.42 ± 0.02 | 0.40 ± 0.00
Week 14 | 0.53 ± 0.02 | 0.52 ± 0.01 | 0.52 ± 0.01 | 0.53 ± 0.02 | 0.54 ± 0.02 | 0.52 ± 0.01
Total protein (g/dL)
Day 4 | 5.6 ± 0.1 | 5.6 ± 0.1 | 5.6 ± 0.1 | 5.6 ± 0.1 | 5.5 ± 0.1 | 5.6 ± 0.1
Day 23 | 5.6 ± 0.1 | 5.5 ± 0.1 | 5.7 ± 0.1 | 5.7 ± 0.1 | 5.7 ± 0.1 | 5.7 ± 0.1
Week 14 | 6.4 ± 0.1 | 6.4 ± 0.1 | 6.5 ± 0.1 | 6.4 ± 0.1 | 6.5 ± 0.1 | 6.5 ± 0.1
Albumin (g/dL)
Day 4 | 4.3 ± 0.0 | 4.3 ± 0.1 | 4.3 ± 0.0 | 4.3 ± 0.0 | 4.2 ± 0.1 | 4.3 ± 0.0
Day 23 | 4.3 ± 0.0 | 4.2 ± 0.0 | 4.3 ± 0.1 | 4.4 ± 0.1 | 4.3 ± 0.1 | 4.4 ± 0.1
Week 14 | 4.6 ± 0.1 | 4.7 ± 0.1 | 4.6 ± 0.1 | 4.5 ± 0.1 | 4.7 ± 0.0 | 4.7 ± 0.0
Alanine aminotransferase (IU/L)
Day 4 | 67 ± 3 | 67 ± 2 | 64 ± 2 | 62 ± 1 | 65 ± 2 | 63 ± 3
Day 23 | 59 ± 3 | 57 ± 2 | 57 ± 1 | 63 ± 3 | 58 ± 1 | 59 ± 2
Week 14 | 92 ± 5 | 90 ± 5 | 103 ± 11 | 85 ± 3 | 85 ± 5 | 80 ± 4
n | 10 | 10 | 10 | 10 | 10 | 10
Alkaline phosphatase (IU/L)
Day 4 | 645 ± 22 | 661 ± 15 | 616 ± 18 | 631 ± 17 | 637 ± 19 | 622 ± 18
Day 23 | 421 ± 9 | 405 ± 9 | 423 ± 7 | 426 ± 10 | 431 ± 14 | 435 ± 10
Week 14 | 288 ± 6 | 300 ± 8 | 278 ± 6 | 265 ± 11 | 280 ± 8 | 256 ± 7^**^
Creatine kinase (IU/L)
Day 4 | 262 ± 17 | 267 ± 22 | 299 ± 24 | 330 ± 68 | 290 ± 31 | 260 ± 14
Day 23 | 360 ± 39 | 287 ± 33 | 353 ± 64 | 326 ± 36 | 334 ± 25 | 331 ± 44
Week 14 | 193 ± 32 | 150 ± 15 | 180 ± 33 | 160 ± 20 | 218 ± 43 | 184 ± 28
Sorbitol dehydrogenase (IU/L)
Day 4 | 12 ± 0 | 12 ± 0 | 12 ± 0 | 12 ± 0 | 12 ± 0 | 12 ± 0
Day 23 | 15 ± 1 | 15 ± 1 | 16 ± 1 | 18 ± 2 | 17 ± 1 | 17 ± 1
Week 14 | 24 ± 2 | 22 ± 2 | 27 ± 5 | 23 ± 1 | 23 ± 1 | 20 ± 1
Bile acids (µmol/L)
Day 4 | 19.9 ± 1.1 | 20.4 ± 1.5 | 18.9 ± 1.2 | 18.9 ± 1.4 | 18.8 ± 1.4 | 17.2 ± 1.1
Day 23 | 19.3 ± 2.1 | 25.1 ± 2.2 | 23.9 ± 2.5 | 18.9 ± 2.3 | 21.8 ± 1.7 | 21.9 ± 2.2
Week 14 | 22.3 ± 3.2 | 30.9 ± 3.8 | 29.3 ± 5.7 | 25.8 ± 2.5 | 26.7 ± 2.4 | 24.6 ± 1.8

* Significantly different (P≤0.05) from the vehicle control group by Dunn’s or Shirley’s test

** P≤0.01

a Data are given as mean ± standard error. Statistical tests were performed on unrounded data.

b n=9

TABLE E2 Hematology Data for B6C3F1 Mice in the 3-Month Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Hematocrit (%) | 47.8 ± 1.1 | 46.4 ± 1.0 | 45.5 ± 0.6 | 46.2 ± 0.6 | 45.4 ± 0.5 | 44.9 ± 0.4
Hemoglobin (g/dL) | 16.2 ± 0.3 | 15.8 ± 0.3 | 15.5 ± 0.2 | 15.8 ± 0.2 | 15.4 ± 0.1 | 15.3 ± 0.1
Erythrocytes (10^6^/µL) | 10.40 ± 0.24 | 10.14 ± 0.22 | 9.89 ± 0.15 | 10.10 ± 0.15 | 9.90 ± 0.12 | 9.85 ± 0.08
Reticulocytes(10^6^/µL) | 0.08 ± 0.01 | 0.07 ± 0.01 | 0.08 ± 0.01 | 0.11 ± 0.01 | 0.06 ± 0.01 | 0.08 ± 0.01
Nucleated erythrocytes (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 45.9 ± 0.1 | 45.8 ± 0.2 | 46.1 ± 0.2 | 45.7 ± 0.2 | 45.9 ± 0.2 | 45.6 ± 0.2
Mean cell hemoglobin (pg) | 15.6 ± 0.1 | 15.5 ± 0.1 | 15.7 ± 0.1 | 15.6 ± 0.0 | 15.6 ± 0.1 | 15.5 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 33.9 ± 0.2 | 34.0 ± 0.1 | 34.0 ± 0.2 | 34.1 ± 0.1 | 33.9 ± 0.1 | 34.0 ± 0.1
Platelets (10^3^/µL) | 793.8 ± 13.4 | 840.6 ± 24.7 | 783.9 ± 17.6 | 858.3 ± 32.9 | 857.6 ± 40.1 | 860.6 ± 24.2
Leukocytes (10^3^/µL) | 3.94 ± 0.14 | 4.39 ± 0.22 | 3.89 ± 0.39 | 4.08 ± 0.21 | 4.46 ± 0.26 | 4.86 ± 0.28
Segmented neutrophils (10^3^/µL) | 0.58 ± 0.06 | 0.72 ± 0.09 | 0.53 ± 0.06 | 0.53 ± 0.03 | 0.66 ± 0.04 | 0.88 ± 0.07^*^
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Monocytes(10^3^/µL) | 0.08 ± 0.02 | 0.08 ± 0.01 | 0.10 ± 0.02 | 0.11 ± 0.01 | 0.09 ± 0.02 | 0.10 ± 0.02
Lymphocytes (10^3^/µL) | 3.19 ± 0.14 | 3.54 ± 0.13 | 3.17 ± 0.30 | 3.38 ± 0.20 | 3.64 ± 0.24 | 3.79 ± 0.22
Basophils (10^3^/µL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/µL) | 0.08 ± 0.02 | 0.06 ± 0.01 | 0.09 ± 0.04 | 0.06 ± 0.01 | 0.07 ± 0.02 | 0.09 ± 0.02
Female
Hematocrit (%) | 49.8 ± 1.3 | 50.2 ± 0.8 | 49.6 ± 0.9 | 48.9 ± 0.7 | 48.9 ± 0.7 | 48.7 ± 0.8
Hemoglobin (g/dL) | 16.4 ± 0.4 | 16.5 ± 0.3 | 16.2 ± 0.3 | 16.0 ± 0.2 | 16.0 ± 0.2 | 15.9 ± 0.3
Erythrocytes (10^6^/µL) | 10.53 ± 0.29 | 10.51 ± 0.16 | 10.44 ± 0.21 | 10.28 ± 0.15 | 10.20 ± 0.14 | 10.19 ± 0.18
Reticulocytes(10^6^/µL) | 0.06 ± 0.01 | 0.07 ± 0.01 | 0.09 ± 0.02 | 0.06 ± 0.01 | 0.05 ± 0.01 | 0.07 ± 0.01
Nucleated erythrocytes (10^3^/µL) | 0.01 ± 0.01 | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.02 ± 0.02 | 0.00 ± 0.00
Mean cell volume (fL) | 47.4 ± 0.1 | 47.7 ± 0.1 | 47.5 ± 0.2 | 47.6 ± 0.1 | 47.9 ± 0.1 | 47.8 ± 0.2
Mean cell hemoglobin (pg) | 15.6 ± 0.1 | 15.7 ± 0.1 | 15.5 ± 0.1 | 15.5 ± 0.1 | 15.7 ± 0.1 | 15.6 ± 0.0
Mean cell hemoglobin concentration (g/dL) | 32.9 ± 0.2 | 32.8 ± 0.2 | 32.6 ± 0.1 | 32.7 ± 0.2 | 32.9 ± 0.2 | 32.6 ± 0.1
Platelets (10^3^/µL) | 753.8 ± 46.5 | 816.3 ± 21.1 | 785.3 ± 32.8 | 804.2 ± 27.3 | 750.6 ± 43.9 | 856.2 ± 35.0
Leukocytes (10^3^/µL) | 5.55 ± 0.42 | 6.00 ± 0.33 | 5.52 ± 0.23 | 5.44 ± 0.37 | 6.33 ± 0.46 | 5.83 ± 0.20
Segmented neutrophils (10^3^/µL) | 0.66 ± 0.10 | 0.64 ± 0.07 | 0.53 ± 0.05 | 0.73 ± 0.09 | 1.10 ± 0.15^*^ | 1.11 ± 0.21^*^
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 4.78 ± 0.40 | 5.28 ± 0.29 | 4.88 ± 0.20 | 4.57 ± 0.28 | 5.09 ± 0.33 | 4.57 ± 0.13
Monocytes(10^3^/µL) | 0.05 ± 0.02 | 0.04 ± 0.02 | 0.05 ± 0.01 | 0.08 ± 0.03 | 0.08 ± 0.03 | 0.08 ± 0.01
Basophils (10^3^/µL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/µL) | 0.06 ± 0.02 | 0.05 ± 0.02 | 0.06 ± 0.02 | 0.06 ± 0.02 | 0.06 ± 0.02 | 0.07 ± 0.02

* Significantly different (P≤0.05) from the vehicle control group by Dunn’s or Shirley’s test

a Data are given as mean ± standard error. Statistical tests were performed on unrounded data.