# APPENDIX D SUMMARY OF LESIONS IN RATS AND B6C3F_1_ MICE IN THE 3-MONTH DERMAL STUDIES OF TRIMETHYLOLPROPANE TRIACRYLATE

TABLE D1 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the 3-Month Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal sacrifice | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Intestine small, ileum | (10) | | | | | (10)
Hyperplasia, lymphoid | | | | | | 1 (10%)
Liver | (10) | (2) | (1) | (1) | (3) | (10)
Hepatodiaphragmatic nodule | | 2 (100%) | 1 (100%) | 1 (100%) | 3 (100%) | 1 (10%)
Inflammation, chronic active | 1 (10%)
Vacuolization cytoplasmic | 2 (20%) | | | | | 2 (20%)
Pancreas | (10) | | | | | (10)
Atrophy | 1 (10%)
Cardiovascular System
Heart | (10) | | | | | (10)
Cardiomyopathy | 5 (50%) | | | | | 4 (40%)
Endocrine System
Pituitary gland | (10) | | | | | (10)
Hyperplasia, focal | 1 (10%)
Thyroid gland | (10) | | | | | (10)
Ultimobranchial cyst | 1 (10%)
General Body System
None
Genital System
Preputial gland | (10) | | | | | (10)
Inflammation, chronic active | | | | | | 1 (10%)
Prostate | (10) | | | | | (10)
Inflammation, chronic active | | | | | | 1 (10%)
Hematopoietic System
Lymph node, mandibular | (10) | | | | | (10)
Ectasia, lymphoid | | | | | | 1 (10%)
Lymph node, mesenteric | (10) | | | | | (10)
Hyperplasia, lymphoid | | | | | | 1 (10%)
Integumentary System
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Dermis, inflammation, chronic active | 2 (20%) | 1 (10%) | | 1 (10%)
Dermis, skin, site of application, fibrosis | | | | | | 1 (10%)
Dermis, skin, site of application, inflammation, chronic active | | 1 (10%) | 3 (30%) | 6 (60%) | 10 (100%) | 10 (100%)
Epidermis, skin, site of application, degeneration | | | 4 (40%) | 7 (70%) | 9 (90%) | 8 (80%)
Epidermis, skin, site of application, hyperplasia | | 4 (40%) | 7 (70%) | 10 (100%) | 10 (100%) | 10 (100%)
Epidermis, skin, site of application, inflammation, suppurative | | | | | | 4 (40%)
Epidermis, skin, site of application, necrosis | | | | 1 (10%) | | 1 (10%)
Sebaceous gland, skin, site of application, hyperplasia | | | 5 (50%) | 10 (100%) | 10 (100%) | 10 (100%)
Skin, site of application, degeneration | | | | 1 (10%)
Skin, site of application, hyperkeratosis | | | 5 (50%) | 10 (100%) | 10 (100%) | 10 (100%)
Musculoskeletal System
Skeletal muscle | | | | | | (1)
Abdominal, inflammation, chronic | | | | | | 1 (100%)
Nervous System
None
Respiratory System
Lung | (10) | (1) | | | (1) | (10)
Hemorrhage | 1 (10%) | 1 (100%) | | | 1 (100%)
Inflammation | 1 (10%)
Inflammation, chronic active | | 1 (100%) | | | | 2 (20%)
Nose | (10) | | | | | (10)
Respiratory epithelium, developmental malformation | | | | | | 1 (10%)
Trachea | (10) | (1) | | | | (10)
Hemorrhage | | 1 (100%)
Special Senses System
Eye | | | | (1)
Atrophy | | | | 1 (100%)
Urinary System
Kidney | (10) | | | | | (10)
Nephropathy | | | | | | 3 (30%)

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE D2 Summary of the Incidence of Neoplasms and Nonneoplastic Lesions in Female Rats in the 3-Month Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal sacrifice | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (2) | (1) | (3) | (1) | (10)
Hepatodiaphragmatic nodule | 1 (10%) | 2 (100%) | 1 (100%) | 3 (100%) | 1 (100%) | 4 (40%)
Inflammation | | | | | | 1 (10%)
Inflammation, chronic active | 9 (90%) | | | | | 9 (90%)
Cardiovascular System
Heart | (10) | | | | | (10)
Cardiomyopathy | 1 (10%)
Endocrine System
Thyroid gland | (10) | | | | | (10)
Ultimobranchial cyst | 1 (10%)
General Body System
None
Genital System
Ovary | (10) | (1) | (1) | (1) | | (10)
Inflammation, chronic | 1 (10%) | 1 (100%) | 1 (100%) | 1 (100%)
Uterus | (10) | | (1) | (1) | | (10)
Deciduoma NOS | | | | 1 (100%)
Hydrometra | 2 (20%) | | 1 (100%) | | | 4 (40%)
Hematopoietic System
Spleen | (10) | | | | | (10)
Pigmentation | 2 (20%) | | | | | 4 (40%)
Integumentary System
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Dermis, skin, site of application, granuloma | | | | | 1 (10%)
Dermis, skin, site of application, inflammation, chronic active | 1 (10%) | 2 (20%) | 1 (10%) | 9 (90%) | 8 (80%) | 10 (100%)
Epidermis, skin, site of application, degeneration | | | | 4 (40%) | 7 (70%) | 10 100%)
Epidermis, skin, site of application, hyperplasia | | | | 7 (70%) | 10 (100%) | 10 (100%)
Epidermis, skin, site of application, inflammation, suppurative | | | | | | 6 (60%)
Epidermis, skin, site of application, necrosis | | | | | | 5 (50%)
Sebaceous gland, skin, site of application, hyperplasia | | 1 (10%) | 6 (60%) | 9 (90%) | 10 (100%) | 10 (100%)
Skin, site of application, hyperkeratosis | | | 3 (30%) | 9 (90%) | 10 (100%) | 10 (100%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (10) | | | | | (10)
Inflammation, chronic active | 4 (40%) | | | | | 2 (20%)
Nose | (10) | | | | | (10)
Respiratory epithelium, metaplasia, squamous | | | | | | 1 (10%)
Special Senses System
Eye | | | | | (1)
Atrophy | | | | | 1 (100%)
Urinary System
Kidney | (10 | | | | | (10)
Nephroblastoma | | | | | | 1 (10%)
Nephropathy | 1 (10%) | | | | | 1 (10%)

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE D3 Summary of the Incidence of Nonneoplastic Lesions in Male B6C3F1 Mice in the 3-Month Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal sacrifice | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | | | | | (10)
Inflammation, suppurative | | | | | | 1 (10%)
Cardiovascular System
None
Endocrine System
None
General Body System
None
Genital System
None
Hematopoietic System
None
Integumentary System
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Dermis, skin, site of application, fibrosis | | | | | | 7 (70%)
Dermis, skin, site of application, inflammation, chronic active | 1 (10%) | | 2 (20%) | 10 (100%) | 9 (90%) | 10 (100%)
Epidermis, skin, site of application, degeneration | | | | 4 (40%) | 8 (80%) | 9 (90%)
Epidermis, skin, site of application, hyperplasia | | | 3 (30%) | 10 (100%) | 10 (100%) | 10 (100%)
Epidermis, skin, site of application, inflammation, suppurative | | | 1 (10%) | | 1 (10%) | 8 (80%)
Epidermis, skin, site of application, necrosis | | | 1 (10%) | 1 (10%) | 2 (20%) | 7 (70%)
Sebaceous gland, skin, site of application, hyperplasia | | | | 9 (90%) | 10 (100%) | 10 (100%)
Skin, site of application, hyperkeratosis | | | 3 (30%) | 8 (80%) | 8 (80%) | 10 (100%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
None
Special Senses System
None
Urinary System
None

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE D4 Summary of the Incidence of Nonneoplastic Lesions in Female B6C3F1 Mice in the 3-Month Dermal Study of Trimethylolpropane Triacrylate^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal sacrifice | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | | | | | (10)
Inflammation, chronic active | 2 (20%) | | | | | 1 (10%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (10) | | | | | (10)
Vacuolization cytoplasmic | 8 (80%) | | | | | 9 (90%)
Subcapsular, hyperplasia | 7 (70%) | | | | | 9 (90%)
General Body System
None
Genital System
Ovary | (10) | | (1) | | | (10)
Inflammation, chronic active | | | 1 (100%)
Hematopoietic System
None
Integumentary System
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Dermis, inflammation, chronic active | | | | 1 (10%) | 2 (20%)
Dermis, skin, site of application, fibrosis | | | | | 1 (10%) | 7 (70%)
Dermis, skin, site of application, inflammation, chronic active | | | 7 (70%) | 10 (100%) | 10 (100%) | 10 (100%)
Epidermis, skin, site of application, degeneration | | | | | 5 (50%) | 9 (90%)
Epidermis, skin, site of application, hyperplasia | | | 3 (30%) | 10 (100%) | 9 (90%) | 10 (100%)
Epidermis, skin, site of application, inflammation, suppurative | | | 1 (10%) | 1 (10%) | 2 (20%) | 5 (50%)
Epidermis, skin, site of application, necrosis | | | | 1 (10%) | 2 (20%) | 8 (80%)
Sebaceous gland, skin, site of application, hyperplasia | | | 1 (10%) | 10 (100%) | 10 (100%) | 10 (100%)
Skin, site of application, hyperkeratosis | | | 3 (30%) | 10 (100%) | 9 (90%) | 8 (80%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
None
Special Senses System
None
Urinary System
None

a Number of animals examined microscopically at the site and the number of animals with lesion